# Results and Evidence Synthesis

## Literature Search Results

The electronic database searches retrieved 344 individual references. From the total references retrieved, 246 were excluded during the title and abstract screening, and 79 studies were excluded during the full-text review. The screening results are outlined in a study selection diagram with reasons for exclusion documented at the full-text review level (Figure 6). The 19 included studies (18 human studies and 1 animal study) are listed in Appendix C.

Figure 6

Study Selection Diagram

## Health Effects Results

The human and animal data across all studies were sorted by exposure and then, if applicable, by individual health outcomes: changes in blood pressure; gestational hypertension; preeclampsia; or eclampsia/hemolysis, elevated liver enzyme levels, and low platelet count (HELLP) syndrome. The associations between TRAP components or traffic measures and health outcomes were evaluated individually and in totality (i.e., hypertensive disorders of pregnancy). The majority of the available evidence for this evaluation comes from epidemiological studies; however, experimental animal studies are presented where applicable. Individual TRAP components that were evaluated within the body of evidence were fine particulate matter (PM_2.5_), nitrogen oxides (NO_x_), carbon monoxide (CO), black carbon (BC), and elemental carbon (EC); direct exposure measurements of traffic density and proximity to major roads were also evaluated. When there was a sufficient number of results and similarity across studies, meta-analyses were conducted to synthesize the findings.

The main findings for associations between exposures to TRAP and hypertensive disorders of pregnancy are summarized below. Sections for Traffic-related Air Pollutants and Traffic Measures present the results and evidence synthesis in detail for each exposure and health outcome evaluated.

### Main Findings for Associations between Exposures to Traffic-related Air Pollution and Hypertensive Disorders of Pregnancy

The principal findings are outlined below including a brief description for the confidence ratings and level-of-evidence conclusions for the data that support the hazard identification conclusion for associations between exposures to TRAP and hypertensive disorders of pregnancy (Figure 7). The overall conclusion for this assessment was developed using a stepwise process. First, confidence ratings were developed for the individual TRAP components. Relevant data, including mechanistic studies, were then used to determine the appropriateness of developing a hazard conclusion for the combined TRAP exposure. The bodies of evidence for each TRAP component were combined and considered as a single TRAP exposure measure and reevaluated for factors that would increase or decrease confidence. Finally, a hazard identification conclusion for the combined TRAP exposure was developed.

Figure 7

Evidence Profile of the Main Findings for Traffic-related Air Pollution

^a^Dadvand et al. (2013), Rudra et al. (2011), Wu et al. (2011), Savitz et al. (2015), Choe et al. (2018).

^b^Malmqvist et al. (2013), Olsson et al. (2015), Dadvand et al. (2013), Wu et al. (2011); Pereira et al. (2013), van den Hooven et al. (2011), Pedersen et al. (2017), Savitz et al. (2015), Madsen et al. (2018).

^c^Olsson et al. (2015), Wu et al. (2011), Wu et al. (2016), van den Hooven et al. (2009), Malmqvist et al. (2013).

^d^Yorifuji et al. (2015), Miranda et al. (2013), van den Hooven et al. (2009), Madsen et al. (2018), Choe et al. (2018).

#### Summary

There is moderate confidence in the combined body of evidence from human studies reporting that exposures to TRAP during the entire gestation period is associated with the development of hypertensive disorders of pregnancy. The moderate confidence in the body of evidence across multiple measures of TRAP exposure translates to a moderate level of evidence. No experimental animal studies were identified for these measures, resulting in an inadequate level of evidence for the animal data. The moderate level of evidence from the human studies alone supports a hazard conclusion of presumed on the basis of a combined body of evidence that supports a consistent effect of TRAP on hypertensive disorders of pregnancy across a larger number of studies. This conclusion indicates multiple mechanisms by which the individual components can affect blood pressure and suggests a greater likelihood that individuals may be exposed to more than one component of TRAP. Therefore, the integration of the body of evidence supports a final hazard conclusion of TRAP exposure of presumed to be a hazard to pregnant women.

#### Individual Traffic-related Air Pollution Components

The effect of TRAP for individual traffic-related components—PM_2.5_, NO_2_, and traffic measures—was supported by meta-analyses. The strongest evidence from the individual TRAP components came from the PM_2.5_ data, which showed an association for preeclampsia per 10 µg/m^3^ increase in PM_2.5_ during the full pregnancy period (meta-OR: 1.51, 95% CI: 1.04, 2.20). Small but positive associations were also demonstrated for NO_2_ exposure and preeclampsia (meta-OR: 1.04, 95% CI: 0.97, 1.10). Consideration of these TRAP components, along with traffic measures, supports moderate initial confidence for the individual components, and there were no factors that would increase or decrease the confidence resulting in a final confidence rating of moderate.

#### Combined Body of Evidence for Traffic-related Air Pollution Exposure

Following the evaluation of individual TRAP components, other relevant factors, including mechanistic data, were considered to determine the appropriateness of developing a hazard conclusion for the combined TRAP exposure. Additional data (not evaluating blood pressure regulation during pregnancy) evaluating single pollutants support that individual PM_2.5_ and NO_2_ exposures can act independently to affect vascular inflammation and oxidative stress pathways that lead to increased blood pressure. Indeed, there was consistency in the direction of effect for studies in the human evidence that evaluated single TRAP components. Studies that evaluated more than one TRAP component also found significant associations between individual components and hypertensive disorders of pregnancy after statistically accounting for other exposures. However, TRAP includes multiple pollutants, and the likelihood of being exposed simultaneously to multiple TRAP components is high. The independent mechanisms by which these pollutants can elevate blood pressure along with evidence of an association between increased TRAP exposure and development of hypertensive disorders of pregnancy (supported by meta-analyses) demonstrate that multiple TRAP components can act on blood pressure parameters during pregnancy to lead to hypertension. Therefore, it was appropriate to develop a hazard conclusion for combined TRAP exposure to more accurately reflect the true exposure to pregnant women.

Conclusions for combined TRAP exposure were based on 18 epidemiological studies from 15 cohort studies,^3^ 1 cross-sectional study, and 2 case-control studies. Similar to the ratings developed for the individual components of TRAP, the initial confidence rating for the combined TRAP exposure was moderate. Factors that could increase or decrease confidence were then considered for the combined body of evidence. Upgrading for consistency was considered for the combined TRAP exposure because of the consistency in the directions of effect across multiple populations and geographic locations from separate lines of evidence for air pollution measures and traffic measures. In several cases, study authors evaluated associations between hypertensive disorders of pregnancy and exposure to a single air pollutant that served as a proxy for TRAP, whereas others evaluated associations between hypertensive disorders of pregnancy and multiple measures of TRAP (e.g., PM_2.5_ and NO_x_). While studies that evaluated multiple measures of TRAP accounted for co-exposures statistically, the body of literature does not represent completely independent lines of evidence, which would have strengthened the overall confidence in the associations. Thus, although consistency was considered as a factor for upgrading confidence, no changes were applied to the initial confidence, resulting in a final confidence rating of moderate for the combined TRAP exposure.

3 Wu et al. (2011) evaluated two independent cohorts.

The moderate confidence in the combined body of literature translates to a moderate level of evidence for the human data. There were no experimental animal studies in the body of evidence that were included in the assessment for the combined TRAP exposure, which translates to an inadequate level of evidence for the animal data. Integration of these level-of-evidence conclusions supports an initial hazard conclusion of presumed to be a hazard to pregnant women because of the extent and consistency of the available data. The body of evidence for combined TRAP exposure was determined to be presumed on the basis of a combined body of evidence that supports a consistent effect of TRAP on hypertensive disorders of pregnancy across a large number of studies. This determination indicates multiple mechanisms by which the individual components can affect blood pressure and suggests a greater likelihood that individuals may be exposed to more than one component of TRAP.

Mechanistic data were not considered to upgrade the final hazard conclusion because, to date, there are no mechanistic studies that investigate the effects of combined TRAP exposure on blood pressure during pregnancy. Mechanistic data that were reviewed were deemed not directly relevant and, therefore, were not considered for potentially upgrading the initial hazard conclusion based on biological plausibility. Taken together, the available evidence for combined TRAP exposure and hypertensive disorders of pregnancy supports a final hazard conclusion of presumed to be a hazard to pregnant women.

#### Integration of Evidence for Hypertensive Disorders of Pregnancy

The final conclusion for the combined TRAP body of evidence was developed after considering the individual TRAP components separately. The effect of TRAP was consistent across bodies of evidence for the individual components and was supported by meta-analyses for individual traffic-related PM_2.5_, and NO_2_.

##### Individual Traffic-related Air Pollution Components (PM_2.5_, NO_2_) and Traffic Measures

- Human body of evidence: Moderate confidence
  - PM_2.5_: Moderate confidence
  - NO_2_: Moderate confidence
  - Traffic Measures: Low confidence
- Animal body of evidence^4^: No evidence identified
  4 Erratum: The confidence rating for the animal body of evidence was changed from “Low (inadequate) confidence” to “No evidence identified” on July 25, 2019.
  - PM_2.5_: No studies
  - NO_2_: No studies
  - Traffic Measures: No studies

##### Combined Traffic-related Air Pollution Measures

- Initial hazard conclusion (Moderate human × Inadequate animal) = Presumed to be a hazard to pregnant women
- Final hazard conclusion: No change (after considering biological plausibility) = Presumed to be a hazard to pregnant women

Taken together, the data support a final hazard conclusion that exposure to TRAP is presumed to be a hazard to pregnant women (see Table 5).

Table 5 Traffic-related Air Pollution Summary Table

Exposure | Health Outcome | Confidence Rating in the Body of Evidence | | Level of Evidence in the Body of Evidence | | Hazard Conclusion
Exposure | Health Outcome | Human | Animal | Human | Animal | Hazard Conclusion
PM_2.5_ | Preeclampsia | Moderate | No Evidence Identified | – | – | –
NO_2_ | Preeclampsia | Moderate | No Evidence Identified | – | – | –
Traffic Density | Preeclampsia | Low | No Evidence Identified | – | – | –
Distance to Road Traffic | Preeclampsia | Low | No Evidence Identified | – | – | –
Combined TRAP | Hypertensive Disorders of Pregnancy | Moderate | No Evidence Identified | Moderate | Inadequate | [underlined: Presumed] to be a hazard to pregnant women

### Risk-of-bias Considerations

Risk-of-bias ratings for each study for all questions are presented in Figure 8 (human studies) and Figure 9 (animal studies). The risk of bias for individual studies in the body of evidence and for the body of evidence as a whole was considered in developing the confidence ratings for each health effect. The key risk-of-bias questions for human studies (e.g., exposure characterization, confounding/modifying variables, and outcome assessment) are discussed in the consideration of the body of evidence for each TRAP metric. Although no study was excluded based on concerns for risk of bias, confidence conclusions were considered with and without higher risk-of-bias studies (e.g., studies rating probably high or definitively high risk of bias for at least two key risk-of-bias questions) to assess the influence of these higher risk-of-bias studies.

Figure 8

Human Study Risk-of-bias Heatmap

Interactive figure and additional study details in Health Assessment Workspace Collaborative (HAWC) (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for human epidemiological studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure 9

Animal Study Risk-of-bias Heatmap

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

For this assessment, one of the key risk-of-bias questions addresses the exposure characterization. To draw conclusions about the associations between air pollution specifically derived from traffic and hypertensive disorders of pregnancy, individual studies are required to use valid, reliable, and sensitive methods to measure the exposure and these methods must be applied consistently across groups. Key considerations include reasonable alignment of the timing of exposure and the development of the outcome, the density of the monitoring network, and the use of appropriate models that account for spatial and temporal variability. Multiple approaches can be used to measure exposures of TRAP components in pregnant women. In general, ambient pollutant monitoring-based measurements, although widely used as a method for measuring air pollution, are generally poor in spatial coverage and are unlikely to capture the high spatial heterogeneity of air pollutants directly emitted from traffic. Geographical information systems (GIS)-based methods, such as land use regression (LUR) models, can provide better estimates of exposure to traffic-specific pollutants compared with monitoring-based measurements. GIS can account for the high spatial heterogeneity of local traffic emissions because they consider traffic surrogate parameters (e.g., distance-weighted traffic density) in the models. Thus, there is higher confidence that exposures can be attributed to traffic when using GIS-based methods to estimate exposures, and only studies in which the exposures could be reasonably attributed to traffic were included in the assessment. Other considerations for exposure include use of models based on individual residential addresses versus aggregated levels and residential mobility of the women during pregnancy. Risk-of-bias responses about the exposure characterization were reviewed and accepted by an external technical expert on exposures.

Another key risk-of-bias question for this assessment was confounding. Potential confounders for the individual pollutant evaluations included co-exposure to other traffic pollutants and traffic-related noise. When reported, correlations were discussed, however, the majority of the studies in the body of literature evaluated single pollutants and/or used single-pollutant models. Because many studies evaluated one pollutant that served as a surrogate for a combined TRAP exposure, the ability to reach hazard conclusions on individual exposures and hypertensive disorders of pregnancy was a limitation of the body of evidence. In addition, most study designs did not distinguish the contribution of traffic-related noise on the outcome of interest, and disentangling and evaluating the overall (and independent) effects of traffic noise on these outcomes is another limitation of this body of evidence (discussed further in Limitations of the Evidence Base). Other potential confounders were body mass index (BMI) and socioeconomic status (SES)—which are known risk factors for hypertensive disorders of pregnancy—and smoking, which, despite being a risk factor for hypertension in the general population, reduces the risk of hypertensive disorders during pregnancy. Race and ethnicity were not considered major confounders if the study evaluated a relatively homogeneous population, such as those studies observing populations in certain regions in Europe.

The third key risk-of-bias question addresses outcome assessment. Chronic or preexisting hypertension refers to elevated blood pressure that occurs before 20 weeks gestation and often predates pregnancy. Many studies in the available body of evidence excluded pregnant women with chronic hypertension or adjusted for this group in the analyses; however, depending on the source of the outcome data (e.g., birth certificate, hospital), this is generally difficult to do with certainty. Consequently, outcome misclassification may be a factor in some analyses.

The following sections include detailed discussions of the available evidence for effects of TRAP on hypertensive disorders of pregnancy (individual and combined outcomes).

## Traffic-related Air Pollutants

Traffic-related air pollutants are one of the main exposures used to characterize TRAP (the other exposure type, traffic measures, is discussed in the Traffic Measures section) and are defined by those primarily emitted by mobile sources due to fossil fuel combustion. Several major air pollutants regulated by the U.S. Environmental Protection Agency (EPA) are used as pollution surrogates for TRAP. Because many exposure surrogates used to identify TRAP are also generated by other sources, many studies utilized multiple exposure metrics to increase the confidence in the exposure characterization. The sections below begin with a brief summary of the bodies of evidence, followed by a narrative summary or meta-analysis of the human and (when applicable) animal evidence and confidence rating for the body of evidence. Some studies evaluated multiple traffic-related measures so there are instances of overlap across some studies.

### Particulate Matter and Hypertensive Disorders of Pregnancy

Particulate matter (PM) is a complex mixture whose major components include solid and liquid organic and inorganic substances (e.g., sulfate, nitrites, ammonia, sodium chloride, black carbon, mineral dust, water) suspended in the air. PM is typically categorized by the aerodynamic diameter of the particles: PM_10_ (coarse particles 2.5–10 µm); PM_2.5_ (fine particles 0.1–2.5 µm); and PM_0.1_ (ultrafine particles ≤0.1 µm). Coarse particle measurements, measured by monitoring stations alone, tend to be more uniform across large areas than the finer particles and therefore are not the best indicator for TRAP. PM_2.5_ or smaller exhibits higher spatial variation and, with the appropriate study design, there is higher confidence that the exposure can be attributed to traffic. There were no studies that evaluated ultrafine PM and met the PECO criteria. Therefore, although coarse, fine, and ultrafine PM are present in vehicle exhaust, this assessment will focus on PM_2.5_.

#### Human Health Studies for PM_2.5_

##### Summary

There is moderate confidence in the body of evidence that exposure to traffic-related PM_2.5_ during the entire gestation period is associated with an increased risk for preeclampsia. The five studies identified reported consistent evidence of an association between PM_2.5_ and preeclampsia in six cohorts of pregnant women in the United States and Spain (Dadvand et al. 2013; Rudra et al. 2011; Savitz et al. 2015; Wu et al. 2011). The studies and data provided were sufficiently similar to support meta-analyses with the summary effect estimate for the main analysis of 1.51 (95% CI: 1.04, 2.20) for risk of preeclampsia after full gestation PM_2.5_ exposure (Table 8; Figure 10). The initial confidence rating was moderate because all the studies included in the body of evidence were cohort studies that contained three out of four study design features (exposure prior to outcome, individual outcome data, and comparison group used). There was no change in the initial moderate confidence rating in the body of evidence after considering factors that may increase or decrease confidence.

Table 8 Pooled ORs and 95% CIs for TRAP-related PM_2.5_ and Preeclampsia

Exposure Window | Number of Results | OR (95% CI) per 10 µg/m^3^ Increase | Heterogeneity
Exposure Window | Number of Results | OR (95% CI) per 10 µg/m^3^ Increase | P Value* | I^2^
Full Gestational Period^a^ | 5 | 1.51 (1.04, 2.20) | <0.001 | 99%
Full Gestational Period [Excluding Savitz et al. (2015)] | 4 | 1.73 (1.51, 1.98) | <0.001 | 88%
Full Gestational Period [Excluding Rudra et al. (2011)] | 4 | 1.52 (0.96, 2.40) | <0.001 | 99%
Full Gestational Period^a^ [Excluding Rudra et al. (2011) and Savitz et al. (2015)] | 3 | 1.84 (1.64, 2.07) | 0.017 | 76%

* P value for test for heterogeneity. Significant values (p < 0.05) reflect results of the random-effects model.

^a^ One study (Wu et al. 2011) contributed two effect estimates to the analysis.

Figure 10

Full Gestation Exposure to PM_2.5_ and Preeclampsia^a^

When I^2^ p value is significant (p < 0.05), the random-effects model results are presented. When nonsignificant, the random-effects model results are identical to the fixed-effects model results.

^a^All ORs were converted to a 10 µg/m^3^ increase before analysis.

##### Overview of Available Human Data for PM_2.5_

Table 6 summarizes the available data in the human body of evidence that evaluated the association between exposure to traffic-related PM_2.5_ and hypertensive disorders of pregnancy. Five studies were identified that reported traffic-related PM_2.5_ exposures (Choe et al. 2018; Dadvand et al. 2013; Rudra et al. 2011; Savitz et al. 2015; Wu et al. 2011). These five studies comprised six independent cohorts from the United States or Spain. The body of evidence from the United States included one prospective cohort study conducted in western Washington (Rudra et al. 2011) and four retrospective cohort studies conducted in New York City (New York) (Savitz et al. 2015), Los Angeles and Orange Counties (California) (Wu et al. 2011), and Providence (Rhode Island) (Choe et al. 2018). In addition, there was one European study that was conducted in a cohort in Barcelona, Spain (Dadvand et al. 2013). The cohorts in Los Angeles and Orange Counties that were evaluated by Wu et al. (2011) were treated as two distinct populations based on the study locations and sociodemographic status of the cohorts and independent exposure assessments.

Table 6 Studies on Hypertensive Disorders of Pregnancy with TRAP-related PM_2.5_ Exposure in Humans

Study | Study Design (Location) Exposure Measure | Sample Size | Cases | Outcome | Exposure Period | OR (95% CI) | Unit Increase | Mean (SD)^a^ Exposure Level | Covariates Considered for Inclusion
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) Land use regression models | 61,640 | 2,211 | Preeclampsia | Trimester 1 | 0.96 (0.86, 1.06) | Per 3.1 µg/m^3^* | 9.7 (1.9) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) Land use regression models | 61,640 | 2,211 | Preeclampsia | Trimester 2 | 0.97 (0.87, 1.07) | Undefined IQR increase | 9.6 (1.9) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) Land use regression models | 61,640 | 2,211 | Preeclampsia | Trimester 3 | 0.97 (0.89, 1.05) | Undefined IQR increase | 9.5 (2.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) Land use regression models | 61,640 | 2,877 | Gestational hypertension | Trimester 1 | 1.00 (0.91, 1.09) | Per 3.1 µg/m^3^* | 9.7 (1.9) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) Land use regression models | 61,640 | 2,877 | Gestational hypertension | Trimester 2 | 1.04 (0.96, 1.14) | Undefined IQR increase | 9.6 (1.9) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) Land use regression models | 61,640 | 2,877 | Gestational hypertension | Trimester 3 | 0.94 (0.87, 1.01) | Undefined IQR increase | 9.5 (2.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | Full gestational period | 1.32 (1.02, 1.71) | Per 5.1 µg/m^3^* | 16.5 (5.1) µg/m^3^ | Maternal age, ethnicity, education, smoking, alcohol use, BMI, marital status, pre-gestational/ gestational diabetes, parity, multiple pregnancy, neighborhood socioeconomic status, season of conception, year of conception
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | Trimester 1 | 1.29 (0.94, 1.76) | Per 7.6 µg/m^3^ | 17.0 (7.6) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | Trimester 2 | 1.12 (0.85, 1.48) | Per 7.4 µg/m^3^* | 17.3 (7.4) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | Trimester 3 | 1.51 (1.13, 2.01) | Per 7.3 µg/m^3^* | 17.3 (7.3) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | Full gestational period | 1.53 (0.94, 2.49) | Per 5.1 µg/m^3^* | 16.5 (5.1) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | Trimester 1 | 1.69 (0.93, 3.05) | Per 7.6 µg/m^3^* | 17.0 (7.6) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | Trimester 2 | 1.41 (0.83, 2.40) | Per 7.4 µg/m^3^* | 17.3 (7.4) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | Trimester 3 | 1.29 (0.72, 2.32) | Per 7.3 µg/m^3^* | 17.3 (7.3) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | Full gestational period | 1.18 (0.87, 1.60) | Per 5.1 µg/m^3^* | 16.5 (5.1) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | Trimester 1 | 1.04 (0.75, 1.44) | Per 7.6 µg/m^3^* | 17.0 (7.6) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | Trimester 2 | 1.14 (0.79, 1.66) | Per 7.4 µg/m^3^* | 17.3 (7.4) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | Trimester 3 | 1.42 (1.01, 2.00) | Per 7.3 µg/m^3^* | 17.3 (7.3) µg/m^3^
Rudra et al. (2011) | Prospective cohort (Western Washington, USA) Land use regression models | 3,675 | 117 | Preeclampsia | Periconceptional^b^ | 1.02 (0.93, 1.12) | Per 0.5 µg/m^3^ | 10.1 (8.7–11.4) µg/m^3^ | Maternal age, nulliparity, BMI, race/ethnicity, education, marital status, smoking, household income, employment in early pregnancy, pre-pregnancy secondhand smoke, physical activity, history of asthma, diabetes, chronic hypertension, year and month of conception
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Total hypertensive disorders | Trimester 1 | 0.93 (0.86, 1.0) | Per 10 µg/m^3^ | 11.9 (2.5) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Total hypertensive disorders | Trimester 2 | 0.91 (0.84, 0.99) | Per 10 µg/m^3^ | 11.9 (2.4) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Gestational hypertension | Trimester 1 | 0.97 (0.86, 1.1) | Per 10 µg/m^3^ | 11.9 (2.5) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Gestational hypertension | Trimester 2 | 0.88 (0.77, 1.0) | Per 10 µg/m^3^ | 11.9 (2.4) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Severe preeclampsia/ eclampsia | Trimester 1 | 0.95 (0.82, 1.1) | Per 10 µg/m^3^ | 11.9 (2.5) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Severe preeclampsia/ eclampsia | Trimester 2 | 0.96 (0.81, 1.1) | Per 10 µg/m^3^ | 11.9 (2.4) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Mild preeclampsia | Trimester 1 | 0.88 (0.78, 1.0) | Per 10 µg/m^3^ | 11.9 (2.5) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | NR^c^ | Mild preeclampsia | Trimester 2 | 0.91 (0.80, 1.0) | Per 10 µg/m^3^ | 11.9 (2.4) µg/m^3^ | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Wu et al. (2011) | Retrospective cohort (Los Angeles County, USA) CALINE 4 air dispersion models^d^ | 38,709 | 1,303 | Preeclampsia | Full gestational period | 1.08 (1.02, 1.15) | Per 1.4 µg/m^3^* | 2.1 (1.2) µg/m^3^ | Maternal age, race/ethnicity, parity, prenatal care insurance type, season of conception, diabetes, poverty
Wu et al. (2011) | Retrospective cohort (Orange County, USA) CALINE 4 air dispersion models^d^ | 42,477 | 1,139 | Preeclampsia | Full gestational period | 1.10 (1.04, 1.17) | Per 1.4 µg/m^3^* | 1.6 (1.4) µg/m^3^ | Maternal age, race/ethnicity, parity, prenatal care insurance type, season of conception, diabetes, poverty

* Effect estimates marked with an asterisk were reported per interquartile range increase in PM_2.5_.

^a^ Dadvand et al. (2013) and Rudra et al. (2011), reported median (IQR) levels of PM_2.5_.

^b^ Rudra et al. (2011) defined the periconceptional period as the 7 months surrounding conception.

^c^ NR = Not reported: The overall number of cases for this study was not reported. The number of cases used in the statistical analyses are presented below in Table 7.

^d^ Wu et al. (2011) also reported land use regression model estimates that are based on ambient air pollution data. The CALINE4 dispersion modeling estimates for PM_2.5_ and NO_x_ were selected as these estimates capture local traffic emissions at a finer resolution (within 3 km of each residence) for five traffic-related pollutants.

Each study evaluated associations between PM_2.5_ exposure and the risk for developing preeclampsia. Additional outcomes evaluated include early- and late-onset preeclampsia (Dadvand et al. 2013), gestational hypertension (Choe et al. 2018; Savitz et al. 2015), severe and mild preeclampsia/eclampsia, and combined hypertensive pregnancy disorders (Savitz et al. 2015).

Most studies evaluated exposure over the entire gestational period, although two studies considered only trimester-specific exposures (Choe et al. 2018; Savitz et al. 2015). Dadvand et al. (2013) assessed the full gestational period in addition to trimester-specific exposures. Investigators reported the odds of developing hypertensive disorders of pregnancy associated with PM_2.5_ using various units of exposure. Most studies reported effect estimates based on interquartile range (IQR) increases in PM_2.5_, whereas others, including Rudra et al. (2011) and Savitz et al. (2015), reported effect estimates associated with 10 μg/m^3^ or 0.5 μg/m^3^ increases in PM_2.5_.

The range in the number of participants varied by study from approximately 3,100 to over 280,000, with the number of cases ranging between 47 and 3,928. Overall, the exposures were well characterized, and the timings of exposure were reasonably well aligned with the outcome assessments for the body of evidence. All studies assessed traffic-related PM_2.5_ exposures using LUR models with the exception of the Wu et al. (2011) study, which used an air dispersion model. The CALINE4 air dispersion model measurement reported in this study was a more sensitive measure of traffic-related PM_2.5_ because it could capture local traffic emissions within 3 km of each residence. This study examined multiple exposure measurements and also included ambient monitoring data for PM_2.5_.

##### Synthesis of Human Evidence and Meta-analysis

The studies that evaluated associations between exposure to PM_2.5_ and hypertensive disorders of pregnancy generally reported an increased risk for developing hypertensive disorders of pregnancy (particularly preeclampsia) with increasing exposures to PM_2.5_. The mean exposures reported by the study authors ranged from 9.3–17.3 µg/m^3^ in studies that modeled exposures using LUR methods. The Wu et al. (2011) study modeled PM_2.5_ exposures using the CALINE4 air dispersion model (but also measured PM_2.5_ using ambient monitoring stations; data not included in the assessment), and mean exposure levels were lower due to the finer resolution by which the model estimate could capture PM_2.5_ concentrations from a single emission source (i.e., local traffic within 3 km of a residence). Associations were evaluated for PM_2.5_ exposures during the entire pregnancy period and/or during each trimester. Studies that estimated exposure to traffic-related PM_2.5_ during the entire pregnancy period reported consistent associations between this TRAP component and hypertensive disorders of pregnancy. Results for trimester-specific exposures were less consistent. Many of the trimester-specific evaluations showed positive associations that did not reach statistical significance, except for Choe et al. (2018) who reported slightly negative (not statistically significant) associations. First trimester associations were generally weakly correlated with hypertensive disorders of pregnancy. In the Savitz et al. (2015) study, trimester-specific odds ratios (ORs) from the standard adjusted model showed significant associations between first and second trimester exposures to PM_2.5_ and total hypertensive disorders, gestational hypertension, and severe preeclampsia, but those associations were eliminated when the models were further adjusted for delivery hospital. Although the pathogenesis of hypertensive disorders of pregnancy (discussed in more detail in the Discussion) is thought to originate in the first trimester, there is inadequate evidence from these studies to determine if specific trimesters are more strongly correlated with hypertensive disorders of pregnancy. The lack of consistent associations during these windows is more likely due to the small number of studies that evaluated trimester-specific exposures and might not reflect the true relationship between these exposure windows and hypertensive disorders of pregnancy.

Correlations across multiple pollutants were not consistently reported across the body of evidence. Some studies evaluated correlations between exposures (e.g., Rudra et al. (2011), Wu et al. (2011)); others used single-pollutant models (Dadvand et al. 2013) and/or adjusted for the other exposures evaluated (Choe et al. 2018; Savitz et al. 2015). For those studies that did evaluate correlations between exposures, authors generally reported moderate correlations between LUR-modeled PM_2.5_ and other pollutants; the CALINE4 model showed high correlation among pollutants (Wu et al. 2011).

The available data for the full pregnancy exposure period were sufficient to perform a meta-analysis to evaluate the effects of PM_2.5_ exposure on the risk of preeclampsia as three or more individual study results were available (Table 7). Choe et al. (2018) did not report an association between PM_2.5_ exposure and preeclampsia. This study was not included in the meta-analysis because this study included ORs for all three trimesters but did not include trimester-specific interquartile range increases. Savitz et al. (2015) reported risk estimates for trimesters 1 and 2, and these results were pooled into one risk estimate for trimesters 1 and 2 combined. Rudra et al. (2011) reported an exposure window around the conception period (i.e., a 7-month period). Because Savitz et al. (2015) and Rudra et al. (2011) reported exposure windows other than the entire pregnancy period, sensitivity analyses were performed with and without these two studies.

Table 7 References Included in Meta-analysis: Studies on Hypertensive Disorders of Pregnancy with TRAP-related PM_2.5_ Exposure in Humans

Study | Study Design (Location) | Analysis Sample Size | Cases Included in Analysis | Outcome | Exposure Period | OR (95% CI) per 10 µg/m^3^ Increase* | Mean (SD)^a^ Exposure Level | Covariates Included in Final Model
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) | 8,398 | 103 | Preeclampsia | Full gestational period | 1.72 (1.22, 2.43) | 16.5 (5.1) µg/m^3^ | Maternal age, ethnicity, education, smoking, alcohol use, BMI, marital status, pre-gestational/ gestational diabetes, parity, multiple pregnancy, neighborhood socioeconomic status, season of conception, year of conception
Rudra et al. (2011) | Prospective cohort (Western Washington, USA) | 3,509 | 117 | Preeclampsia | Periconceptional^b^ | 1.49 (1.35, 1.63) | 10.1 (8.7–11.4) µg/m^3^ | Maternal age, nulliparity, BMI, race/ethnicity, smoking, season, and year of conception
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 4,226 | Severe preeclampsia | Trimesters 1, 2 | 0.96 (0.89, 1.03) | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 6,940 | Mild preeclampsia | Trimesters 1, 2 | 0.90 (0.86, 0.94) | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 11,166 | Combined mild and severe preeclampsia | Trimesters 1, 2 | 0.92 (0.88, 0.95)^d^ | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, hospital of delivery
Wu et al. (2011) | Retrospective cohort (Los Angeles County, USA) | Not reported^e^ | 1,303 | Preeclampsia | Full gestational period | 1.73 (1.62, 1.85) | 2.1 (1.2) µg/m^3^ | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception
Wu et al. (2011) | Retrospective cohort (Orange County, USA) | Not reported^e^ | 1,103 | Preeclampsia | Full gestational period | 1.98 (1.85, 2.11) | 1.6 (1.4) µg/m^3^ | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception

* All ORs were converted to a 10 µg/m^3^ increase before analysis.

^a^ Dadvand et al. (2013) and Rudra et al. (2011) reported median (IQR) levels of PM_2.5_.

^b^ Rudra et al. (2011) defined the periconceptional period as the 7 months surrounding conception.

^c^ Savitz et al. (2015) reported mean PM_2.5_ exposures for trimester 1 and trimester 2 separately.

^d^ This effect estimate was calculated by combining the severe and mild preeclampsia values that were reported by Savitz et al. (2015).

^e^ Not reported = The overall number of participants included in each analysis was not reported by county. The adjusted NO_2_ LUR model included 81,186 subjects total, and the NO_x_ CALINE4 model included 79,629 individuals total.

The available evidence indicate that the meta-OR for preeclampsia was 1.51 (95% CI: 1.04, 2.20) per 10 µg/m^3^ increase in PM_2.5_ concentration (Table 8; Figure 10). Sensitivity analyses with and without Rudra et al. (2011) and Savitz et al. (2015) were performed and showed a larger effect estimate when the analysis only included studies that evaluated the full gestational period (Table 8).

There was evidence of heterogeneity among studies that reported PM_2.5_ exposure during the full gestational period (p < 0.001 [Table 8]). Separate sensitivity analyses that excluded each study one at a time and reevaluated the model revealed that no single study influenced the meta-analysis to a large degree (Table E-1; Figure E-1). In addition, a formal test of publication bias (Egger's test and funnel plots) revealed no evidence of publication bias (p = 0.318) (Figure E-2; Table E-2); thus, a trim and fill analysis was not necessary.

##### Risk-of-bias Considerations

The PM_2.5_ studies were generally rated probably low or definitely low across all risk-of-bias domains, including the key risk-of-bias questions, as shown in the risk-of-bias heatmap (Figure 11) and bar chart (Figure 12). Therefore, confidence in the body of evidence for PM_2.5_ was not changed for risk of bias. The key risk-of-bias considerations are detailed below, and the study-specific rating details can be found in HAWC (https://hawcproject.org/assessment/60/) (NTP 2019a).

Figure 11

Risk-of-bias Heatmap: PM_2.5_ and Hypertensive Disorders of Pregnancy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for human epidemiological studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure 12

Risk-of-bias Bar Chart: PM_2.5_ and Hypertensive Disorders of Pregnancy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for human epidemiological studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

###### Exposure Characterization

Overall, the exposure and outcome data were reasonably well aligned, although the exposures were not truncated at the time of diagnosis in three studies (Choe et al. 2018; Savitz et al. 2015; Wu et al. 2011). The monitoring networks were sufficiently dense. The LUR exposure models used in all but one study have high resolution to capture the spatial heterogeneity of air pollutants directly emitted from traffic and can characterize temporal variability using temporal trends derived from ambient monitoring stations to reasonably attribute the PM_2.5_ exposures to traffic. The CALINE4 air dispersion model has high spatial and moderate temporal variability and has the resolution to estimate concentrations of PM_2.5_ from local traffic within 3 km of a residence (Wu et al. 2011), thus making it a more sensitive model to estimate traffic-related contributions. Exposures were assessed at the residential address level at the time of delivery, however, there is a potential exposure misclassification due to the lack of residential mobility information (e.g., moving or working in a different location) from any of the studies for this exposure. This might represent a nondifferential exposure misclassification, which would likely bias the results toward the null because exposures may vary at a different location.

###### Outcome Assessment

Chronic hypertension was usually excluded from analyses, and study authors explicitly stated this exclusion or it was inferred from the definition of the outcome evaluated (e.g., preeclampsia was defined as elevated blood pressure and proteinuria after 20 weeks gestation in previously normotensive women). In some cases, the availability of this information depends on the source of outcome data. In general, birth certificate data poorly report information surrounding preexisting hypertension because they are more often dependent on the timing of the first prenatal visit in clinical records for first pregnancies. However, documentation for both hospital and birth certificate data of preexisting (chronic) hypertension is typically more complete in women who have pregnancy complications. Thus, there is likely some outcome misclassification in the “noncases” for these studies that would bias the effect estimates toward the null. There were no other risk-of-bias concerns about outcome classification in the other studies evaluating associations between PM_2.5_ and hypertensive disorders of pregnancy.

###### Confounding and Modifying Variables

Covariates used in the models are provided in tables for this report. All of the studies considered the standard covariates that are thought to be associated with hypertensive disorders of pregnancy (e.g., maternal age, race/ethnicity, socioeconomic status [SES]). Smoking was not addressed consistently across the body of evidence. Statistical adjustments were made for smokers in half of the studies examined; in other studies, smokers were excluded. Because of the established, although paradoxical, negative association (Conde-Agudelo et al. 1999; Engel et al. 2013; England and Zhang 2007; Jeyabalan et al. 2008; Karumanchi and Levine 2010; Wei et al. 2015; Wikstrom et al. 2010) between smoking and hypertensive disorders of pregnancy, the lack of adjustment in some studies could bias the effect sizes toward the null, and the true relationship between the PM_2.5_ exposure and preeclampsia may be greater than what is reported in the analyses. Considerations of BMI were more consistent, with most studies adjusting for BMI. In general, the same studies that included smokers in the analysis also did not adjust for BMI (Wu et al. 2011). The lack of adjustments for BMI in some cohorts complicates the interpretation of results because obesity is also a risk factor for hypertensive disorders of pregnancy. Savitz et al. (2015) reported positive associations between exposure to PM_2.5_ during the first and second trimesters and total hypertensive disorders, gestational hypertension, and severe preeclampsia using standard adjustments (e.g., maternal age, race/ethnicity, education, parity, conception year, BMI); however, when data were adjusted for the delivery hospital, those positive associations were eliminated. This potential source of confounding was not considered in other studies, and the interpretation of those findings is unclear. The outcome data were obtained primarily from hospital discharge data (some data were obtained from linked birth certificate files if they were available), and the impact of the delivery hospital more likely reflects differences in disease coding for degrees of hypertensive disorders of pregnancy across the different hospitals. While this adjustment may be warranted for gestational hypertension and mild preeclampsia, as disorders with milder effects are more likely to be misclassified, this is less of a concern when evaluating total hypertensive disorders of pregnancy and severe preeclampsia/eclampsia. Thus, adjusting for hospital would likely be an over adjustment; however, for consistency, only the fully adjusted models (including hospital delivery) were included in the analysis. Because the standard adjusted model showed positive associations for several outcomes, the overall effect size would be slightly larger (meta-OR: 1.58 (95% CI: 1.35, 1.86)) if those estimates were included in the analysis. Other potential or known confounders and variables were appropriately adjusted in the analyses.

###### Summary

While there were some risk-of-bias concerns, those concerns would potentially bias the results toward and away from the null. Given the general consistency of effects across studies despite the different directions of potential bias, the results support the likelihood of a true association between exposure to PM_2.5_ during pregnancy and hypertensive disorders of pregnancy. For all remaining risk-of-bias questions in all other individual studies that evaluated PM_2.5_, there was low risk of bias and, thus, no major concerns over the internal validity of the reported results that would decrease the overall confidence in the body of evidence.

##### Experimental Animal Studies for PM_2.5_

There were no animal data evaluating associations between PM_2.5_ exposure and hypertensive disorders of pregnancy that met the PECO criteria for this assessment.

##### Evidence Synthesis for Studies of PM_2.5_

Traffic-related PM_2.5_ exposure is consistently associated with the development of preeclampsia in humans based on the available evidence. There is moderate confidence in the body of evidence that exposure to traffic-related PM_2.5_ during the entire gestation period is associated with an increased risk for preeclampsia. The summary effect estimate for the meta-analysis is 1.51 (95% CI: 1.04, 2.20) for developing preeclampsia with increasing (per 10 µg/m^3^ increase) traffic-related PM_2.5_ exposure. No animal studies were identified. The confidence ratings are summarized below.

- Human body of evidence: Moderate confidence
- Animal body of evidence: No studies

### Nitrogen Oxides and Hypertensive Disorders of Pregnancy

Nitrogen oxides (NO_x_) is a generic term that refers to the sum of seven nitrogen oxide compounds, including nitric oxide (NO) and nitrogen dioxide (NO_2_). These compounds are derived primarily from combustion-related emissions sources, such as motor vehicles, although NO_x_ are also produced naturally by lightning and (minimally) by microbial processes in soils. NO_x_ can react with other chemicals in the air to form PM and ozone. Of the seven NO_x_ compounds, NO_2_ is used as the indicator for the larger group of NO_x_ because it is the most prevalent form in the atmosphere generated by human activities. Thus, although the available evidence for this assessment evaluated associations between NO_2_ or combined NO_x_ exposures and hypertensive disorders of pregnancy, the main conclusions are based primarily on NO_2_ evidence.

#### Human Health Studies for NO_2_ or NO_x_

##### Summary

There is moderate confidence in the body of evidence that exposure to traffic-related NO_2_ or NO_x_ during the entire gestation period is associated with an increased risk for preeclampsia or hypertensive disorders of pregnancy. The nine studies identified (eight cohort studies and one case-control study in the United States, Spain, Sweden, Australia, Denmark, Norway, and The Netherlands) reported consistent evidence of an association between NO_2_ or NO_x_ and preeclampsia or combined hypertensive disorders of pregnancy. The studies and data for NO_2_ were sufficiently similar to perform meta-analyses with a summary effect estimate for the main analysis of 1.04 (95% CI: 0.97, 1.10) for risk of preeclampsia after full gestation exposure to NO_2_ (Figure 14). The initial confidence rating was moderate because all of the studies included in the body of evidence were cohort studies that contained three out of four study design features (exposure prior to outcome, individual outcome data, comparison group used). There was no change in the initial moderate confidence rating in the body of evidence after considering factors that may increase or decrease confidence.

Figure 14

Full Gestation Exposure to NO_2_ and Preeclampsia^a^

When I^2^ p value is significant (p < 0.05), the random-effects model results are presented. When nonsignificant, the random-effects model results are identical to the fixed-effects model results.

^a^All ORs were converted to a 10 µg/m^3^ increase before analysis.

##### Overview of Available Human Data for NO_2_ or NO_x_

Table 9 summarizes the available data in the human body of evidence that evaluated the associations between exposure to traffic-related NO_2_ or combined NO_x_ and the health outcomes of interest. Nine studies were identified that evaluated associations between traffic-related NO_2_ or NO_x_ exposures and preeclampsia or combined hypertensive disorders of pregnancy. The available evidence included five retrospective cohort studies from Spain (Dadvand et al. 2013), Sweden (Olsson et al. 2015), the United States (Savitz et al. 2015; Wu et al. 2011) and Australia (Pereira et al. 2013); three prospective cohort studies from Denmark (Pedersen et al. 2017), Norway (Madsen et al. 2018), and The Netherlands (van den Hooven et al. 2011); and one case-control study from Sweden (Malmqvist et al. 2013). The number of participants in these studies ranged from 7,000 to more than 260,000 pregnant women and included between 100 and 17,000 cases. All studies assessed traffic-related NO_2_ or NO_x_ exposures using LUR models (Dadvand et al. 2013; Madsen et al. 2018; Pereira et al. 2013; Savitz et al. 2015) or air dispersion models (Malmqvist et al. 2013; Olsson et al. 2015; Pedersen et al. 2017; van den Hooven et al. 2011). Wu et al. (2011) compared multiple exposure measures and estimated NO_2_ exposures using LUR models and NO_x_ exposures using air dispersion models for each cohort in Los Angeles and Orange Counties.

Table 9 Studies on Hypertensive Disorders of Pregnancy with TRAP-related NO_2_ or NO_x_ Exposure in Humans

Study | Study Design (Location) Exposure Measure | Sample Size | Cases | Outcome | Exposure | Exposure Period | OR (95% CI) | Unit Increase | Mean (SD)^a^ Exposure Level | Covariates Considered for Inclusion
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_2_ | Full gestational period | 1.09 (0.94, 1.27) | Per 19.7 µg/m^3^* | 55.7 (19.7) µg/m^3^ | Maternal age, ethnicity, education, smoking, alcohol use, BMI, marital status, pre-gestational/ gestational diabetes, parity, multiple pregnancy, neighborhood socioeconomic status, season of conception, year of conception
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_2_ | Trimester 1 | 1.11 (0.91, 1.35) | Per 28.1 µg/m^3^* | 56.8 (28.1) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_2_ | Trimester 2 | 1.05 (0.85, 1.30) | Per 27.8 µg/m^3^* | 58.0 (27.8) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_2_ | Trimester 3 | 1.17 (0.99, 1.37) | Per 27.7 µg/m^3^* | 57.7 (27.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_x_ | Full gestational period | 1.07 (0.97, 1.18) | Per 43.7 µg/m^3^* | 107.5 (43.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_x_ | Trimester 1 | 1.09 (0.94, 1.26) | Per 73.4 µg/m^3^* | 105.3 (73.4) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_x_ | Trimester 2 | 1.06 (0.90, 1.26) | Per 73.6 µg/m^3^* | 107.8 (73.6) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 103 | Preeclampsia (all cases) | NO_x_ | Trimester 3 | 1.14 (0.99, 1.29) | Per 73.8 µg/m^3^* | 106.5 (73.8) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_2_ | Full gestational period | 1.11 (0.86, 1.44) | Per 19.7 µg/m^3^* | 55.7 (19.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_2_ | Trimester 1 | 1.17 (0.85, 1.59) | Per 28.1 µg/m^3^* | 56.8 (28.1) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_2_ | Trimester 2 | 1.13 (0.82, 1.55) | Per 27.8 µg/m^3^* | 58.0 (27.8) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_2_ | Trimester 3 | 1.08 (0.73, 1.60) | Per 27.7 µg/m^3^* | 57.7 (27.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_x_ | Full gestational period | 1.10 (0.95, 1.27) | Per 43.7 µg/m^3^* | 107.5 (43.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_x_ | Trimester 1 | 1.14 (0.94, 1.38) | Per 73.4 µg/m^3^* | 105.3 (73.4) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_x_ | Trimester 2 | 1.13 (0.90, 1.42) | Per 73.6 µg/m^3^* | 107.8 (73.6) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 26 | Early-onset preeclampsia | NO_x_ | Trimester 3 | 1.12 (0.85, 1.46) | Per 73.8 µg/m^3^* | 106.5 (73.8) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_2_ | Full gestational period | 1.06 (0.86, 1.29) | Per 19.7 µg/m^3^* | 55.7 (19.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_2_ | Trimester 1 | 1.06 (0.82, 1.37) | Per 28.1 µg/m^3^* | 56.8 (28.1) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_2_ | Trimester 2 | 1.01 (0.77, 1.33) | Per 27.8 µg/m^3^* | 58.0 (27.8) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_2_ | Trimester 3 | 1.14 (0.93, 1.40) | Per 27.7 µg/m^3^* | 57.7 (27.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_x_ | Full gestational period | 1.04 (0.98, 1.21) | Per 43.7 µg/m^3^* | 107.5 (43.7) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_x_ | Trimester 1 | 1.04 (0.84, 1.22) | Per 73.4 µg/m^3^* | 105.3 (73.4) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_x_ | Trimester 2 | 0.94 (0.72, 1.22) | Per 73.6 µg/m^3^* | 107.8 (73.6) µg/m^3^
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) Land use regression models | 8,398 | 75 | Late-onset preeclampsia | NO_x_ | Trimester 3 | 1.10 (0.92, 1.32) | Per 73.8 µg/m^3^* | 106.5 (73.8) µg/m^3^
Madsen et al. (2018) | Prospective cohort (Norway) Land use regression models | 17,533 | 590 | Preeclampsia | NO_2_ | Full gestational period | 0.89 (0.74, 1.08) | Per 10 µg/m^3^ | 13.6 (6.9) µg/m^3^ | Maternal age, marital status, education, BMI, parity, smoking, diabetes, chronic hypertension, child sex, area, year of birth
Madsen et al. (2018) | Prospective cohort (Norway) Land use regression models | 17,533 | 941 | Hypertension during pregnancy | NO_2_ | Full gestational period | 0.91 (0.78, 1.06) | Per 10 µg/m^3^ | 13.6 (6.9) µg/m^3^ | Maternal age, marital status, education, BMI, parity, smoking, diabetes, chronic hypertension, child sex, area, year of birth
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 2,323 | Preeclampsia (all cases) | NO_x_ | Trimester 1 | 1.43 (1.25, 1.63) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 2,323 | Preeclampsia (all cases) | NO_x_ | Trimester 2 | 1.50 (1.31, 1.71) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 2,323 | Preeclampsia (all cases) | NO_x_ | Trimester 3 | 1.51 (1.32, 1.73) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 1,799 | Mild preeclampsia | NO_x_ | Trimester 1 | 1.47 (1.26, 1.71) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 1,799 | Mild preeclampsia | NO_x_ | Trimester 2 | 1.59 (1.36, 1.86) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 1,799 | Mild preeclampsia | NO_x_ | Trimester 3 | 1.51 (1.29, 1.77) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 571 | Severe preeclampsia | NO_x_ | Trimester 1 | 1.30 (1.00, 1.69) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 571 | Severe preeclampsia | NO_x_ | Trimester 2 | 1.24 (0.95, 1.62) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Malmqvist et al. (2013) | Case-control (Sweden) Dispersion models | 81,110 | 571 | Severe preeclampsia | NO_x_ | Trimester 3 | 1.48 (1.12, 1.95) | For >22.7 µg/m^3^ compared with 2.5–8.9 µg/m^3^ (reference) | 14.2 µg/m^3^ | Maternal age, BMI, smoking, parity, ethnicity, type 1 diabetes, gestational diabetes, year of delivery
Olsson et al. (2015) | Retrospective cohort (Sweden) Dispersion models | 102,768 | 2,762 | Pregnancy-induced hypertensive disorders | NO_x_ | Trimester 1 | 1.17 (1.10, 1.26) | Per 10 µg/m^3^ | 15.1 (7.4) µg/m^3^ | Maternal age, asthma, region of origin, education, parity, date of conception, first trimester ozone, first trimester temperature, smoking, BMI, family situation
Pedersen et al. (2017) | Prospective cohort (Denmark) Dispersion models | 72,745 | 1,880 | Preeclampsia (all cases) | NO_2_ | Full gestational period | 1.08 (1.01, 1.15) | Per 10 µg/m^3^ | 11.5 (6.7) µg/m^3^ | Maternal age, BMI, height, parity, season of conception, education, household income, smoking, physical activity, railway or airport noise, year of last menstrual period
Pedersen et al. (2017) | Prospective cohort (Denmark) Dispersion models | 72,745 | 487 | Severe preeclampsia | NO_2_ | Full gestational period | 0.90 (0.78, 1.04) | Per 10 µg/m^3^ | 11.5 (6.7) µg/m^3^ | Maternal age, BMI, height, parity, season of conception, education, household income, smoking, physical activity, railway or airport noise, year of last menstrual period
Pedersen et al. (2017) | Prospective cohort (Denmark) Dispersion models | 72,745 | 1,393 | Mild preeclampsia | NO_2_ | Full gestational period | 1.14 (1.06, 1.23) | Per 10 µg/m^3^ | 11.5 (6.7) µg/m^3^ | Maternal age, BMI, height, parity, season of conception, education, household income, smoking, physical activity, railway or airport noise, year of last menstrual period
Pedersen et al. (2017) | Prospective cohort (Denmark) Dispersion models | 72,745 | 671 | Early-onset preeclampsia | NO_2_ | Full gestational period | 1.19 (1.07, 1.32) | Per 10 µg/m^3^ | 11.5 (6.7) µg/m^3^ | Maternal age, BMI, height, parity, season of conception, education, household income, smoking, physical activity, railway or airport noise, year of last menstrual period
Pedersen et al. (2017) | Prospective cohort (Denmark) Dispersion models | 72,745 | 1,209 | Late-onset preeclampsia | NO_2_ | Full gestational period | 1.01 (0.93, 1.10) | Per 10 µg/m^3^ | 11.5 (6.7) µg/m^3^ | Maternal age, BMI, height, parity, season of conception, education, household income, smoking, physical activity, railway or airport noise, year of last menstrual period
Pedersen et al. (2017) | Prospective cohort (Denmark) Dispersion models | 72,745 | 765 | Gestational hypertension | NO_2_ | Full gestational period | 1.01 (0.91, 1.13) | Per 10 µg/m^3^ | 11.5 (6.7) µg/m^3^ | Maternal age, BMI, height, parity, season of conception, education, household income, smoking, physical activity, railway or airport noise, year of last menstrual period
Pedersen et al. (2017) | Prospective cohort (Denmark) Dispersion models | 72,745 | 2,430 | Hypertensive disorders in pregnancy | NO_2_ | Full gestational period | 1.07 (1.01, 1.14) | Per 10 µg/m^3^ | 11.5 (6.7) µg/m^3^ | Maternal age, BMI, height, parity, season of conception, education, household income, smoking, physical activity, railway or airport noise, year of last menstrual period
Pereira et al. (2013) | Retrospective cohort (Perth, Australia) Land use regression models | 23,425 | 943 | Preeclampsia | NO_2_ | Full gestational period | 1.12 (1.01, 1.25) | Per 5.63 ppb* (10.58 µg/m^3^) | 23.04 (4.14) ppb [43.32 (7.8) µg/m^3^] | Maternal age, pre-gestational and gestational diabetes, aboriginal status, parity, season of conception, smoking, area socioeconomic status
Pereira et al. (2013) | Retrospective cohort (Perth, Australia) Land use regression models | 23,425 | 943 | Preeclampsia | NO_2_ | Trimester 1 | 1.07 (0.91, 1.27) | Per 15.99 ppb* (30.06 ug/m^3^) | 23.29 (10.19) ppb [43.79 (19.2) µg/m^3^] | Maternal age, pre-gestational and gestational diabetes, aboriginal status, parity, season of conception, smoking, area socioeconomic status
Pereira et al. (2013) | Retrospective cohort (Perth, Australia) Land use regression models | 23,425 | 943 | Preeclampsia | NO_2_ | Trimester 2 | 1.04 (0.86, 1.26) | Per 16.97 ppb* (31.90 µg/m^3^) | 23.27 (10.29) ppb [43.75 (19.3) µg/m^3^] | Maternal age, pre-gestational and gestational diabetes, aboriginal status, parity, season of conception, smoking, area socioeconomic status
Pereira et al. (2013) | Retrospective cohort (Perth, Australia) Land use regression models | 23,425 | 943 | Preeclampsia | NO_2_ | Trimester 3 | 1.30 (1.07, 1.58) | Per 16.64 ppb* (31.28 µg/m^3^) | 22.54 (9.87) ppb [42.38 (18.6) µg/m^3^] | Maternal age, pre-gestational and gestational diabetes, aboriginal status, parity, season of conception, smoking, area socioeconomic status
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 4,226 | Severe preeclampsia | NO_2_ | Trimester 1 | 0.96 (0.90, 1.0) | Per 10 ppb (18.8 µg/m^3^) | 27.8 (6.2) ppb [52.26 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 4,226 | Severe preeclampsia | NO_2_ | Trimester 2 | 0.93 (0.87, 0.99) | Per 10 ppb (18.8 µg/m^3^) | 27.0 (6.2) ppb [50.76 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 6,940 | Mild preeclampsia | NO_2_ | Trimester 1 | 0.89 (0.84, 0.93) | Per 10 ppb (18.8 µg/m^3^) | 27.8 (6.2) ppb [52.26 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 6,940 | Mild preeclampsia | NO_2_ | Trimester 2 | 0.94 (0.89, 0.99) | Per 10 ppb (18.8 µg/m^3^) | 27.0 (6.2) ppb [50.76 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 5,834 | Gestational hypertension | NO_2_ | Trimester 1 | 0.95 (0.90, 1.0) | Per 10 ppb (18.8 µg/m^3^) | 27.8 (6.2) ppb [52.26 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 5,834 | Gestational hypertension | NO_2_ | Trimester 2 | 1.0 (0.95, 1.1) | Per 10 ppb (18.8 µg/m^3^) | 27.0 (6.2) ppb [50.76 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 17,000 | Total Hypertensive Disorders | NO_2_ | Trimester 1 | 0.93 (0.90, 0.96) | Per 10 ppb (18.8 µg/m^3^) | 27.8 (6.2) ppb [52.26 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) Land use regression models | 268,601 | 17,000 | Total Hypertensive Disorders | NO_2_ | Trimester 2 | 0.96 (0.93, 0.99) | Per 10 ppb (18.8 µg/m^3^) | 27.0 (6.2) ppb [50.76 (11.7) µg/m^3^] | Maternal age, parity, race/ethnicity, conception year, education, BMI, BMI^2^, Medicaid status, social deprivation index, hospital of delivery
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 250 | Preeclampsia | NO_2_ | Full gestational period | 1.23 (0.75, 2.02) | Per 10 µg/m^3^ | 39.9 (4.2) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 141 | Pregnancy-induced hypertension | NO_2_ | Full gestational period | 1.21 (0.83, 1.77) | Per 10 µg/m^3^ | 39.9 (4.2) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 4,853^b^ | Diastolic blood pressure | NO_2_ | Trimester 1 | 0.35 (−0.15, 0.86)^c^ | Per 10 µg/m^3^ | 40.5 (5.4) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 6,361^b^ | Diastolic blood pressure | NO_2_ | Trimester 2 | 0.37 (−0.11, 0.85)^c^ | Per 10 µg/m^3^ | 40.3 (5.0) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 6,488^b^ | Diastolic blood pressure | NO_2_ | Trimester 3 | −0.05 (−0.59, 0.50)^c^ | Per 10 µg/m^3^ | 40.0 (4.5) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 4,853^b^ | Systolic blood pressure | NO_2_ | Trimester 1 | 1.19 (0.54, 1.83)^c^ | Per 10 µg/m^3^ | 40.5 (5.4) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 6,361^b^ | Systolic blood pressure | NO_2_ | Trimester 2 | 1.35 (0.76, 1.95)^c^ | Per 10 µg/m^3^ | 40.3 (5.0) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) Dispersion Models | 7,006 | 6,488^b^ | Systolic blood pressure | NO_2_ | Trimester 3 | 0.73 (0.04, 1.41)^c^ | Per 10 µg/m^3^ | 40.0 (4.5) µg/m^3^ | Maternal age, height, weight, ethnicity, education, parity, gestational age, folic acid supplementation, smoking, alcohol use, road traffic noise exposure
Wu et al. (2011) | Retrospective cohort (Los Angeles County, USA) Land use regression (NO_2_); CALINE 4 dispersion models (NO_X_) | 38,709 | 1,303 | Preeclampsia | NO_2_ | Full gestational period | 1.12 (1.02, 1.23) | Per 5.1 ppb (9.59 µg/m^3^) | 28.6 (6.0) ppb [53.77 (11.3) µg/m^3^] | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception
Wu et al. (2011) | Retrospective cohort (Los Angeles County, USA) Land use regression (NO_2_); CALINE 4 dispersion models (NO_X_) | 38,709 | 1,303 | Preeclampsia | NO_x_ | Full gestational period | 1.08 (1.02, 1.15) | Per 5.6 ppb* (10.53 µg/m^3^) | 8.9 (4.9) ppb [16.73 (9.2) µg/m^3^] | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception
Wu et al. (2011) | Retrospective cohort (Orange County, USA) Land use regression (NO_2_); CALINE 4 dispersion models (NO_x_) | 42,277 | 1,139 | Preeclampsia | NO_2_ | Full gestational period | 1.01 (0.93, 1.10) | Per 5.1 ppb* (9.59 µg/m^3^) | 27.5 (7.7) ppb [51.70 (14.8) µg/m^3^] | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception
Wu et al. (2011) | Retrospective cohort (Orange County, USA) Land use regression (NO_2_); CALINE 4 dispersion models (NO_x_) | 42,277 | 1,139 | Preeclampsia | NO_x_ | Full gestational period | 1.08 (1.01, 1.16) | Per 5.6 ppb* (10.53 µg/m^3^) | 5.7 (5.0) ppb [10.72 (9.4) µg/m^3^] | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception

* Effect estimates marked with an asterisk were reported per interquartile range increase in NO_x_ or NO_2_.

^a^ Dadvand et al. (2013), Malmqvist et al. (2013), and Pedersen et al. (2017) reported median (IQR) levels of NO_2_ and NO_x_.

^b^ Blood pressure case sample size reflects the number of women who had blood pressure measurements taken.

^c^ van den Hooven et al. (2011) reported results for blood pressure as regression coefficients rather than odds ratios.

With the exception of the Olsson et al. (2015) study, which evaluated only combined hypertensive disorders of pregnancy, preeclampsia was the primary outcome in every study. In addition to preeclampsia, four studies assessed gestational hypertension (Madsen et al. 2018; Pedersen et al. 2017; Savitz et al. 2015; van den Hooven et al. 2011) and one study evaluated changes in blood pressure (van den Hooven et al. 2011).

##### Summary of the Human Evidence and Meta-analyses

The human evidence evaluating the associations between hypertensive disorders of pregnancy and NO_2_ or NO_x_ generally reported slight but significant increased risk for developing preeclampsia or hypertensive disorders of pregnancy with increasing concentrations of NO_2_ or combined NO_x_ exposures. Slight negative associations were reported between exposure to relatively low levels of NO_2_ during the full gestational period and preeclampsia and gestational hypertension (Madsen et al. 2018) and between first and second trimester NO_2_ exposures and hypertensive disorders of pregnancy (after adjusting for the delivery hospital [Savitz et al. (2015)]). NO_2_ or NO_x_ exposures that were estimated using air dispersion models were between 10.7 and 16.7 µg/m^3^ for most studies (Malmqvist et al. 2013; Olsson et al. 2015; Pedersen et al. 2017; Wu et al. 2011), but the highest concentration (40 µg/m^3^) was reported by van den Hooven et al. (2011). Estimates of NO_2_ concentrations using LUR models ranged from 43.3–55.7 µg/m^3^ (Dadvand et al. 2013; Pereira et al. 2013; Savitz et al. 2015; Wu et al. 2011). Lower concentrations (13.6 µg/m^3^) were reported by Madsen et al. (2018), which may have contributed to the lack of an association observed between NO_2_ exposure and hypertensive disorders of pregnancy. Only one study estimated NO_x_ concentrations using LUR (2013), and those concentrations (105.3–107.8 µg/m^3^) were higher than those estimated using air dispersion models. Multiple studies evaluated trimester-specific exposures in addition to the entire pregnancy period (Dadvand et al. 2013; Malmqvist et al. 2013; Olsson et al. 2015; Pereira et al. 2013; Savitz et al. 2015; van den Hooven et al. 2011), and positive associations were reported for most trimester exposure windows and hypertensive disorders of pregnancy, although some did not reach statistical significance for some outcomes. Third trimester exposures were also positively associated with hypertensive disorders of pregnancy and, in some cases (e.g., for preeclampsia or severe preeclampsia), were more strongly correlated than first trimester exposures (Malmqvist et al. 2013; Pereira et al. 2013). These correlations may reflect different mechanisms of action for NO_x_ exposure on the pathogenesis of hypertension during pregnancy, but additional studies would be needed to support this assertion. Most studies evaluated preeclampsia (and various subcategories of preeclampsia) or combined hypertensive disorders of pregnancy, but one study found a statistically significant positive association between NO_x_ exposures and systolic blood pressure, particularly in the first trimester. However, the evidence from a single study is inadequate to draw conclusions on associations between systolic and/or diastolic blood pressures and hypertensive disorders of pregnancy following NO_x_ exposure. There were also limited data to determine if associations between NO_2_ or NO_x_ concentrations were more strongly correlated with subcategories of preeclampsia (e.g., mild versus severe, early onset versus late onset).

Correlations across exposures were the highest between NO_x_ and NO_2_ and were generally low to moderate for other pollutants when reported (although the majority of studies used single-pollutant models). The data were sufficient to evaluate the effects of NO_2_ exposure on hypertensive disorders of pregnancy using meta-analyses (Table 10). The analyses evaluated associations between traffic-related NO_2_ exposures during the full gestational period and (1) preeclampsia and (2) combined hypertensive disorders of pregnancy.

Table 10 References Included in Meta-analysis: Studies on Hypertensive Disorders of Pregnancy with TRAP-related NO_2_ Exposure in Humans

Study | Study Design (Location) | Sample Size | Cases Included in Analysis | Outcome | Exposure | Exposure Period | OR (95% CI)* | Mean (SD)^a^ Exposure Levels | Covariates Included in Final Model
Dadvand et al. (2013) | Retrospective cohort (Barcelona, Spain) | 8,398 | 103 | Preeclampsia | NO_2_ | Full gestational period | 1.04 (0.89, 1.23) | 55.7 (19.7) µg/m^3^ | Maternal age, ethnicity, education, smoking, alcohol use, BMI, marital status, pre-gestational/ gestational diabetes, parity, multiple pregnancy, neighborhood socioeconomic status, season of conception, year of conception
Madsen et al. (2018) | Prospective cohort (Norway) | 17,533 | 526 | Preeclampsia | NO_2_ | Full gestational period | 0.89 (0.74, 1.08) | 13.6 (6.9) µg/m^3^ | Maternal age, BMI, diabetes, chronic hypertension, education, marital status, parity, smoking, area, season, and year of birth
Madsen et al. (2018) | Prospective cohort (Norway) | 17,533 | 841 | Hypertension during pregnancy | NO_2_ | Full gestational period | 0.91 (0.78, 1.06) | 13.6 (6.9) µg/m^3^ | Maternal age, BMI, diabetes, chronic hypertension, education, marital status, parity, smoking, area, season, and year of birth
Madsen et al. (2018) | Prospective cohort (Norway) | 17,533 | 1,367 | Combined hypertensive disorders of pregnancy | NO_2_ | Full gestational period | 0.90 (0.80, 1.02)^b^ | 13.6 (6.9) µg/m^3^ | Maternal age, BMI, diabetes, chronic hypertension, education, marital status, parity, smoking, area, season, and year of birth
Pedersen et al. (2017) | Prospective cohort (Denmark) | 72,745 | 1,880 | Preeclampsia (all cases) | NO_2_ | Full gestational period | 1.08 (1.01, 1.15) | 11.5 (6.7) µg/m^3^ | Maternal age, parity, BMI, height, household income, education, season of conception, traffic noise
Pedersen et al. (2017) | Prospective cohort (Denmark) | 72,745 | 765 | Gestational hypertension | NO_2_ | Full gestational period | 1.01 (0.91, 1.13) | 11.5 (6.7) µg/m^3^ | Maternal age, parity, BMI, height, household income, education, season of conception, traffic noise
Pedersen et al. (2017) | Prospective cohort (Denmark) | 72,745 | 2,430 | Combined hypertensive disorders of pregnancy | NO_2_ | Full gestational period | 1.07 (1.01, 1.14)^c^ | 11.5 (6.7) µg/m^3^ | Maternal age, parity, BMI, height, household income, education, season of conception, traffic noise
Pereira et al. (2013) | Retrospective cohort (Perth, Australia) | 23,452 | 943 | Preeclampsia | NO_2_ | Full gestational period | 1.11 (0.99, 1.25) | 23.04 (4.14) ppb [43.32 (7.8) µg/m^3^] | Maternal age, diabetes, aboriginal status, parity, season of conception, smoking, area socioeconomic status
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 4,226 | Severe preeclampsia | NO_2_ | Trimesters 1, 2 | 0.97 (0.94, 1.01) | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, and hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 6,940 | Mild preeclampsia | NO_2_ | Trimesters 1, 2 | 0.95 (0.92, 0.98) | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, and hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 11,166 | Combined mild and severe preeclampsia | NO_2_ | Trimesters 1, 2 | 0.96 (0.94, 0.98)^d^ | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, and hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 5,834 | Gestational hypertension | NO_2_ | Trimesters 1, 2 | 0.98 (0.94, 1.02) | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, and hospital of delivery
Savitz et al. (2015) | Retrospective cohort (New York City, USA) | 268,601 | 17,000 | Combined hypertensive disorders of pregnancy | NO_2_ | Trimesters 1, 2 | 0.96 (0.95, 0.98)^f^ | Pooled mean not reported^c^ | Maternal age, ethnicity, education, Medicaid status, parity, conception year, social deprivation index, BMI, BMI^2^, and hospital of delivery
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) | 6,518 | 250 | Preeclampsia | NO_2_ | Full gestational period | 1.23 (0.75, 2.02) | 39.9 (4.2) µg/m^3^ | Maternal age, height, weight, parity, ethnicity, education, folic acid supplementation, smoking, alcohol use, gestational age, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) | 6,626 | 141 | Pregnancy-induced hypertension | NO_2_ | Full gestational period | 1.21 (0.83, 1.77) | 39.9 (4.2) µg/m^3^ | Maternal age, height, weight, parity, ethnicity, education, folic acid supplementation, smoking, alcohol use, gestational age, road traffic noise exposure
van den Hooven et al. (2011) | Prospective cohort (Rotterdam, Netherlands) | 6,626 | 391 | Combined hypertensive disorders of pregnancy | NO_2_ | Full gestational period | 1.22 (0.90, 1.65)^g^ | 39.9 (4.2) µg/m^3^ | Maternal age, height, weight, parity, ethnicity, education, folic acid supplementation, smoking, alcohol use, gestational age, road traffic noise exposure
Wu et al. (2011) ^i^ | Retrospective cohort (Los Angeles County, USA) | Not reported^h^ | 1,303 | Preeclampsia | NO_2_ | Full gestational period | 1.13 (1.01, 1.25) | 28.6 (6.0) ppb [53.77 (11.3) µg/m^3^] | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception
Wu et al. (2011) ^i^ | Retrospective cohort (Orange County, USA) | Not reported^h^ | 1,139 | Preeclampsia | NO_2_ | Full gestational period | 1.01 (0.93, 1.10) | 27.5 (7.7) ppb [51.7 (14.5) µg/m^3^] | Maternal age, race/ethnicity, parity, diabetes, prenatal care insurance type, poverty, season of conception

* All ORs were converted to a 10 µg/m^3^ increase before analysis. The numbers in parentheses were calculated by the authors of monograph.

^a^ Dadvand et al. (2013) and Pedersen et al. (2017) reported median (IQR) levels of NO_2_ and NO_x_.

^b^ This effect estimate was calculated by combining the preeclampsia and hypertensive during pregnancy values that were reported by Madsen et al. (2018).

^c^ This effect estimate was calculated by combining the preeclampsia (all cases) and gestational hypertension values that were reported by Pedersen et al. (2017).

^d^ This effect estimate was calculated by combining the severe and mild preeclampsia values that were reported by Savitz et al. (2015).

^e^ Savitz et al. (2015) reported mean NO_2_ exposures for trimester 1 and trimester 2 separately.

^f^ This effect estimate was calculated by combining the severe preeclampsia, mild preeclampsia, and gestational hypertension values that were reported by Savitz et al. (2015).

^g^ This effect estimate was calculated by combining the preeclampsia and pregnancy-induced hypertension values that were reported by van den Hooven et al. (2011).

^h^ Not reported = The overall number of participants included in each analysis was not reported by county. The adjusted NO_2_ LUR model includes 81,186 subjects total, and the NO_x_.

^i^ CALINE4 model included 79,629 individuals total.

Four studies (Madsen et al. 2018; Pedersen et al. 2017; Savitz et al. 2015; van den Hooven et al. 2011) reported both gestational hypertension and preeclampsia as separate effect estimates; those risk estimates were first combined for each study, and the pooled estimates from each study were included in the combined hypertensive disorders of pregnancy meta-analysis. As discussed for the PM analysis, Wu et al. (2011) evaluated two cohorts, and risk estimates from each these groups were treated as independent effects. Savitz et al. (2015) reported risk estimates for trimesters 1 and 2 for mild and severe preeclampsia. These were pooled into one risk for trimesters 1 and 2 for preeclampsia combined. Because Savitz et al. (2015) reported exposure windows other than the entire pregnancy period, sensitivity analyses were performed with and without this study.

Six studies reported effects following exposure to NO_2_ over the full gestational period, and all of those studies reported preeclampsia as the outcome. In addition to preeclampsia, three studies (Pedersen et al. 2017; Savitz et al. 2015; van den Hooven et al. 2011) reported gestational hypertension. Together with the two separate risk estimates reported by Wu et al. (2011), a total of eight results were included in the combined hypertensive disorders of pregnancy meta-analysis (Table 11; Figure 13). Eight results were included in the preeclampsia-only meta-analysis (Table 11; Figure 14).

Table 11 Pooled ORs and 95% CIs for Full Gestational Period TRAP-related NO_2_ Exposures and Hypertensive Disorders of Pregnancy

Outcome | Number of Results | OR (95% CI) per 10 µg/m^3^ increase | Heterogeneity
Outcome | Number of Results | OR (95% CI) per 10 µg/m^3^ increase | P Value* | I^2^
Hypertensive Disorders of Pregnancy^a,b^ | 8 | 1.03 (0.97, 1.09) | <0.001 | 74%
Preeclampsia^c^ | 8 | 1.04 (0.97, 1.10) | 0.001 | 73%
Hypertensive Disorders of Pregnancy^a^ [excluding Savitz et al. (2015)] | 7 | 1.05 (1.01, 1.09) | 0.085 | 46%
Preeclampsia^d^ [excluding Savitz et al. (2015)] | 7 | 1.06 (1.02, 1.11) | 0.299 | 17%

* P value for test for heterogeneity. When significant (p < 0.05), the random-effects model results are presented. When nonsignificant, the random-effects model results are identical to the fixed-effects model results.

^a^ Four studies (Madsen et al. 2018; Pedersen et al. 2017; van den Hooven et al. 2011; Wu et al. 2011) contributed two effect estimates each to the analysis.

^b^ One study (Savitz et al. 2015) contributed three effect estimates to the analysis.

^c^ Two studies (Savitz et al. 2015; Wu et al. 2011) contributed two effect estimates each to the analysis.

^d^ One study (Wu et al. 2011) contributed two effect estimates to the analysis.

Figure 13

Full Gestation Exposure to NO_2_ and Hypertensive Disorders of Pregnancy^a^

When I^2^ p value is significant (p < 0.05), the random-effects model results are presented. When nonsignificant, the random-effects model results are identical to the fixed-effects model results.

HDP = hypertensive disorders of pregnancy.

^a^All ORs were converted to a 10 µg/m^3^ increase before analysis.

The available evidence indicates that the summary risk estimates from this meta-analysis were 1.03 (95% CI: 0.97, 1.09) and 1.04 (95% CI: 0.97, 1.10) for the associations between exposure to traffic-related NO_2_ and combined hypertensive disorders of pregnancy (Table 11; Figure 13) and preeclampsia only (Table 11; Figure 14), respectively. The summary risk estimate was 1.06 (95% CI: 0.98, 1.14) for the association between traffic-related NO_x_ and preeclampsia only (Figure 15). For both combined hypertensive disorders of pregnancy and preeclampsia-only analyses, there was moderate heterogeneity among the studies, and an influence analysis revealed that no single study influenced either meta-analysis to a large degree (Table E-3; Table E-4; Figure E-3; Figure E-4). A formal test for publication bias revealed no evidence of publication bias (p-values = 0.068, and 0.089, respectively) in the meta-analyses (Table E-5; Table E-6; Figure E-5; Figure E-6).

Figure 15

Full Gestation Exposure to NO_x_ and Preeclampsia^a^

When I^2^ p value is significant (p < 0.05), the random-effects model results are presented. When nonsignificant, the random-effects model results are identical to the fixed-effects model results.

^a^All ORs were converted to a 10 µg/m^3^ increase before analysis.

##### Risk-of-bias Considerations

The NO_2_ and NO_x_ studies were generally rated probably low or definitely low across all risk-of-bias domains, including the key risk-of-bias questions, as shown in the risk-of-bias heatmap (Figure 16) and bar chart (Figure 17). Therefore, confidence in the body of evidence for NO_2_ and NO_x_ was not changed for risk of bias. The key risk-of-bias considerations are discussed below, and the study-specific rating details can be found in HAWC (https://hawcproject.org/assessment/60/) (NTP 2019a).

Figure 16

Risk-of-bias Heatmap: NO_x_ and Hypertensive Disorders of Pregnancy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for human epidemiological studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure 17

Risk-of-bias Bar Chart: NO_x_ and Hypertensive Disorders of Pregnancy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for human epidemiological studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

###### Exposure Characterization

Overall, the exposure measurements were well characterized for the assessment of NO_2_ and NO_x_. Most studies utilized LUR models or air dispersion-based models that used dense monitoring networks to allow for high temporal and spatial resolution. There was reasonable alignment between the exposure and outcome data, and appropriate adjustments were made to account for temporal trends in pollutants between the monitoring period and the study period. Residential mobility information was included in four studies (Madsen et al. 2018; Malmqvist et al. 2013; Pedersen et al. 2017; Pereira et al. 2013) and, of those, the three that performed sub-analyses (Madsen et al. 2018; Pedersen et al. 2017; Pereira et al. 2013) found slightly stronger associations between NO_2_ or NO_x_ exposures and hypertensive disorders of pregnancy in nonmovers compared with those who had moved to a different location during pregnancy. The other studies included in these analyses did not account for residential mobility, and there may be some exposure misclassification as a result. In addition, the LUR model used in the Wu et al. (2011) study was developed based on data from Los Angeles, but the model was used to estimate NO_2_ concentrations in both Los Angeles and Orange Counties. Consequently, there might be exposure misclassification in the Orange County study which may contribute to the lack of statistical significance between NO_2_ exposure and preeclampsia for this cohort. There were no other concerns about exposure characterization in the body of evidence for NO_2_ or NO_x_ exposures.

###### Outcome Assessment

As discussed in the PM_2.5_ section, chronic hypertension was usually excluded from the analyses by the study authors, but this is difficult to do with certainty, and outcome misclassification is likely to occur in the “noncases,” resulting in bias for the effect estimates toward the null. In addition, the apparent effect of the delivery hospital on associations between NO_2_ exposure and hypertensive disorders of pregnancy is not entirely clear but may reflect differences in coding of hypertensive disorders of pregnancy across hospitals. As indicated in the PM_2.5_ section, the additional adjustment for delivery hospital is likely not necessary when evaluating severe preeclampsia or combined hypertensive disorders of pregnancy because outcome misclassification is less of a concern in these analyses. Estimates using fully adjusted models (including delivery hospital) were included in the meta-analyses and contributed over 20% to the overall effect estimate. Because the standard adjusted models showed positive associations for several outcomes, the overall effect size would be slightly larger (and would have reached statistical significance) if those estimates were included in the meta-analyses.

###### Confounding and Modifying Variables

Potential confounders are provided in tables for this report. All of the studies considered the standard covariates that are thought to be associated with hypertensive disorders of pregnancy (e.g., maternal age, race/ethnicity, socioeconomic status [SES]). Most studies adjusted for smoking and BMI, and the few studies that did not make those adjustments could have biased the results in opposing directions; however, given the consistency of the data and the fact that no single study significantly influenced the meta-analyses, these studies did not affect the overall confidence in the conclusions. There were no concerns over the internal validity or other factors that would increase or decrease the confidence in the body of evidence.

###### Summary

The few risk-of-bias concerns within the same studies potentially biased the results toward and away from the null. Given the general consistency of effects across studies despite the different directions of bias, the results support the likelihood of a true association between exposure to NO_x_ during pregnancy and hypertensive disorders of pregnancy. For all remaining risk-of-bias questions in all other individual studies that evaluated NO_x_, there was low risk of bias and, thus, no major concerns over the internal validity of the reported results that would decrease the overall confidence in the body of evidence.

#### Experimental Animal Studies for NO_2_ or NO_x_

There were no animal data evaluating associations between NO_2_ or NO_x_ exposures and hypertensive disorders of pregnancy that met the PECO criteria for this assessment.

#### Evidence Synthesis for Studies of NO_2_ or NO_x_

Traffic-related NO_2_ or NO_x_ exposures are consistently associated with increased risk of hypertensive disorders of pregnancy in the available human studies. Because NO_2_ is a better indicator of anthropogenic NO_x_ contributions, the hazard conclusions are based on the NO_2_ data. There is moderate confidence in the body of evidence that exposure to traffic-related NO_2_ during the entire gestation period is associated with an increased risk for hypertensive disorders of pregnancy. The effect estimate for the main meta-analysis is 1.03 (95% CI: 0.97, 1.09) for risk of hypertensive disorders of pregnancy during the full gestation NO_2_ exposure. No animal studies were identified. The confidence ratings are summarized below.

- Human body of evidence: Moderate confidence
- Animal body of evidence: No studies

The human body of evidence presents a consistent pattern of findings that exposure to higher levels of traffic-related NO_2_ or NO_x_ is associated with the development of hypertensive disorders of pregnancy and supports a moderate confidence rating.

### Other Pollutants and Hypertensive Disorders of Pregnancy

Three additional TRAP components were identified in the literature that met the inclusion criteria: carbon monoxide (CO), elemental carbon (EC), and black carbon (BC). CO is produced in the incomplete combustion of carbon-containing fuels, and vehicle emissions represent the largest anthropogenic source of CO in the United States. EC that is attributable to traffic (ECAT) is generated from traffic-related diesel combustion. BC is a component of fine PM consisting of several linked forms of pure carbon and is formed through the incomplete combustion of a variety of sources, including fossil fuels, biofuels, and biomass. The available evidence for these exposures was limited: Three studies evaluated carbon monoxide, two studies evaluated BC, and one study evaluated EC. The studies evaluated associations between these exposures and preeclampsia, gestational hypertension, combined hypertensive disorders of pregnancy, or blood pressure changes.

#### Human and Experimental Animal Health Effects for CO, ECAT, and BC

##### Summary

There were too few studies to conduct a full evaluation on these bodies of evidence for either CO, ECAT, or BC. The following section describes the available evidence for all three TRAP components (Table 12; Table 13).

Table 12 Studies on Hypertensive Disorders of Pregnancy with TRAP-related CO, ECAT, and BC Exposure in Humans

Study | Study Design (Location) Exposure Measure | Outcome | Exposure | Exposure Period | Sample Size | Cases | OR (95% CI) | Unit Increase | Mean (SD)^a^ Exposure Level | Covariates Considered for Inclusion
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 1 | 4,726 | 387 | 1.03 (0.90–1.17) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^ | Parity, multi-fetal gestation, pre-pregnancy diabetes, gestational diabetes, maternal age, race/ethnicity, education, paternity acknowledgement, BMI, year and season of conception, birth hospital, prenatal care received, trimester prenatal care began, Medicaid-funded delivery, smoking, alcohol consumption, average relative humidity, average relative temperature
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 2 | 5,069 | 401 | 1.07 (0.94–1.23) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 3 | 5,261 | 402 | 1.12 (0.98–1.28) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 4 | 5,246 | 403 | 0.97 (0.85–1.12) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 5 | 5,224 | 407 | 1.04 (0.91–1.19) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 6 | 5,017 | 394 | 1.05 (0.91–1.20) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 7 | 4,688 | 375 | 1.12 (0.96–1.29) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 8 | 4,327 | 339 | 1.04 (0.89–1.21) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Assibey-Mensah et al. (2019) | Retrospective cohort (Monroe County, New York, USA) Land use regression models | Hypertensive disorders of pregnancy | Black carbon | Month 9 | 3,777 | 267 | 0.89 (0.74–1.06) | Per 0.86 µg/m^3*^ | 1.14 (0.75) µg/m^3b^
Choe et al. (2018) | Retrospective cohort (Rhode Island) Land use regression models | Preeclampsia | Black carbon | Trimester 1 | 61,640 | 2,221 | 0.98 (0.92–1.06) | Per 0.13 µg/m^3^ | 0.5 (0.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island) Land use regression models | Preeclampsia | Black carbon | Trimester 2 | 61,640 | 2,221 | 1.03 (0.95–1.10) | Undefined IQR increase | 0.5 (0.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island) Land use regression models | Preeclampsia | Black carbon | Trimester 3 | 61,640 | 2,221 | 0.94 (0.88–1.01) | Undefined IQR increase | 0.5 (0.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island) Land use regression models | Gestational hypertension | Black carbon | Trimester 1 | 61,640 | 2,877 | 0.95 (0.89–1.01) | Per 0.13 µg/m^3^ | 0.5 (0.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island) Land use regression models | Gestational hypertension | Black carbon | Trimester 2 | 61,640 | 2,877 | 0.97 (0.91–1.04) | Undefined IQR increase | 0.5 (0.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Choe et al. (2018) | Retrospective cohort (Rhode Island) Land use regression models | Gestational hypertension | Black carbon | Trimester 3 | 61,640 | 2,877 | 0.95 (0.90–1.01) | Undefined IQR increase | 0.5 (0.1) µg/m^3^ | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, neighborhood socioeconomic status, year of last menstrual period
Rudra et al. (2011) | Prospective cohort (Western Washington, USA) Land use regression models | Preeclampsia | Carbon monoxide | Periconceptional^c^ | 3,675 | 117 | 0.98 (0.91–1.06) | Per 0.1 ppm | 0.80 (0.43) ppm | Maternal age, nulliparity, BMI, race/ethnicity, education, marital status, smoking, household income, employment in early pregnancy, pre-pregnancy secondhand smoke, physical activity, history of asthma, diabetes, chronic hypertension, year, and month of conception
Sears et al. (2018) | Prospective cohort (Cincinnati, Ohio, USA) Land use regression models | Hypertensive disorders of pregnancy | Elemental carbon attributable to traffic | Full gestational period | 370 | 35 | 0.7 (0.5–1.2) | Per 0.16 µg/m^3^ | 0.37 (0.16) µg/m^3^ | Maternal age, race, education, marital status, tobacco smoke exposure, BMI, parity, income, gestational age, exposure to traffic noise, season of conception, neighborhood socioeconomic status
Wu et al. (2011) | Retrospective cohort (Los Angeles County, USA) CALINE 4 air dispersion models | Preeclampsia | Carbon monoxide | Full gestational period | 38,709 | 1,303 | 1.11 (1.03–1.19) | Per 0.4 ppm | 0.9 (0.4) ppm | Maternal age, race/ethnicity, parity, prenatal care insurance type, season of conception, diabetes, poverty
Wu et al. (2011) | Retrospective cohort (Orange County, USA) CALINE 4 air dispersion models | Preeclampsia | Carbon monoxide | Full gestational period | 42,477 | 1,139 | 0.97 (0.87–1.09) | Per 0.4 ppm | 0.6 (0.3) ppm | Maternal age, race/ethnicity, parity, prenatal care insurance type, season of conception, diabetes, poverty

* Effect estimates marked with an asterisk were reported per interquartile range increase.

^a^ Rudra et al. (2011) and Sears et al. (2018) reported median (IQR) levels of elemental carbon attributable to traffic.

^b^ Assibey-Mensah et al. (2019) reported mean (SD) values for gestational month 1 only.

^c^ Rudra et al. (2011) defined the periconceptional period as the 7 months surrounding conception.

Table 13 Studies on Hypertensive Disorders of Pregnancy with TRAP-related CO, ECAT, and BC Exposure in Animals

Study | Species/ Strain | Sample Size | Exposure | Dose Level | Dose Duration | Groups | Endpoints Measured | Findings
Venditti et al. (2014) | Pregnant female CD-1 mice | 6/group | Ambient carbon monoxide | 250 ppm | Gestational day 10.5–15.5 | Untreated Control ± CO | Proteinuria | No significant difference in proteinuria between unexposed control and control+CO groups
Venditti et al. (2014) | Pregnant female CD-1 mice | 6/group | Ambient carbon monoxide | 250 ppm | Gestational day 10.5–15.5 | Untreated Control ± CO | Systolic blood pressure | No significant difference in systolic blood pressure between control and control+CO groups
Venditti et al. (2014) | Pregnant female CD-1 mice | 12–18/group | Ambient carbon monoxide | 250 ppm | Gestational day 10.5–15.5 | AdsFlt-1-induced preeclampsia (hypertension and proteinuria) ± CO | Proteinuria | Significant increase in proteinuria in the AdsFlt-1-induced unexposed group compared with the AdsFlt-1+CO group
Venditti et al. (2014) | Pregnant female CD-1 mice | 12–18/group | Ambient carbon monoxide | 250 ppm | Gestational day 10.5–15.5 | AdsFlt-1-induced preeclampsia (hypertension and proteinuria) ± CO | Systolic blood pressure | Significant increase in systolic blood pressure in the AdsFlt-1-induced unexposed group compared with the AdsFlt-1+CO group
Venditti et al. (2014) | Pregnant female CD-1 mice | 7–9/group | Ambient carbon monoxide | 250 ppm | Gestational day 10.5–15.5 | AdEV ± CO | Proteinuria | No significant difference in proteinuria between unexposed AdEV and AdEV+CO groups
Venditti et al. (2014) | Pregnant female CD-1 mice | 7–9/group | Ambient carbon monoxide | 250 ppm | Gestational day 10.5–15.5 | AdEV ± CO | Systolic blood pressure | No significant difference in systolic blood pressure between unexposed AdEV and AdEV+CO groups

AdsFlt = fms-like tyrosine kinase-1 Adenovirus encoding vector.

AdEV = Ad Empty Vector control.

##### Overview of Available Data and Summary of Carbon Monoxide, Elemental Carbon Attributable to Traffic, and Black Carbon Findings

Two human studies (three cohorts) and one animal study in the body of evidence evaluated the association between exposure to CO and health outcomes of interest. The human studies (Rudra et al. 2011; Wu et al. 2011) were conducted in the United States and evaluated preeclampsia. The single animal study measured changes in blood pressure in mice (Venditti et al. 2014). The data from the human studies are inadequate to evaluate whether exposure to CO is related to hypertension in pregnancy due to the paucity of studies and inconclusive findings across studies. Wu et al. (2011) reported a positive association for CO exposure measured by monitors and preeclampsia in the Los Angeles County cohort (OR: 1.11, 95% CI: 1.03, 1.91 per IQR increase); however, the OR was close to unity in the Orange County cohort. In a study in Washington State, no association was found between predicted periconceptional CO exposure and preeclampsia in a statistical model that adjusted for year of conception, although a positive association was found using a statistical model adjusting for other factors but not year of conception (OR: 0.98, 95% CI: 0.91, 1.06 per 0.1 CO ppm increase) (Rudra et al. (2011)). It is unclear whether adjusting for conception year was appropriate because both the incidence of preeclampsia and CO concentrations had decreased over time. The experimental animal study found decreased blood pressure following CO exposure in mice (Venditti et al. 2014), which is consistent with known vasodilatory effects of CO. However, it is important to note that the objective for that animal study was to determine the effectiveness of CO in decreasing blood pressure in a hypertensive pregnant mouse model rather than to determine if CO affected blood pressure in normotensive pregnant mice. The risk-of-bias ratings for the two human studies were generally rated probably low or definitely low risk of bias, and any potential threats to bias were unclear (likely directed toward and away from the null) (Figure D-2 and Figure D-4). The animal study was rated probably high risk of bias for five of the nine domains, although the exposure was well characterized (Figure D-1 and Figure D-3).

In addition to CO, one study conducted in Ohio evaluated associations between ECAT exposure and blood pressure or hypertensive disorders of pregnancy (Sears et al. 2018). Systolic blood pressure in late pregnancy was significantly associated with ECAT exposures; however, no significant associations were observed between ECAT and hypertensive disorders of pregnancy in the same study (Sears et al. 2018). Two U.S. studies (Assibey-Mensah et al. 2019; Choe et al. 2018) evaluated BC exposure and gestation hypertension, preeclampsia, or combined hypertensive disorders of pregnancy (Assibey-Mensah et al. 2019; Choe et al. 2018). No significant associations were found between exposure to BC and hypertensive disorders of pregnancy for two studies that evaluated these associations for each trimester (Assibey-Mensah et al. 2019; Choe et al. 2018) or gestational month (Assibey-Mensah et al. 2019). There were no major risk-of-bias concerns for most of the domains for these studies, although there was a probably high risk of bias for the exposure characterization in one study (Assibey-Mensah et al. 2019) because the monitoring network may not have been sufficiently dense for this evaluation. Overall, the data were inconsistent across studies, or the small number of studies precluded the ability to draw meaningful conclusions. As such, additional evaluation of this body of evidence was not conducted.

## Traffic Measures

Traffic measures are surrogate indicators of exposure to TRAP. Traffic measures may include distance to main road, length of main streets with a buffer zone around homes or schools, and traffic volume. These measurements are relatively easy to obtain and often involve use of GIS-based methods. One potential limitation of traffic measures is the lack of precision because often they do not account for meteorology, dispersion, and terrain (HEI 2010). However, information from studies evaluating associations between traffic measures and hypertensive disorders of pregnancy are still useful, particularly when evaluating potential effects of a combined TRAP exposure. Further, when considered with surrogates of traffic pollutants, traffic measures can strengthen the confidence in the body of evidence.

The following sections begin with a brief summary of the body of evidence followed by a narrative summary or meta-analysis of the human evidence and a confidence rating for the body of evidence. Because some studies evaluated multiple measures of TRAP, there are instances of overlap across studies.

### Traffic Measures and Hypertensive Disorders of Pregnancy

Traffic density (i.e., number of vehicles per day on a given stretch of roadway) and proximity to a major road were the two traffic measures that were reported in the available literature. For the analyses that follow, traffic density and proximity to a major road were evaluated separately and then combined as “traffic measures” to determine associations with hypertensive disorders of pregnancy.

#### Human Traffic Measures Data

##### Summary

There is low confidence in the body of evidence that combined traffic measures is associated with an increased risk for hypertensive disorders of pregnancy. The nine studies identified (six cohort studies, one cross-sectional study, and two case-control studies (Choe et al. 2018; Madsen et al. 2018; Malmqvist et al. 2013; Miranda et al. 2013; Olsson et al. 2015; van den Hooven et al. 2009; Wu et al. 2011; Wu et al. 2016; Yorifuji et al. 2015)) reported consistent evidence of an association between traffic density and proximity to a major road and the risk for hypertensive disorders of pregnancy. There were small but positive ORs reported for associations between hypertensive disorders of pregnancy and living in close proximity to a major road or near high-traffic density regions during the entire pregnancy period (Figure 18[REMOVED REF FIELD]). The initial confidence rating was moderate based on the six cohort studies included in the body of evidence that contained three out of four study design features (exposure prior to outcome, individual outcome data, comparison group used). The initial confidence was downgraded to low for imprecision because several studies reported positive but nonsignificant associations between hypertensive disorders of pregnancy and traffic measures. There were no other changes to the confidence rating after considering factors that may increase or decrease confidence.

Figure 18

Traffic Density and Hypertensive Disorders of Pregnancy

When I^2^ p value is significant (p < 0.05), the random-effects model results are presented. When nonsignificant, the random-effects model results are identical to the fixed-effects model results.

HDP = hypertensive disorders of pregnancy.

##### Overview of Available Human Data for Traffic Measures

Table 14 summarizes the available data in the human body of evidence that evaluated the associations between exposure to traffic measures and the health outcomes of interest. Nine studies were identified that reported associations between traffic measures and hypertensive disorders of pregnancy (Choe et al. 2018; Madsen et al. 2018; Malmqvist et al. 2013; Miranda et al. 2013; Olsson et al. 2015; van den Hooven et al. 2009; Wu et al. 2011; Wu et al. 2016; Yorifuji et al. 2015). The available evidence comprised four retrospective cohort studies (Choe et al. 2018; Olsson et al. 2015; Wu et al. 2011; Yorifuji et al. 2015), two prospective cohort studies (Madsen et al. 2018; van den Hooven et al. 2009), one cross-sectional study (Miranda et al. 2013), and two case-control studies (Malmqvist et al. 2013; Wu et al. 2016). Three studies were conducted in the United States (Choe et al. 2018; Miranda et al. 2013; Wu et al. 2011), one study was conducted in Japan (Yorifuji et al. 2015), and five studies were conducted in Europe.

Table 14 Studies on Hypertensive Disorders of Pregnancy and Traffic Measures in Humans

Study | Study Design (Location) | Sample Size | Cases | Traffic Measure | Outcome | Exposure Period | OR (95% CI) | Exposure Level | | Covariates Considered for Inclusion
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) | 61,541 | 2,221 | Proximity to road: living ≤150 m of an A1 or A2 roadway or ≤50 m of an A3 roadway | Preeclampsia | Full gestational period | 0.99 (0.87, 1.12) | 19.8% live within ≤150 m of an A1 or A2 roadway or ≤50 m of an A3 roadway | | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, year of last menstrual period, neighborhood socioeconomic status
Choe et al. (2018) | Retrospective cohort (Rhode Island, USA) | 57,793 | 2,877 | Proximity to road: living ≤150 m of an A1 or A2 roadway or ≤50 m of an A3 roadway | Gestational hypertension | Full gestational period | 0.97 (0.87, 1.09) | 19.8% live within ≤150 m of an A1 or A2 roadway or ≤50 m of an A3 roadway | | Maternal age, parity, race, education, marital status, health insurance status, tobacco use, year of last menstrual period, neighborhood socioeconomic status
Madsen et al. (2018) | Prospective cohort (Norway) | 17,533 | 590 | Proximity to road: road within 15 m | Preeclampsia | Full gestational period | 1.16 (0.96, 1.39) | 46.6% live within 15 m of a road | | Maternal age, marital status, education, BMI, parity, smoking, diabetes, chronic hypertension, child sex of child, area, year of birth
Madsen et al. (2018) | Prospective cohort (Norway) | 17,533 | 941 | Proximity to road: road within 15 m | Hypertension during pregnancy | Full gestational period | 1.12 (0.96, 1.29) | 46.6% live within 15 m of a road | | Maternal age, marital status, education, BMI, parity, smoking, diabetes, chronic hypertension, child sex of child, area, year of birth
Malmqvist et al. (2013) | Case-control (Sweden) | 81,110 | 2,323 | Traffic density: no road within 200 m (reference) versus road with >10 vehicles/min within 200 m | Preeclampsia (all cases) | Full gestational period | 1.10 (0.94, 1.30) | Summary measure not reported | | Maternal age, BMI, smoking, ethnicity, parity, type 1 diabetes, and gestational diabetes
Malmqvist et al. (2013) | Case-control (Sweden) | 81,110 | 1,799 | Traffic density: no road within 200 m (reference) versus road with >10 vehicles/min within 200 m | Mild preeclampsia | Full gestational period | 1.04 (0.86, 1.26) | Summary measure not reported | | Maternal age, BMI, smoking, ethnicity, parity, type 1 diabetes, and gestational diabetes
Malmqvist et al. (2013) | Case-control (Sweden) | 81,110 | 571 | Traffic density: no road within 200 m (reference) versus road with >10 vehicles/min within 200 m | Severe preeclampsia | Full gestational period | 1.24 (0.86, 1.77) | Summary measure not reported | | Maternal age, BMI, smoking, ethnicity, parity, type 1 diabetes, and gestational diabetes
Miranda et al. (2013) | Cross-sectional (North Carolina, USA) | 468,517 | 25,768 | Proximity to road: ≥500 m to major road (reference) vs. <250 m to major roads | Gestational hypertension | Full gestational period | 1.04 (1.00, 1.07) | 65.8% Live within ≥500 m of major roads 18.4% Live within <250 m of major roads | | Maternal age, race, nativity, education, marital status, parity, tobacco use, season of birth, tract-level urbanization, and tract-level median income
Olsson et al. (2015) | Retrospective cohort (Sweden) | 102,726 | 2,671 | Traffic density: per 3,672 vehicles/day increase within 100 m^2^ of home address | Pregnancy-induced hypertensive disorders | Full gestational period | 1.02 (1.00, 1.04) | Mean (SD) maximal traffic flow within 100 m^2^ of home address: 2,569 (7,712) vehicles/day | | Maternal age, education, region of origin, asthma, parity, date of conception, first trimester ozone, and first trimester temperature, smoking, BMI, family situation
van den Hooven et al. (2009) | Prospective cohort (Rotterdam, Netherlands) | 7,339 | 144 | Traffic density: <158,503 vehicles/day*m within 150 m (reference) versus >1,235,384 vehicles/day*m within 150 m | Preeclampsia | Full gestational period | 1.14 (0.71, 1.82) | Median traffic density: 550,000 vehicles/day*m | Maternal age, education, ethnicity, BMI, parity, smoking, alcohol use, and fetal sex
van den Hooven et al. (2009) | Prospective cohort (Rotterdam, Netherlands) | 7,339 | 250 | Traffic density: <158,503 vehicles/day*m within 150 m (reference) versus >1,235,384 vehicles/day*m within 150 m | Pregnancy-induced hypertension | Full gestational period | 1.07 (0.75, 1.53) | Median traffic density: 550,000 vehicles/day*m | Maternal age, education, ethnicity, BMI, parity, smoking, alcohol use, and fetal sex
van den Hooven et al. (2009) | Prospective cohort (Rotterdam, Netherlands) | 7,339 | 144 | Proximity to road: >200 m to major roads (reference) versus <50 m to major roads | Preeclampsia | Full gestational period | 1.03 (0.63, 1.69) | Median distance to major road: 143 m | Maternal age, education, ethnicity, BMI, parity, smoking, alcohol use, and fetal sex
van den Hooven et al. (2009) | Prospective cohort (Rotterdam, Netherlands) | 7,339 | 250 | Proximity to road: >200 m to major roads (reference) versus <50 m to major roads | Pregnancy-induced hypertension | Full gestational period | 1.08 (0.74, 1.60) | Median distance to major road: 143 m | Maternal age, education, ethnicity, BMI, parity, smoking, alcohol use, and fetal sex
Wu et al. (2011) | Retrospective cohort (Los Angeles County, California United States) | 38,709 | 1,303 | Traffic density: per 76.6 vehicles/day*m/m^2^ increase within 300 m | Preeclampsia | Full gestational period | 1.03 (0.99, 1.06) | Mean (SD) traffic density: 82.5 (114.2) vehicles/day*m/m^2^ | Maternal age, race/ethnicity, parity, prenatal care insurance type, season of conception, diabetes, and poverty
Wu et al. (2011) | Retrospective cohort (Orange County, California, United States) | 42,477 | 1,139 | Traffic density: per 76.6 vehicles/day*m/m^2^ increase within 300 m | Preeclampsia | Full gestational period | 1.03 (1.00, 1.07) | Mean (SD) traffic density: 66.0 (117.6) vehicles/day*m/m^2^ | Maternal age, race/ethnicity, parity, prenatal care insurance type, season of conception, diabetes, and poverty
Wu et al. (2016) | Case-control (Basel, Switzerland) | 100 | 50 | Traffic density: total length of major roads within 500 m | Preeclampsia | Full gestational period | Significant difference in median total length between cases (1,571 m) and controls (2,311 m) | Summary measure not reported | Maternal age
Wu et al. (2016) | Case-control (Basel, Switzerland) | 100 | 50 | Proximity to road: distance to nearest first-class main road | Preeclampsia | Full gestational period | No statistical difference between cases (114 m) and controls (160 m) | Summary measure not reported | Maternal age
Wu et al. (2016) | Case-control (Basel, Switzerland) | 100 | 50 | Proximity to road: distance to nearest freeway | Preeclampsia | Full gestational period | No statistical difference between cases (1,087 m) and controls (926 m) | Summary measure not reported | Maternal age
Yorifuji et al. (2015) | Retrospective cohort (Japan) | 19,077 | 630 | Proximity to road: >200 m to major roads (reference) vs. ≤200 m to major roads | Preeclampsia | Full gestational period | 1.3 (1.0, 1.8) | Summary measure not reported | Maternal age, occupation, smoking, BMI, area socioeconomic status, season, and year of conception

All but one study (Miranda et al. 2013) evaluated preeclampsia. Miranda et al. (2013) only assessed gestational hypertension, and van den Hooven et al. (2009) and Choe et al. (2018) assessed both gestational hypertension and preeclampsia. Five studies assessed traffic density as the exposure metric (Malmqvist et al. 2013; Olsson et al. 2015; van den Hooven et al. 2009; Wu et al. 2011; Wu et al. 2016) and five studies considered the proximity to major roadways (Choe et al. 2018; Madsen et al. 2018; Miranda et al. 2013; van den Hooven et al. 2009; Yorifuji et al. 2015). All included studies evaluated exposure over the entire gestational period. Sample sizes ranged from just over 7,300 to more than 460,000 women and included 50 to approximately 26,000 cases.

##### Summary of the Human Evidence

###### Traffic Density

In general, there were small but positive associations that did not reach statistical significance between traffic density measures and combined hypertensive disorders of pregnancy (Figure 18) or preeclampsia only (Figure 19). With the exception of van den Hooven et al. (2009), these studies also evaluated one or more traffic-related air pollutants. Although correlations between the air pollutants and traffic density were not discussed for most studies, Wu et al. (2011) found that traffic density measures were moderately correlated with CALINE4-modeled exposures and poorly correlated with ambient monitor-based measures. In all studies, ORs for traffic density and hypertensive disorders of pregnancy were smaller than those reported for the air pollutants (Malmqvist et al. 2013; Olsson et al. 2015; van den Hooven et al. 2009; Wu et al. 2011).

Figure 19

Traffic Density and Preeclampsia

HELLP = hemolysis, elevated liver enzyme levels, and low platelet count syndrome.

###### Proximity to Road Measures

The five studies that evaluated proximity to main road measures and hypertensive disorders of pregnancy reported small but positive associations, with some reaching statistical significance (Choe et al. 2018; Madsen et al. 2018; Miranda et al. 2013; van den Hooven et al. 2009; Yorifuji et al. 2015) (Figure 20). Correlations between these proximity to road measures and modeled or measured air pollutants were not reported, but ORs were similar in the studies that evaluated both metrics (Choe et al. 2018; Madsen et al. 2018). In addition, Wu et al. (2016) reported statistically significant positive associations between exposure to TRAP and development of late-onset preeclampsia but only performed descriptive analyses for incidence of preeclampsia and road density parameters and did not calculate ORs or CIs.

Figure 20

Proximity to Traffic and Combined Hypertensive Disorders during Pregnancy

HDP = hypertensive disorders of pregnancy.

##### Risk-of-Bias Considerations

Risk-of-bias ratings for individual studies of traffic density or proximity to road measures were generally rated probably low or definitely low across most risk-of-bias domains, as shown in the risk-of-bias heatmap (Figure 21) and bar chart (Figure 22), and the overall confidence rating was not changed because of risk of bias.

Figure 21

Risk-of-bias Heatmap: Traffic and Hypertensive Disorders of Pregnancy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for human epidemiological studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure 22

Risk-of-bias Bar Chart: Traffic and Hypertensive Disorders of Pregnancy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

*Questions in bold are the key risk-of-bias questions for human epidemiological studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

###### Exposure Characterization

Inherent in studies evaluating traffic measures is a reduction in precision (resulting in bias toward the null) for the exposure measurements compared with measurements of surrogates for traffic-related air pollutants. Therefore, the true effect of TRAP exposure on hypertensive disorders of pregnancy may not be reflected in studies that evaluate traffic measures. Two studies were included in which there were risk-of-bias concerns about the exposure characterization (Miranda et al. 2013; Yorifuji et al. 2015). In both cases, there was a probably high risk of bias for the exposure characterization because there was poor alignment between the exposure assessments and outcome measurements (i.e., the timing of the exposure measurements did not line up well with the timing of the pregnancy periods). Most studies accounted for residential mobility in sensitivity analyses; thus, exposure misclassification due to residential mobility was minimal.

###### Outcome Assessment

Risk-of-bias ratings for the outcome assessment were probably low or definitely low for all studies that reported traffic measurements.

###### Confounding and Modifying Variables

Most studies that evaluated traffic measures adjusted for smoking and BMI; however, those studies that did not adjust for smoking also did not adjust for BMI resulting in potential bias in both directions. In the Wu et al. (2016) study, there were also clear risk-of-bias concerns that would lower the confidence of the overall conclusions in this study, including probably high risk of bias for comparison groups and confounding variables. However, exclusion of this study did not affect the overall ratings for traffic measures and hypertensive disorders of pregnancy.

###### Summary

In some studies, there were a few risk-of-bias concerns about exposure characterization and confounding variables that would potentially bias the results toward and away from the null. For all remaining risk-of-bias questions for all of the individual studies that evaluated traffic measures, there was probably low or definitely low risk of bias and, therefore, no concerns over the internal validity of the reported results that would further decrease the confidence in the body of evidence.

#### Animal Traffic Measures Data

There were no animal data evaluating associations between traffic measures and hypertensive disorders of pregnancy that met the PECO criteria for this assessment.

#### Evidence Synthesis for Traffic Measures

Both traffic density and proximity to road measures showed positive but nonsignificant associations with increased risk for developing hypertensive disorders of pregnancy in the available human evidence. There is low confidence in the body of evidence that close proximity to a major road or increased traffic density during pregnancy is associated with an increased risk for a hypertensive disorder of pregnancy. The confidence ratings are summarized below.

- Human body of evidence: Low confidence
- Animal body of evidence: No studies

The human body of evidence suggests that one’s proximity to main roads and proximity to high-traffic density regions during pregnancy could be associated with the development of a hypertensive disorder of pregnancy.