# Methods

## Problem Formulation and Protocol Development

The National Toxicology Program (NTP) Office of Health Assessment and Translation (OHAT) received a nomination to evaluate emerging children’s health issues associated with ambient air pollution (Federal Register 77 FR 41406, 13 July 2012; https://ntp.niehs.nih.gov/go/trap). The nomination suggested that OHAT focus on traffic-derived air pollutants and avoid reviewing the effects of well-characterized exposures (e.g., tobacco smoke, mercury, lead, arsenic).

The health effects nominated for evaluation focused on emerging children’s health outcomes. To help refine the focus, OHAT conducted a preliminary inventory of the literature using a search strategy designed to capture the types of pollutants outlined in the original nomination and a variety of health outcomes relevant to children’s health. The preliminary search results were used to identify emerging health areas of concern in addition to types of air pollution that could be considered together in a systematic review (e.g., traffic-related sources). OHAT prioritized the list of emerging health outcomes to review based on the extent of the available literature and evaluations of health effects conducted by other federal agencies. Outcomes related to respiratory health were not considered for evaluation as these outcomes are studied and reviewed more commonly.

Based on the results of this effort, OHAT determined that hypertensive disorders of pregnancy were among the best health outcomes to evaluate due to their effect on children’s health. In addition, the majority of literature on these health outcomes had been published recently (since 2009) and would not have been included in the 2010 Health Effects Institute (HEI) Special Report 17 on health effects of traffic-related air pollution (TRAP) (HEI 2010) or the U.S. Environmental Protection Agency (EPA) Integrated Science Assessments for carbon monoxide (CO) (USEPA 2010), nitrogen oxides (NO_x_) (USEPA 2008), or particulate matter (PM) (USEPA 2009). The only recent review by a federal agency evaluating health effects in children following TRAP exposure was published by the Centers for Disease Control and Prevention (CDC) and focused on pediatric cancer (Boothe et al. 2014). Two additional groups evaluated the association between ambient air pollution and hypertensive disorders of pregnancy, but these studies did not specifically focus on traffic-derived air pollution nor did they assess internal validity (risk of bias) for the individual studies (Hu et al. 2014; Pedersen et al. 2014).

The overall objective and specific aims stated above were developed and refined through a series of problem formulation steps including: (1) review of the topic by the evaluation design team and other technical experts with backgrounds in air pollution, toxicology, epidemiology, reproductive physiology, information science, and systematic review; (2) deliberation with NTP staff and consultation with scientists at other federal agencies represented on the NTP Executive Committee;^1^ (3) public review of the concept for Evaluation of Traffic-Related Air Pollution and Children’s Health at the April 16–18, 2014 meeting of the NTP Board of Scientific Counselors (https://ntp.niehs.nih.gov/go/9741); (4) guidance outlined in the OHAT Handbook for Conducting a Literature-Based Health Assessment (NTP 2015); and (5) external peer review of the draft protocol. The protocol was posted in June 2016 ([underlined: Appendix G]) and was used to conduct this review. Updates and clarifications to the OHAT Handbook were posted in March 2019 (https://ntp.niehs.nih.gov/go/systematic_review) and included clarifications to the OHAT approach for reaching conclusions across multiple related exposures. A brief summary of the methods is presented below.

1 The NTP Executive Committee provides programmatic and policy oversight to the NTP Director and meets once or twice a year in closed forum. Members of this committee include the heads (or their designees) from the following federal agencies: Consumer Product Safety Commission (CPSC), Department of Defense (DoD), Environmental Protection Agency (EPA), Food and Drug Administration (FDA), National Cancer Institute (NCI), National Center for Environmental Health/Agency for Toxic Substances and Disease Registry (NCEH/ATSDR), National Institute of Environmental Health Sciences (NIEHS), National Institute for Occupational Safety and Health (NIOSH), and Occupational Safety and Health Administration (OSHA).

## PECO Statements

To address NTP’s overall objective and specific aims, a PECO ([underlined: P]opulation, [underlined: E]xposure, [underlined: C]omparator, and [underlined: O]utcome) statement was developed as an aid to identify search terms and inclusion/exclusion criteria as appropriate for addressing the overall research question for the systematic review (AHRQ 2014; Higgins and Green 2011). The PECO statement is provided below for human and animal studies (Table 1). For the evaluation of hypertensive disorders of pregnancy associated with TRAP, the outcomes of interest were gestational hypertension; preeclampsia; eclampsia; hemolysis, elevated liver enzyme levels, and low platelet count (HELLP) syndrome; and changes in blood pressure.

Table 1 PECO Statement

PECO Element | Evidence
Population | Female humans or mammalian animals who were pregnant at exposure and outcome assessment
Exposure | Exposure to traffic-related air pollution, including traffic measures (e.g., distance to main road, length of main streets with a buffer zone around homes or schools, traffic volume) and air pollutants associated with traffic emissions (e.g., CO, NO_x_, BC, EC, coarse PM, PM_2.5_, and ultrafine PM) as well as mobile source toxics (e.g., benzene, diesel exhaust, PAHs); air pollutants measured or modeled that estimate the pollutant-exposure surrogate and could reasonably be traffic-related (e.g., near-road monitors); inhalation route of exposure (human, animal), including nasal installation (animal)
Comparator | A comparison population exposed to lower levels (or no exposure/exposure below detection levels) of traffic-related air pollution
Outcome | Gestational hypertension, preeclampsia, eclampsia, HELLP syndrome, blood pressure measurements

BC = black carbon; CO = carbon monoxide; EC = elemental carbon; HELLP = hemolysis, elevated liver enzymes, low platelet count; NO_x_ = nitrogen oxides; PAHs = polycyclic aromatic hydrocarbons; PM = particulate matter.

The exposure characterization was an important consideration for this assessment because it focuses on air pollution derived specifically from traffic rather than more general ambient air pollution. Exposures were characterized by direct measures of traffic or measured or modeled concentrations of traffic-related air pollutant surrogates. Direct measures of traffic included distance to the nearest road or highway, distance to street canyons (i.e., streets lined with tall buildings on either side), and length of main streets within a buffer zone around homes or schools. Concentrations of traffic-related air pollutants included those obtained from monitors or other sources of measurement for pollutant-exposure surrogates that could be reasonably attributed to traffic (e.g., roadway-specific monitoring or subjects who lived within short distances of fixed monitors) or those estimated from dispersion models of traffic-related air pollutants or other models used to estimate traffic-related air pollutants (e.g., land use regression model) (Table 2). Many of the air pollutants regulated by EPA are established pollutant surrogates for TRAP (e.g., CO, NO_x_, PM), and the criteria used in this assessment were peer reviewed and accepted by epidemiologists with expertise in exposure characterization. Although it is acknowledged that many exposure surrogates used to identify TRAP are also generated by other sources, these exposure characterization criteria substantially increase the confidence in reaching hazard conclusions about associations between exposure to air pollution derived from traffic and hypertensive disorders of pregnancy.

Table 2 Traffic Exposure Metrics

Metric | Examples
Direct Measurements of Traffic^a^
Distance or Length | Distance to nearest main road of highway; distance to street canyons (i.e., streets lined with tall buildings on either side); length of main streets within buffer zone around homes or schools
Traffic Density | Density on nearest road; average density estimated from road networks with buffer zones around homes or schools; street canyons with buffers
Traffic-related Air Pollutants^b^
Measurements^c^ | Measurements of traffic-related air pollutants from monitors or other sources of measurements that could reasonably be attributed to traffic (e.g., near-road monitors)
Modeling | Dispersion of traffic-related air pollutants; other models used to estimate traffic-related air pollution (e.g., land use regression model)

^a^ Studies with self-reporting of direct measures of traffic will be included; however, they will be identified as definitely high risk of bias.

^b^ Includes carbon monoxide; black carbon; elemental carbon; nitrogen oxides; particulate matter (specifically PM_2.5_ [fine PM], ultrafine PM, and coarse PM); and mobile source toxics such as benzene, diesel exhaust, and polycyclic aromatic hydrocarbons.

^c^ Studies utilizing personal air monitoring and/or urine biomarkers will be used as long as some description of traffic is included in the methods.

## Literature Search

Literature search strategies were developed to identify all relevant published evidence on hypertensive disorders of pregnancy potentially associated with TRAP through (1) review of PubMed’s Medical Subject Headings for relevant and appropriate terms, (2) data extraction of a test set of relevant studies, and (3) evaluation of search strategies presented in other reviews. The search strategy was performed, and the results were assessed to ensure that 100% of the previously identified relevant primary studies were retrieved. Three databases (PubMed, Scopus, and Web of Science) were searched through January 28, 2019, using a strategy customized for each database (Appendix B). No publication year limits or language restrictions were imposed. The literature search was developed in collaboration with a librarian trained in systematic review methodology. Although unpublished studies were eligible (see protocol for more details;[underlined: Appendix G]), there were no unpublished data that met the PECO criteria for inclusion for this assessment.

### Searching Other Resources

The reference lists of all included studies, relevant reviews, commentaries, and other nonresearch articles identified during the initial literature search were manually searched for additional relevant publications. Studies were evaluated using the same inclusion and exclusion criteria that were used for screening records retrieved from the electronic search.

## Study Selection

### Evidence Selection Criteria

To be eligible for inclusion, studies had to satisfy eligibility criteria specified by the PECO statement in Table 1. Reviews and other papers that did not provide original data on potential health effects were excluded but were considered for context if the information they provided (e.g., exposure, metabolism data) was useful for evaluating confidence in bodies of evidence or integrating evidence across human and animal data from the included studies. The following additional exclusion criteria were applied: (1) studies using nonpregnant subjects or animals other than nonhuman mammals; (2) studies that evaluated CO poisoning, noninhalation routes of exposure to relevant pollutants, heavy or transitional metals, formaldehyde or other volatile organic compounds relevant to vehicle exhaust; (3) articles with no original data, conference abstracts or other studies published in abstract form only, and retracted articles.

### Screening Process

References retrieved from the literature search were screened for relevance and eligibility against the evidence selection criteria using DistillerSR^®^ (https://www.evidencepartners.com/products/distillersr-systematic-review-software/) by Evidence Partners, a web-based, systematic review software program with structured forms and procedures to ensure standardization of the process. Screeners from the evidence evaluation team were trained with an initial pilot phase to improve clarity of the inclusion and exclusion instructions and to improve accuracy and consistency among screeners. All references were independently screened by two trained screeners (one of which was the project lead) at the title and abstract level to determine whether a reference met the evidence selection criteria. Studies that were not excluded during the title and abstract review were screened with a full-text review. Screening conflicts were resolved through discussion. Following full-text review, the remaining studies were “included” and used for the evaluation.

## Data Extraction

### Extraction Process

Data were collected (i.e., extracted) from included studies by one member of the evaluation team and checked by a second member for completeness and accuracy. Any discrepancies in data extraction were resolved by discussion. Information that was inferred, converted, or estimated during data extraction is annotated (e.g., using brackets [n = 10]). Study extraction files noted when an attempt was made to contact study authors by email (and whether a response was received) for missing data considered important for evaluating key study findings.

### Data Availability

Data extraction was completed using the Health Assessment Workspace Collaborative (HAWC (https://hawcproject.org/portal/)), an open-source and freely available web-based interface application, for visualization and warehousing.^2^ The data extraction results for included studies are publicly available (https://hawcproject.org/assessment/60/) and can be downloaded in Excel format through HAWC (NTP 2019a). Data extraction elements are listed separately for human, animal, and in vitro studies in the protocol ([underlined: Appendix G]) (NTP 2019b).

2 HAWC (Health Assessment Workspace Collaborative): A Modular Web-based Interface to Facilitate Development of Human Health Assessments of Chemicals (https://hawcproject.org/portal/).

## Quality Assessment of Individual Studies

Risk of bias was assessed for individual studies using a tool developed by OHAT that outlines a parallel approach to evaluating risk of bias in human and animal studies to facilitate consideration of risk of bias across evidence streams with common terms and categories (NTP 2015). The risk-of-bias tool comprises a common set of 11 questions that are answered based on the specific details of individual studies to develop risk-of-bias ratings for each question. Study design determines the subset of questions used to assess risk of bias for an individual study (Figure 1).

Figure 1

OHAT Risk-of-bias Questions and Applicability by Study Design

*Experimental animal studies are controlled exposure studies. Nonhuman animal observational studies can be evaluated using the design features of observational human studies such as cross-sectional study design.

**Human controlled trials are studies in humans with controlled exposure (e.g., randomized controlled trials).

***Cross-sectional studies include population surveys with individual data (e.g., NHANES) and surveys with aggregate data (i.e., ecological studies).

Assessors were trained with an initial pilot phase undertaken to improve clarity of rating criteria and to improve consistency among assessors. Studies were independently evaluated by two trained assessors who answered all applicable risk-of-bias questions with one of four options shown in Figure 2 following pre-specified criteria detailed in the protocol ([underlined: Appendix G]). The criteria describe aspects of study design, conduct, and reporting required to reach risk-of-bias ratings for each question and specify factors that can distinguish among ratings (e.g., what separates “definitely low” from “probably low” risk of bias).

Figure 2

The Four Risk-of-bias Rating Options

Answers to the risk-of-bias (study quality) questions result in one of the four risk-of-bias ratings.

In the OHAT approach, some risk-of-bias questions or elements are considered potentially more important when assessing studies because there is more empirical evidence that these areas of bias have a greater effect on estimates of the effect size or because these issues are generally considered to have a greater effect on the credibility of study results in environmental health studies (Rooney et al. 2016). There were three key questions for observational human studies: confounding, exposure characterization, and outcome assessment. There were also three key questions for the experimental animal study: randomization, exposure characterization, and outcome assessment.

Any discrepancies in ratings between assessors were resolved through discussion to reach the final recorded risk-of-bias rating for each question along with a statement of the basis for that rating. Members of the evaluation team were consulted for assistance if additional expertise was necessary to reach final risk-of-bias ratings based on specific aspects of study design or performance reported for individual studies. Information or study procedures that were not reported is assumed not to have been conducted, resulting in an assessment of probably high risk of bias. Authors were queried by email to obtain missing information, and responses received were used to update risk-of-bias ratings.

## Organizing and Rating Confidence in Bodies of Evidence

### Health Outcome and Endpoint Grouping by Categories of Health Effects and Exposure

After data were extracted from all studies, the health effects results were grouped across studies to develop bodies of evidence or collections of studies with data on the same or related outcomes for the four main categories of interest: (1) blood pressure change during pregnancy, (2) gestational hypertension, (3) preeclampsia, and (4) eclampsia and HELLP syndrome (Table 3). Within these main endpoint categories, studies were grouped by exposure (e.g., traffic measures, PM, NO_x_) and evaluated individually and together as combined hypertensive disorders of pregnancy for each exposure.

Table 3 Hypertensive Disorders of Pregnancy: Endpoint Categories for Human and Animal Studies

Endpoint Category | Description
Blood Pressure Change | An increase or decrease related to the reference pregnant population (human or animal)
Gestational Hypertension | Isolated systolic blood pressure (SBP) ≥140 mmHg or diastolic blood pressure (DBP) ≥90 mmHg during the second half of pregnancy
Preeclampsia | Gestational hypertension accompanied by proteinuria after 20 weeks of gestation
Eclampsia and HELLP | [underlined: Eclampsia]: Gestational hypertension, with or without proteinuria, plus at least one observed seizure in a woman with no prior history of a seizure disorder [underlined: Hemolysis elevated liver enzyme low platelet count (HELLP) syndrome]: Hemolysis (abnormal peripheral smear, bilirubin > 1.2 mg/dl, or lactose dehydrogenase > 600 IU/L), elevated liver enzymes (aspartate amino transferase or alanine aminotransferase > 70 IU/L), and low platelet count (<100,000 mm^3^)

## Considerations for Pursuing a Narrative or Quantitative Evidence Synthesis

Heterogeneity within the available evidence was used to determine whether a narrative approach with or without a quantitative synthesis (meta-analysis) was most appropriate for evidence integration. Meta-analysis approaches are considered most suitable if there are at least 6–10 results for a continuous variable and at least 4 results for a categorical variable (Rudra et al. 2011). Groups of studies for two pollutants displayed enough similarity across exposures to deem them appropriate for meta-analyses: PM_2.5_ and NO_2_. Due to heterogeneity of the evidence or small bodies of evidence across other TRAP measures, only a narrative approach (and not a meta-analysis) was appropriate for evidence synthesis of these measures.

### Confidence Rating: Assessment of Body of Evidence

The quality of evidence for hypertensive disorders of pregnancy was evaluated using the GRADE system for rating the confidence in the body of evidence (AHRQ 2014; Guyatt et al. 2011). More detailed guidance on reaching confidence ratings in the body of evidence as “high,” “moderate,” “low,” or “very low” is provided in the OHAT Handbook for Conducting a Literature-Based Health Assessment (https://ntp.niehs.nih.gov/go/38673, see STEP 5). In brief, available human and animal studies on a particular health outcome in Table 3 were initially grouped by key study design features, and each grouping of studies was given an initial confidence rating by those features. Starting at this initial rating (column 1 of Figure 3), potential downgrading of the confidence rating was considered for factors that decrease confidence in the results (column 2 of Figure 3 [risk of bias, unexplained inconsistency, indirectness or lack of applicability, imprecision, and publication bias]); and potential upgrading of the confidence rating was considered for factors that increase confidence in the results (column 3 of Figure 3 [large magnitude of effect, dose response, consistency across study designs/populations/animal models or species, consideration of residual confounding, and other factors that increase confidence in the association or effect]). Consideration of consistency across study designs, human populations, or animal species is not included in the GRADE guidance (Guyatt et al. 2011); however, it is considered in the modified version of GRADE used by OHAT (Rooney et al. 2014).

Figure 3

Assessing Confidence in the Body of Evidence

Confidence ratings were assessed by federal staff and reviewed by members of the evaluation review team for accuracy and consistency, and discrepancies were resolved by consensus and consultation with technical advisors as needed. Confidence ratings for the outcomes are summarized in evidence profile tables for each outcome.

## Preparation of Level-of-evidence Conclusions

The confidence ratings were translated into level of evidence of health effects for each type of health outcome (if applicable) and hypertensive disorders of pregnancy as a whole for each traffic-related pollutant, each traffic measure, and traffic-related air pollution as a whole according to one of four statements: (1) High, (2) Moderate, (3) Low, or (4) Inadequate (Figure 4 and Table 4). The descriptor “evidence of no health effect” is used to indicate confidence that the substance is not associated with a health effect. Because of the inherent difficulty in proving a negative, the conclusion “evidence of no health effect” is only reached when there is high confidence in the body of evidence.

Figure 4

Translation of Confidence Ratings into Evidence of Health Effect Conclusions

Table 4 Definitions of Level-of-evidence Descriptors

Evidence Descriptors | Definition
High Level of Evidence | There is high confidence in the body of evidence for an association between exposure to TRAP and the health outcome(s).
Moderate Level of Evidence | There is moderate confidence in the body of evidence for an association between exposure to TRAP and the health outcome(s).
Low Level of Evidence | There is low confidence in the body of evidence for an association between exposure to TRAP and the health outcome(s), or no data are available.
Inadequate Evidence | There is insufficient evidence available to assess if exposure to TRAP is associated with the health outcome(s).
Evidence of No Health Effect | There is high confidence in the body of evidence that exposure to TRAP is not associated with the health outcome(s).

## Integration of Evidence to Develop Hazard Identification Conclusions

Finally, the level-of-evidence ratings for human and animal data were integrated with consideration of in vitro/mechanistic data to reach one of five possible hazard identification categories: Known, Presumed, Suspected, Not classifiable, or Not Identified to Be a Hazard to Pregnant Women (Figure 5).

Figure 5

Hazard Identification Scheme for Hypertensive Disorders of Pregnancy

### Considerations for Human and Animal Data

Initial hazard identification conclusions were reached by integrating the highest level-of-evidence conclusions for TRAP-related hypertensive disorders of pregnancy for human and animal evidence streams. Hazard identification conclusions were reached on the effects of individual exposures to induce or exacerbate each health outcome (Figure 2) or the combined hypertensive disorders of pregnancy. The level-of-evidence conclusion for human data for the health outcome was considered together with the level of evidence for nonhuman animal data on the health outcome to reach one of four initial hazard identification conclusions: Known, Presumed, Suspected, or Not classifiable. When either the human or animal evidence stream was characterized as inadequate evidence for a particular outcome, conclusions were based on the remaining evidence stream alone (which is equivalent to treating the missing evidence as “Low” in Figure 5).

### Considerations for Evaluating Combined Traffic-related Air Pollution Exposure

Evidence for an association between TRAP and hypertensive disorders of pregnancy was evaluated in a stepwise manner. This stepwise approach for considering the combined evidence across multiple exposures or the individual pollutants that make up TRAP is analogous to the method for evaluating multiple biologically related outcomes to inform confidence on the overall health outcome. In each case, the evidence is evaluated for individual exposures or outcomes and then the combined evidence is considered collectively. First, the bodies of evidence for individual TRAP components (e.g., PM_2.5_, NO_x_) were evaluated. A confidence rating for each TRAP component was then developed.

Because TRAP comprises multiple pollutants, NTP considered the appropriateness of evaluating the evidence across all TRAP measures included in the evaluation as a single combined TRAP exposure. Two key points were weighed in making this determination: (1) whether individual TRAP components could act independently to elevate blood pressure and (2) if exposure to multiple TRAP components is likely during pregnancy. Most studies in the human evidence evaluated single TRAP components, and studies were generally consistent in finding an association (with the same direction of effect) between the individual TRAP components and elevated blood pressure during pregnancy. Studies that evaluated multiple TRAP components still found significant associations between the individual components and hypertensive disorders of pregnancy after statistically accounting for other exposures. Further, mechanistic studies demonstrated that multiple TRAP components could act independently on pathways that lead to elevated blood pressure (e.g., through vascular inflammation and oxidative stress). Therefore, consistency in the evidence for an association between the individual TRAP components and hypertensive disorders of pregnancy and mechanistic data supporting independent mechanisms by which TRAP can elevate blood pressure enabled NTP to support the development of a hazard conclusion for the combined TRAP exposure. Thus, the evidence in the body of literature was considered together and then reevaluated for properties related to downgrading or upgrading confidence in the body of evidence.

### Consideration of Mechanistic Data

There is no requirement to consider mechanistic or mode-of-action data to reach hazard identification conclusions; however, when available, this and other relevant supporting types of evidence may be used to raise (or lower) the category of the hazard identification conclusion. Mechanistic data can come from a wide variety of studies that are not intended to identify a disease phenotype. This source of experimental data includes in vitro and in vivo laboratory studies directed at cellular, biochemical, and molecular mechanisms that explain how a chemical produces particular adverse effects.

The factors outlined for increasing or decreasing confidence that the mechanistic data support biological plausibility are conceptually similar to those used to rate confidence in bodies of evidence for human or animal in vivo studies and are listed below and described in depth in the protocol ([underlined: Appendix G]). Four factors were considered that contribute to increased confidence: potency, dose response, consistency in terms of cellular events observed at the same or lower doses than in vivo health effects, and consistency across cellular targets on the same pathway. Four factors were considered that contribute to decreased confidence: unexplained inconsistency across studies of the same endpoint, risk of bias, indirectness/applicability of the pathway for human health or concentrations for human exposure, and publication bias. Evaluations of the strength of evidence provided by mechanistic data were made on an outcome-specific basis following a discussion by the evaluation team and consultation with technical advisors as needed.

- If mechanistic data provided strong support for biological plausibility of the relationship between exposure and the health effect, the hazard identification conclusion may be upgraded (indicated by black “up” arrows in Figure 5) from that initially derived by considering the human and nonhuman animal evidence together.
- If mechanistic data provided strong opposition for biological plausibility of the relationship between exposure and the health effect, the hazard identification conclusion may be downgraded (indicated by gray “down” arrows in Figure 5) from that initially derived by considering the human and nonhuman animal evidence together.

To date, the mechanism(s) underlying the effects of air pollution on blood pressure during pregnancy have not been investigated. A significant challenge to this area of research lies in the fact that the mechanisms underlying the etiology of hypertensive disorders of pregnancy themselves are not clearly understood, although improper remodeling of the uterine arteries resulting in reduced blood flow to the placenta appears to play a role. Although studies investigating the physiology of vascular remodeling events and endocrine adaptations during pregnancy were considered to provide context for the available data, none of those studies investigated the effect of air pollution on those mechanisms. Thus, mechanistic data relevant to the hemodynamic, endocrine, and cardiovascular adaptations during normal pregnancy were not used to assess biological plausibility for consideration of upgrading or downgrading confidence.

Although it is envisioned that strong evidence for a relevant process from mechanistic data alone could indicate a greater potential for the substance to induce or exacerbate hypertensive disorders of pregnancy, for this evaluation, the mechanistic data on individual TRAP components on blood pressure parameters in the nonpregnant state were considered only to inform the appropriateness of developing a hazard conclusion for the combined TRAP exposure. The mechanistic studies considered for this assessment evaluated several features associated with hypertensive disorders of pregnancy, although none of the studies specifically evaluated the effects of air pollutants on mechanisms affecting blood pressure during pregnancy. Studies that were considered included those that evaluated effects of air pollutants on placental vascularization in early pregnancy or effects of air pollutants on mechanisms related to blood pressure changes in the nonpregnant state.

### Considerations for Meta-analyses and Meta-analyses Methods

Meta-analyses were conducted to explore the associations between exposures to PM_2.5_, NO_2_, or NO_x_ and hypertensive disorders of pregnancy. The available evidence was evaluated with respect to several criteria to ensure results included in the meta-analyses would be sufficiently similar. The following criteria were considered:

- Outcome: The outcome of interest was hypertensive disorders of pregnancy, including gestational hypertension, preeclampsia, and eclampsia.
- Exposure unit: The study outcomes were evaluated with respect to a 10 μg/m^3^ increase in exposure.
- Effect estimate: The study reported effects as odds ratios (ORs) and included 95% confidence intervals (CIs) or standard errors (SES).

When necessary, to ensure consistent units across studies and to allow comparisons of effect estimates between studies, the reported effect estimates were converted to common exposure increments. For example, in this assessment, most of the studies that evaluated associations between PM_2.5_ exposure and preeclampsia reported effects for every 10 µg/m^3^ increase in PM_2.5_. Therefore, for PM_2.5_ studies that reported effects associated with a 5 μg/m^3^ increase in PM_2.5_, effect estimates were transformed to represent effects at a 10 μg/m^3^ increase. Several studies reported exposures in parts per billion (ppb), and these exposures were converted as described in the Pedersen et al. (2014) meta-analysis supplement. Exposure estimations for NO_2_ that were expressed in ppb instead of mass per volume of air were converted to μg/m^3^ using a general conversion factor of 1.88 (assuming that 1 ppb equals 1.88 μg/m^3^ at 1 atmosphere for both pollutants). Thus, for each study, an OR and 95% CI were obtained for the association between the outcome of interest and a 10 μg/m^3^ increase in PM_2.5_, NO_2_, or NO_x_.

Adjusted ORs were used in the meta-analyses, and if results from multiple models were reported within a single study, the fully adjusted, single-pollutant models were selected.

Wu et al. (2011) reports results associated with PM_2.5_, NO_2_, NO_x_, and traffic measures from two separate study locations (Los Angeles County and Orange County, California). Because the land use regression (LUR) models were originally developed based on measurements taken only in Los Angeles County and the difference in socioeconomic status between the two counties is remarkable, the two county results were treated as independent effects and both were included in the analyses. Furthermore, given that the focus of the assessment was on TRAP, the CALINE4 line-source dispersion modeling estimates for PM_2.5_ and NO_x_ were used (rather than the estimates based on ambient monitoring data) because these estimates are more precise than other exposure measurements and can capture the local traffic emissions within 3 km of each residence for five traffic-related pollutants. The adjusted LUR model results were used for the NO_2_ analyses.

In general, if a study reported multiple hypertension-related results (e.g., gestational hypertension and preeclampsia, mild and severe preeclampsia), the effect estimates were pooled, and one effect estimate was included in the exposure-specific combined hypertensive disorders of pregnancy meta-analysis.

The combined risk estimates for studies with categorical effect estimates were estimated using the highest versus the lowest exposure category. When effect estimates of two different categorical analyses of proximity to major roads were reported (Miranda et al. 2013), the one with the greatest exposure contrast was selected.

If possible, estimates for multiple exposure periods (e.g., full gestational period, trimester 1, trimester 2) were reported. Meta-analyses were not performed if fewer than four results were available for a specific exposure-outcome combination.

Fixed- and random-effects models were used to obtain the summary risk estimates. Heterogeneity of the included studies was assessed using the Q-test (Cochran 1954). The random-effects model results are presented when the Q-test showed evidence of heterogeneity (p < 0.05) (DerSimonian and Laird 1986). When the p value for heterogeneity was greater than 0.05, the random-effects model results are identical to the fixed-effects model results (Mantel and Haenszel 1959). Forest plots were used to display the individual study-specific results and summary risk estimates. Publication bias was examined using the Egger’s test and funnel plots (Egger et al. 1997).

Data management was performed with Excel. Statistical analyses were performed using STATA version 15 (StataCorp 2017) using the metan, metareg, metainf, metafunnel, metabias, and metatrim packages.