# Introduction

The National Toxicology Program (NTP) Office of Health Assessment and Translation (OHAT) conducted a systematic review to evaluate the evidence that exposure to traffic-related air pollution (TRAP) is associated with hypertensive disorders of pregnancy.

TRAP refers to air pollution exposures derived from primary emissions from motor vehicles due to fossil fuel combustion. Sources of TRAP include passenger cars, diesel trucks and buses, and nonroad equipment (e.g., recreational vehicles, lawn and garden equipment). Motor vehicles emit large amounts of carbon dioxide (CO_2_), carbon monoxide (CO), nitrogen and sulfur oxides (NO_x_ and SO_x_, respectively), volatile organic compounds (VOCs), and particulate matter (PM). Many of these pollutants are regulated by the U.S. Environmental Protection Agency (EPA) and are used as pollutant surrogates for TRAP (https://www.epa.gov/criteria-air-pollutants).

Pollution-control regulations, along with innovative technologies and approaches developed to improve air quality domestically and abroad, reflect the increased concern over potential health effects associated with exposure to TRAP. Currently, 39% of the U.S. population lives in areas with populations greater than 2.5 million people (USEPA 2016). Rapid population growth, expansion of metropolitan areas, and increased dependence on motor vehicles contribute to TRAP exposure (HEI 2010). In addition, the fraction of the population living and working near busy roads and highways continues to increase. As a result, TRAP may contribute significantly to ambient air pollution, especially in urban settings where high-density traffic patterns and domiciles in close proximity to high-traffic roadways are common (Krzyzanowski et al. 2005).

Across the United States, TRAP emissions have declined since the 1990s, but the urban setting continues to be an area of higher exposures to traffic-related emissions. There is considerable variability in fine particulate matter (PM_2.5_) and other TRAP component concentrations across the United States, with the highest concentrations of PM_2.5_ (>18 µg/m^3^) reported in areas of southern California, Alabama, and Pennsylvania. Overall PM_2.5_ concentrations have decreased since 1999 (the beginning of nationwide monitoring for PM_2.5_) and remained nearly constant from 2002 to 2007 (USEPA 2009). The most recent analysis from EPA’s Air Quality System network data indicate that PM_2.5_ concentrations continue to decline. Similarly, total NO_x_ emissions have declined from 1990 to 2013, but highway vehicles and off-highway vehicles and engines continue to contribute substantially (with more than three-quarters of total emissions) in urban areas (USEPA 2016). With the recognized role of motor vehicles in air pollution—particularly in urban environments—identifying and further characterizing health effects associated with TRAP exposure is needed, especially for susceptible populations (HEI 2010).

The components of TRAP are recognized risk factors for cardiovascular disease in the general population in the United States and abroad (Coogan et al. 2012; Guo et al. 2010; Sorensen et al. 2012; USEPA 2009; WHO 2016). Although the mechanisms by which air pollution affects cardiovascular disease, particularly hypertension, are not completely understood, some of the likely and overlapping pathways that may be involved include effects on oxidative stress, the autonomic nervous system, and vascular function (Brook and Rajagopalan 2009).

Epidemiological and toxicological studies suggest a causal relationship between acute and long-term exposures to components of PM and cardiovascular effects in the general population (USEPA Abraham et al. 2018; 2009). Hypertension, which is an important risk factor for developing cardiovascular disease, poses a greater burden in women than in men (Mozaffarian et al. 2016). Although hypertension affects women in all phases of life, hypertension in pregnancy presents unique challenges. Hypertensive disorders of pregnancy pose risks to the mother and child, increasing the risk for developing cardiovascular disease later in life for the mother and increasing the risk of preterm birth, prematurity-related diseases, and other adverse effects for the child. Air pollution-related research on children’s health have focused mainly on the development and exacerbation of asthma or other respiratory problems (HEI 2010). Fewer studies have evaluated other aspects of children’s health, although there is growing evidence that TRAP increases the likelihood of developing hypertensive disorders of pregnancy, which increases the risk for adverse health outcomes in children.

The American College of Obstetricians and Gynecologists classifies hypertensive disorders of pregnancy into four categories: (1) gestational hypertension, (2) preeclampsia/eclampsia, (3) chronic hypertension, and (4) chronic hypertension with superimposed preeclampsia. These disorders complicate approximately 10% of pregnancies and are one of the leading causes of maternal and fetal morbidity and mortality worldwide (ACOG 2013). Hypertensive disorders of pregnancy are characterized typically by differences in the timing of onset of symptoms (Duley 2009). Chronic hypertension with or without superimposed preeclampsia is defined by elevated blood pressure that predates conception or is detected during the first half of gestation, whereas gestational hypertension and preeclampsia/eclampsia typically occur during the second half of gestation. These disorders range in severity from hypertension alone to multiorgan dysfunction and seizures. Preeclampsia, for example, is responsible for 50,000–60,000 maternal deaths each year and is associated with multiple maternal complications, including edema, intravascular coagulation, renal and liver dysfunction, stroke, and placental abruption (separation) or infarction (blockage of blood supply) (Duley 2009). Although viewed as a condition specific to the pregnancy and (in some cases) postpartum periods, hypertensive disorders of pregnancy can have long-term effects on the mother’s health and the health of her offspring. Women who experience hypertension in pregnancy are at an increased risk for developing cardiovascular disease, stroke, and type 2 diabetes later in life (Bauer and Cleary 2009; Bellamy et al. 2007; Duley 2009). Of relevance to children’s health, infants born to mothers with hypertension during pregnancy are at higher risk for preterm delivery, low birth weight, being small for gestational age, and a range of prematurity-related neonatal diseases with long-term effects that can persist into adulthood (Doyle 2008). As such, this assessment will extend the literature synthesis efforts of the Health Effects Institute (HEI), EPA, Centers for Disease Control and Prevention (CDC), and other researchers to understand the effects of TRAP that are relevant to maternal and children’s health.

Given the relationship between maternal blood pressure status and adverse maternal and early childhood health outcomes and the increasing evidence suggesting that TRAP is significantly associated with hypertension during pregnancy, this systematic review was developed to evaluate the human, animal, and mechanistic evidence for an association between TRAP and hypertensive disorders of pregnancy.

## Objective and Specific Aims

### Objective

The overall objective of this evaluation was to develop hazard identification conclusions about whether traffic-related air pollution is associated with hypertensive disorders of pregnancy by integrating levels of evidence from human and experimental animal studies.

### Specific Aims

- Identify literature reporting the effects of TRAP exposure characterized by traffic measures (e.g., distance to main road, length of main streets with a buffer zone around homes or schools, traffic volume) and air pollutants associated with traffic emissions (e.g., carbon monoxide, nitrogen oxides, black carbon, coarse particulate matter [2.5–10 μm], fine particulate matter [0.1–2.5 μm], and ultrafine particulate matter [<0.1 μm] as well as benzene, diesel exhaust, and polycyclic aromatic hydrocarbons) on hypertensive disorders of pregnancy in humans and animals (experimental and wildlife).
- Extract data on potential health effects from relevant studies (data extraction files of the included studies will be shared upon release of final report).
- Assess the internal validity (risk of bias) of individual human and animal studies using predefined criteria.

Dependent on the extent and nature of the available evidence:

- Synthesize the evidence using a narrative approach or meta-analysis (if appropriate) considering the limitations on data integration such as study design heterogeneity.
- Rate the confidence in the body of evidence for human and animal studies separately according to one of four statements: (1) High, (2) Moderate, (3) Low, or (4) Very Low or No Evidence Available.
- Translate confidence ratings into level of evidence of health effects for human and animal studies separately according to one of four statements: (1) High, (2) Moderate, (3) Low, or (4) Inadequate.
- Use the level-of-evidence ratings for human and animal data to reach one of five possible hazard identification conclusions: (1) Known, (2) Presumed, (3) Suspected, (4) Not Classifiable, or (5) Not Identified to Be a Hazard to Pregnant Women.