# Conflict of Interest

Individuals identified as collaborators in the About This Review section have certified that they have no known real or apparent conflict of interest related to traffic-related air pollution or hypertensive disorders of pregnancy.