# Appendix G Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NTP-DATA-MGRAPH-7.

## G.1 Protocol Information

Protocol

Revised Protocol