# Appendix F Protocol History

The original and revised protocols are available in Appendix G.

Table F-1 Protocol History and Revisions

Date | Activity or Revision
September 5, 2015 | Draft protocol reviewed: sent to peer reviewers for comment/review
June 24, 2016 | Evaluation protocol to be posted on OHAT website
August 7, 2019 | Revised protocol posted on OHAT website to reflect principal updates made during evaluation with justifications and date implemented noted: 1. Added Brandiese Beverly, Ph.D., as the Project Co-Lead (February 2017); 2. Protocol was originally developed to outline two OHAT systematic reviews, however, only TRAP and Hypertensive Disorders of Pregnancy was pursued (January 2018); 3. Systematic review on neurological disorders and TRAP was not pursued because this topic is currently under review by other organizations; here and throughout, text related to neurological disorders has a strike-through notation or is noted with a footnote that NTP will not pursue this topic (January 2018); 4. Here and throughout, the term pregnancy-induced hypertension or pregnancy-associated hypertension has been replaced with hypertensive disorders of pregnancy to reflect the more accurate term to describe the collection of disorders (February 2017); 5. The American College of Obstetrics and Gynecology recognizes 4 categories of hypertensive disorders of pregnancy, which include chronic hypertension and chronic hypertension with superimposed preeclampsia, and studies were not excluded solely based on the inclusion of pregnant women with chronic hypertension (August 2018); 6. Updated Figure 3 to reflect a clarification and update to the OHAT approach for systematic review and evidence integration, which clarified how hazard conclusions are reached when there is moderate level-of-evidence for human data with low or inadequate level-of-evidence for the animal evidence stream (March 2019); 7. Brandiese Beverly, Ph.D., added as Project Co-Lead in affiliation section, along with updates to contributor affiliations (July 2019); and 8. Paradoxically, smoking is a negative risk factor for preeclampsia and is not a confounder. Body mass index (BMI) is a risk factor for preeclampsia and was added as a confounder (August 2018).