# Appendix E Meta-analysis Sub-analyses Results

## E.1 Full Gestation PM_2.5_ Results

Table E-1 Influence Analysis of References Included in the Full Gestational Period PM_2.5_ Exposure and Preeclampsia Meta-analysis

Study Omitted | Odds Ratio (95% Confidence Interval)
Dadvand et al. (2013) | 1.47 (0.97, 2.32)
Rudra et al. (2011) | 1.52 (0.95, 2.40)
Savitz et al. (2015) | 1.73 (1.14, 1.98)
Wu et al. (2011) | 1.41 (0.93, 2.09)
Wu et al. (2011) | 1.46 (0.95, 2.32)
Combined | 1.51 (1.04, 2.20)

Table E-2 Publication Bias in References Included in the Full Gestational Period PM_2.5_ Exposure and Preeclampsia Meta-analysis

Egger’s Test for Small-study Effects: Regress Standard Normal Deviate of Intervention Effect Estimate against Its Standard Error
Number of Studies = 5 | | | Root MSE = 11.22
Standard Effect | Coefficient | Standard Error | t | P > \|t\| | 95% Confidence Interval
Slope | −0.1397884 | 0.3333834 | −0.42 | 0.703 | (−1.200763, 0.9211864)
Bias | 12.52648 | 10.47258 | 1.20 | 0.318 | (−20.80195, 45.85491)
Test of H_0_: No small-study effects | | | p = 0.318

MSE = mean square error.

Figure E-1

Influence Analysis Plot: References Included in the Full Gestational Period PM_2.5_ Exposure and Preeclampsia Meta-analysis

Figure E-2

Publication Bias in References Included in the Full Gestational Period PM_2.5_ Exposure and Preeclampsia Meta-analysis

## E.2 Full Gestation NO_2_ Results

Table E-3 Influence Analysis of References Included in the Full Gestational Period NO_2_ Exposure and Hypertensive Disorders of Pregnancy Meta-analysis

Study Omitted | Odds Ratio (95% Confidence Interval)
Dadvand et al. (2013) | 1.03 (0.97, 1.10)
Madsen et al. (2018) | 1.05 (0.98, 1.12)
Pedersen et al. (2017) | 1.02 (0.96, 1.09)
Pereira et al. (2013) | 1.02 (0.96, 1.09)
Savitz et al. (2015) | 1.05 (0.99, 1.11)
van den Hooven et al. (2011) | 1.03 (0.97, 1.09)
Wu et al. (2011) | 1.03 (0.97, 1.11)
Wu et al. (2011) | 1.02 (0.96, 1.08)
Combined | 1.03 (0.97, 1.09)

Table E-4 Influence Analysis of References Included in the Full Gestational Period NO_2_ Exposure and Preeclampsia Meta-analysis

Study Omitted | Odds Ratio (95% CI)
Dadvand et al. (2013) | 1.03 (0.97, 1.11)
Madsen et al. (2018) | 1.04 (0.98, 1.12)
Pedersen et al. (2017) | 1.02 (0.96, 1.10)
Pereira et al. (2013) | 1.02 (0.96, 1.09)
Savitz et al. (2015) | 1.06 (1.01, 1.11)
van den Hooven et al. (2011) | 1.03 (0.97, 1.10)
Wu et al. (2011) | 1.04 (0.96, 1.12)
Wu et al. (2011) | 1.02 (0.96, 1.09)
Combined | 1.04 (0.97, 1.10)

Table E-5 Publication Bias in References Included in the Full Gestational Period NO_2_ Exposure and Hypertensive Disorders of Pregnancy Meta-analysis

Egger’s Test for Small-study Effects: Regress Standard Normal Deviate of Intervention Effect Estimate against Its Standard Error
Number of Studies = 8 | | | Root MSE = 1.563
Standard Effect | Coefficient | Standard Error | t | P > \|t\| | 95% CI
Slope | −0.0499923 | 0.0204239 | −2.45 | 0.050 | (−0.0999678, −0.0000169)
Bias | 1.758844 | 0.7933426 | 2.22 | 0.068 | (−0.1823958, 3.700083)
Test of H_0_: No small-study effects | | | p = 0.068

MSE = mean square error.

Table E-6 Publication Bias in References Included in the Full Gestational Period NO_2_ Exposure and Preeclampsia Meta-analysis

Egger’s Test for Small-study Effects: Regress Standard Normal Deviate of Intervention Effect Estimate against Its Standard Error
Number of Studies = 8 | | | Root MSE = 1.591
Standard Effect | Coefficient | Standard Error | t | P > \|t\| | 95% CI
Slope | −0.0516838 | 0.0246087 | −2.10 | 0.080 | (−0.1118992, 0.0085316)
Bias | 1.674924 | 0.8264967 | 2.03 | 0.089 | (−0.3474407, 3.697288)
Test of H_0_: No small-study effects | | | p = 0.089

MSE = mean square error.

Figure E-3 Influence Analysis Plot: References Included in the Full Gestational Period NO_2_ Exposure and Hypertensive Disorders of Pregnancy Meta-analysis

Figure E-4 Influence Analysis Plot: References Included in the Full Gestational Period NO_2_ Exposure and Preeclampsia Meta-analysis

Figure E-5

Publication Bias in References Included in the Full Gestational Period NO_2_ Exposure and Hypertensive Disorders of Pregnancy Meta-analysis

Figure E-6

Publication Bias in References Included in the Full Gestational Period NO_2_ Exposure and Preeclampsia Meta-analysis