# Appendix D Risk-of-bias Figures

Figure D-1

Risk-of-bias Heatmap: Other Pollutants and Hypertensive Disorders of Pregnancy for Animal Studies

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

Figure D-2

Risk-of-bias Heatmap: Other Pollutants and Hypertensive Disorders of Pregnancy for Epidemiological Studies

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

Figure D-3

Risk-of-bias Bar Chart: Other Pollutants and Hypertensive Disorders of Pregnancy for Animal Studies

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).

Figure D-4

Risk-of-bias Bar Chart: Other Pollutants and Hypertensive Disorders of Pregnancy for Epidemiological Studies

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).