# Appendix C List of Included Studies

## C.1 Studies in Humans

Choe SA, Kauderer S, Eliot MN, Glazer KB, Kingsley SL, Carlson L, Awad YA, Schwartz JD, Savitz DA, Wellenius GA. 2018. Air pollution, land use, and complications of pregnancy. Sci Total Environ. 645:1057-1064. https://dx.doi.org/10.1016/j.scitotenv.2018.07.237

Dadvand P, Figueras F, Basagana X, Beelen R, Martinez D, Cirach M, Schembari A, Hoek G, Brunekreef B, Nieuwenhuijsen MJ. 2013. Ambient air pollution and preeclampsia: A spatiotemporal analysis. Environ Health Perspect. 121(11-12):1365-1371. https://dx.doi.org/10.1289/ehp.1206430

Huang X, Qiu J, Zhang Y, Qiu W, He X, Wang Y, Sun Q, Zhao N, Cui H, Liu S et al. 2015. Ambient air pollutant PM10 and risk of pregnancy-induced hypertension in urban China. Environ Res Lett. 10(8). 1 https://dx.doi.org/0.1088/1748-9326/10/8/084025

Madsen C, Haberg SE, Aamodt G, Stigum H, Magnus P, London SJ, Nystad W, Nafstad P. 2018. Preeclampsia and hypertension during pregnancy in areas with relatively low levels of traffic air pollution. Matern Child Health J. 22(4):512-519. https://dx.doi.org/10.1007/s10995-017-2417-6

Malmqvist E, Jakobsson K, Tinnerberg H, Rignell-Hydbom A, Rylander L. 2013. Gestational diabetes and preeclampsia in association with air pollution at levels below current air quality guidelines. Environ Health Perspect. 121(4):488-493. https://dx.doi.org/10.1289/ehp.1205736

Miranda ML, Edwards SE, Chang HH, Auten RL. 2013. Proximity to roadways and pregnancy outcomes. J Expo Sci Environ Epidemiol. 23(1):32-38. https://dx.doi.org/10.1038/jes.2012.78Olsson D, Mogren I, Eneroth K, Forsberg B. 2015. Traffic pollution at the home address and pregnancy outcomes in Stockholm, Sweden. Br Med J Open. 5(8):e007034. https://dx.doi.org/10.1136/bmjopen-2014-007034

Pedersen M, Halldorsson TI, Olsen SF, Hjortebjerg D, Ketzel M, Grandstrom C, Raaschou-Nielsen O, Sorensen M. 2017. Impact of road traffic pollution on pre-eclampsia and pregnancy-induced hypertensive disorders. Epidemiology. 28(1):99-106. https://dx.doi.org/10.1097/EDE.0000000000000555

Pereira G, Haggar F, Shand AW, Bower C, Cook A, Nassar N. 2013. Association between pre-eclampsia and locally derived traffic-related air pollution: A retrospective cohort study. J Epidemiol Community Health. 67(2):147-152. https://dx.doi.org/10.1136/jech-2011-200805

Rudra CB, Williams MA, Sheppard L, Koenig JQ, Schiff MA. 2011. Ambient carbon monoxide and fine particulate matter in relation to preeclampsia and preterm delivery in western Washington State. Environ Health Perspect. 119(6):886-892. https://dx.doi.org/10.1289/ehp.1002947

Savitz DA, Elston B, Bobb JF, Clougherty JE, Dominici F, Ito K, Johnson S, McAlexander T, Ross Z, Shmool JL et al. 2015. Ambient fine particulate matter, nitrogen dioxide, and hypertensive disorders of pregnancy in New York City. Epidemiology. 26(5):748-757. https://dx.doi.org/10.1097/EDE.0000000000000349

Sears CG, Braun JM, Ryan PH, Xu Y, Werner EF, Lanphear BP, Wellenius GA. 2018. The association of traffic-related air and noise pollution with maternal blood pressure and hypertensive disorders of pregnancy in the HOME study cohort. Environmental International. 121(Pt 1):574-581. https://dx.doi.org/10.1016/j.envint.2018.09.049

van den Hooven EH, Jaddoe VW, de Kluizenaar Y, Hofman A, Mackenbach JP, Steegers EA, Miedema HM, Pierik FH. 2009. Residential traffic exposure and pregnancy-related outcomes: A prospective birth cohort study. Environ Health. 8:59. https://dx.doi.org/10.1186/1476-069X-8-59

van den Hooven EH, de Kluizenaar Y, Pierik FH, Hofman A, van Ratingen SW, Zandveld PY, Mackenbach JP, Steegers EA, Miedema HM, Jaddoe VW. 2011. Air pollution, blood pressure, and the risk of hypertensive complications during pregnancy: The generation R study. Hypertension. 57(3):406-412. https://dx.doi.org/10.1161/HYPERTENSIONAHA.110.164087

Wu J, Wilhelm M, Chung J, Ritz B. 2011. Comparing exposure assessment methods for traffic-related air pollution in an adverse pregnancy outcome study. Environ Res. 111(5):685-692. https://dx.doi.org/10.1016/j.envres.2011.03.008

Wu M, Ries JJ, Proietti E, Vogt D, Hahn S, Hoesli I. 2016. Development of late-onset preeclampsia in association with road densities as a proxy for traffic-related air pollution. Fetal Diagn Ther. 39(1):21-27. https://dx.doi.org/10.1159/000381802

Yorifuji T, Naruse H, Kashima S, Murakoshi T, Doi H. 2015. Residential proximity to major roads and obstetrical complications. Sci Total Environ. 508:188-192. https://dx.doi.org/10.1016/j.scitotenv.2014.11.077

## C.2 Studies in Nonhuman Animals

Venditti CC, Casselman R, Young I, Karumanchi SA, Smith GN. 2014. Carbon monoxide prevents hypertension and proteinuria in an adenovirus sFlt-1 preeclampsia-like mouse model. PLoS One. 9(9). https://dx.doi.org/10.1371/journal.pone.0106502