# Appendix B Literature Search Strategy

The search terms for PubMed, Scopus, and Web of Science are provided below. The specific search strategies for other databases are available in the protocol ([underlined: Appendix G]).

Table B-1 Literature Search Strategy

Database | Set | Search Terms
PubMed | 1 | “air pollution”[mh:noexp] OR “air pollutants”[mh:noexp] OR ((“air pollution”[tiab] OR “air pollutant”[tiab] OR “air pollutants”[tiab]) NOT (indoor*[tiab] OR household[tiab])) OR “particulate matter”[mh:noexp] OR smog[mh] OR soot[mh] OR “particulate matter”[tiab] OR PM2.5[tiab] OR “PM(2.5)”[tiab] OR PM10[tiab] OR “PM(10)”[tiab] OR smog[tiab] OR soot[tiab] OR “carbon black”[tiab] OR “black carbon”[tiab] OR “elemental carbon”[tiab] OR ((air[tiab] OR airborne[tiab] OR coarse[tiab] OR ultrafine[tiab] OR fine[tiab]) AND (particle*[tiab] OR particulate*[tiab])) OR “vehicle emissions”[mh] OR motor vehicles[mh] OR ((vehicle[tiab] OR vehicles[tiab] OR vehicular[tiab] OR auto[tiab] OR automobile[tiab] OR bus[tiab] OR buses[tiab] OR car[tiab] OR truck*[tiab] OR engine[tiab] OR transport[tiab]) AND (emissions[tiab] OR exhaust[tiab] OR fume*[tiab])) OR (traffic[tiab] NOT (safety[tiab] OR accident*[tiab] OR injur*[tiab] OR collision*[tiab] OR crash*[tiab])) OR ((proximity OR near) AND (road*[tiab] OR highway*[tiab] OR freeway*[tiab] OR motorway*[tiab])) OR ((air[tiab] OR outdoor[tiab] OR ambient[tiab] OR pollut*[tiab] OR emissions[tiab] OR exhaust*[tiab]) AND (“sulfur dioxide”[mh] OR “sulfur dioxide”[tiab] OR S02[tiab] OR ozone[mh] OR ozone[tiab] OR O3[tiab] OR “hydrogen sulfide”[mh] OR “hydrogen sulfide”[tiab] OR H2S[tiab] OR “carbon monoxide”[mh] OR “carbon monoxide”[tiab] OR “nitric oxide”[tiab] OR “nitrogen oxide”[tiab] OR “nitrogen oxides”[tiab] OR “nitrogen dioxide”[mh] OR “nitrogen dioxide”[tiab] OR NOx [tiab] OR “NO(x)”[tiab] OR NO2[tiab])) OR “volatile organic compounds”[mh] OR “fossil fuels”[mh] OR “volatile organic compounds”[tiab] OR gasoline*[tiab] OR diesel[tiab] OR petrol*[tiab] OR Polycyclic hydrocarbons, aromatic[mh:noexp] OR “benzo(a)pyrene”[mh] OR benzene[mh] OR “polycyclic aromatic hydrocarbons”[tiab] OR “benzopyrene”[tiab] OR “benzo a pyrene”[tiab] OR “3,4-benzopyrene”[tiab] OR benzene[tiab]
PubMed | 2 | AND “Hypertension, Pregnancy-Induced”[Mesh] OR “Gestational Hypertension”[tiab] OR “pregnancyinduced hypertension”[tiab] OR (pregnan*[tiab] AND hypertens*[tiab]) OR pre-eclampsia[tiab] OR preeclampsia[tiab] OR (pregnan*[tiab] AND toxemia*[tiab])
Scopus | 1 | (((“air pollution” OR “air pollutant” OR “air pollutants”) AND NOT (indoor* OR household)) OR “particulate matter” OR PM2.5 OR PM10 OR smog OR soot OR “carbon black” OR “black carbon” OR “elemental carbon” OR ((air OR airborne OR coarse OR ultrafine OR fine) AND (particle* OR particulate*)) OR ((vehicle OR vehicles OR vehicular OR auto OR automobile OR bus OR buses OR car OR truck* OR engine OR transport) AND (emissions OR exhaust OR fume*)) OR (traffic AND NOT (safety OR accident* OR injur* OR collision* OR crash*)) OR ((proximity OR near) AND (road* OR highway* OR freeway* OR motorway*)) OR ((air OR outdoor OR ambient OR pollut* OR emissions OR exhaust*) AND (“sulfur dioxide” OR S02 OR ozone OR O3 OR “hydrogen sulfide” OR H2S OR “carbon monoxide” OR “nitric oxide” OR “nitrogen oxide” OR “nitrogen oxides” OR “nitrogen dioxide” OR NOx OR “NO(x)” OR NO2)) OR “volatile organic” OR “fossil fuel” OR “fossil fuels” OR gasoline* OR diesel OR petrol* OR “polycyclic aromatic hydrocarbons” OR “benzopyrene” OR “benzo a pyrene” OR “3,4-benzopyrene” OR benzene)
Scopus | 2 | AND (“Gestational Hypertension” OR “pregnancy-induced hypertension” OR (pregnan* w/8 hypertens*) OR pre-eclampsia OR preeclampsia OR (pregnan* w/8 toxemia*))
Web of Science | 1 | (((“air pollution” OR “air pollutant” OR “air pollutants”) NOT (indoor* OR household)) OR “particulate matter” OR PM2.5 OR “PM(2.5)” OR PM10 OR “PM(10)” OR smog OR soot OR “carbon black” OR “black carbon” OR “elemental carbon” OR ((air OR airborne OR coarse OR ultrafine OR fine) AND (particle* OR particulate*)) OR ((vehicle OR vehicles OR vehicular OR auto OR automobile OR bus OR buses OR car OR truck* OR engine OR transport) AND (emissions OR exhaust OR fume*)) OR (traffic NOT (safety OR accident* OR injur* OR collision* OR crash*)) OR ((proximity OR nearby) AND (road* OR highway* OR freeway* OR motorway*)) OR ((air OR outdoor OR ambient OR pollut* OR emissions OR exhaust*) AND (“sulfur dioxide” OR S02 OR ozone OR O3 OR “hydrogen sulfide” OR H2S OR “carbon monoxide” OR “nitric oxide” OR “nitrogen oxide” OR “nitrogen oxides” OR “nitrogen dioxide” OR NOx OR NO2)) OR “volatile organic” OR “fossil fuel” OR “fossil fuels” OR gasoline* OR diesel OR petrol* OR “polycyclic aromatic hydrocarbons” OR “benzopyrene” OR “benzo a pyrene” OR “3,4-benzopyrene” OR benzene)
Web of Science | 2 | AND (“Gestational Hypertension” OR “pregnancy-induced hypertension” OR (pregnan* near/8 hypertens*) OR pre-eclampsia OR preeclampsia OR (pregnan* near/8 toxemia*))