# Appendix A Data Figures

Figure A-1

NO_x_ Exposure and Hypertensive Disorders of Pregnancy in Humans

Results are indicated as significant if the associated confidence interval did not encompass 1.0, regardless of whether the study reported p values. Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/60/) (NTP, 2019a).