# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-5144

DOI: https://doi.org/10.22427/NTP-MGRAPH-6

Report Series: NTP Monograph Series

Report Series Number: 06

Official citation: National Toxicology Program (NTP). 2019. NTP monograph on the systematic review of long-term neurological effects of sarin. Research Triangle Park, NC: National Toxicology Program. NTP Monograph 06.