# Peer Review

The National Toxicology Program (NTP) convened a virtual external ad hoc panel to peer review the Draft NTP Monograph on Systematic Review of Long-term Neurological Effects Following Acute Exposure to the Organophosphorus Nerve Agent Sarin on February 4, 2019. NTP announced the peer-review meeting in the Federal Register (83 FR 63662, December 11, 2018, and 84 FR 368, January 25, 2019). The public could view the proceedings online and opportunities were provided for submission of written and oral public comments. The selection of panel members and conduct of the peer review were in accordance with federal policies and regulations. The panel was charged to:

1. Comment on whether the Draft NTP Monograph on Systematic Review of Long-term Neurological Effects Following Acute Exposure to the Organophosphorus Nerve Agent Sarin is technically correct, clearly stated, and objectively presented.
2. Vote on whether the scientific evidence from animal studies and from human studies supports the level of evidence conclusions regarding health effects following acute sarin exposure.
3. Vote on whether the scientific evidence supports NTP’s policy decisions for hazard categorization on long-term neurological effects following acute sarin exposure.

NTP carefully considered the panel’s recommendations in finalizing the monograph. The peer-review report is provided in Appendix G. Other meeting materials are available on the NTP website (https://ntp.niehs.nih.gov/go/meeting).

## Peer Reviewers

- Pam Factor-Litvak, Ph.D. (chair)
  Associate Dean for Research Resources, Professor, Epidemiology
  Columbia University Medical Center
  New York, New York, USA
- Frédéric Baud, M.D.
  Expert Consultant, Department of Anesthesiology and Intensive Care Medicine
  Université Paris Diderot, Assistance Publique – Hôpitaux de Paris
  Paris, France
- John Beard, Ph.D.
  Assistant Professor, Department of Public Health
  Brigham Young University
  Provo, Utah, USA
- Peter Blain, M.D.
  Researcher and Professor of Environmental Medicine
  Medical Toxicology Research Centre, Newcastle University
  Newcastle upon Tyne, England
- Michelle Block, Ph.D.
  Associate Professor, Department of Anatomy and Cell Biology
  Indiana University School of Medicine, Stark Neuroscience Research Institute
  Indianapolis, Indiana, USA
- Arik Eisenkraft, M.D.
  Adjunct Clinical Senior Lecturer in Military Medicine
  The Hebrew University Faculty of Medicine
  Tel-Mond, Israel
- Lawrence Engel, Ph.D.
  Associate Professor, Department of Epidemiology
  University of North Carolina at Chapel Hill
  Chapel Hill, North Carolina, USA
- Virginia Moser, Ph.D.
  Private Neurotoxicology Consultant Retired
  U.S. Environmental Protection Agency
  Apex, North Carolina, USA