# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Contributed to conception or design and contributed to drafting of protocol and report
  Andrew A. Rooney, Ph.D., Project Lead
- Assessed risk of bias and critically reviewed draft report
  Kyla W. Taylor, Ph.D.
- Developed figures and critically reviewed draft report
  Vickie R. Walker, B.S.
- National Institute of Neurological Disorders and Stroke, National Institutes of Health, Bethesda, Maryland, USA
  Contributed to conception or design and contributed to drafting protocol and report
  David A. Jett, Ph.D., Project Co-lead
- ICF, Durham, North Carolina, USA
  Screened studies, extracted data, assessed risk of bias, and contributed to drafting report
  Robyn B. Blain, Ph.D.
  Christopher A. Sibrizzi, M.P.H., Lead Work Assignment Manager
- Extracted data, developed visualizations, and contributed to drafting report
  Pamela A. Hartman, M.E.M.
- University of California Davis School of Veterinary Medicine, Davis, California, USA
  Contributed to conception or design and contributed to drafting protocol and report
  Pamela J. Lein, Ph.D.