# References

Abou-Donia MB, Dechkovskaia AM, Goldstein LB, Bullman SL, Khan WA. 2002. Sensorimotor deficit and cholinergic changes following coexposure with pyridostigmine bromide and sarin in rats. Toxicol Sci. 66(1):148–158. 10.1093/toxsci/66.1.148 11861982
Abou-Donia MB, Siracuse B, Gupta N, Sobel Sokol A. 2016. Sarin (GB, O-isopropyl methylphosphonofluoridate) neurotoxicity: Critical review. Crit Rev Toxicol. 46(10):845–875. 10.1080/10408444.2016.1220916 27705071
Abu-Qare AW, Abou-Donia MB. 2002. Sarin: Health effects, metabolism, and methods of analysis. Food Chem Toxicol. 40(10):1327–1333. 10.1016/S0278-6915(02)00079-0 12387297
Agency for Toxic Substances and Disease Registry (ATSDR).2011. Nerve Agents (GA, GB, GD, VX). Atlanta, GA: US Department of Health and Human Services.https://www.atsdr.cdc.gov/substances/toxsubstance.asp?toxid=93. [Accessed: Jul 25 2017]
Allon N, Chapman S, Egoz I, Rabinovitz I, Kapon J, Weissman BA, Yacov G, Bloch-Shilderman E, Grauer E. 2011. Deterioration in brain and heart functions following a single sub-lethal (0.8 LCt50) inhalation exposure of rats to sarin vapor: A putative mechanism of the long term toxicity. Toxicol Appl Pharmacol. 253(1):31–37. 10.1016/j.taap.2011.03.007 21419149
Augerson WS.2000. A review of the scientific literature as it pertains to Gulf War illnesses. Volume 5: Chemical and biological warfare agents. RAND Corporation.
Baker DJ, Sedgwick EM. 1996. Single fibre electromyographic changes in man after organophosphate exposure. Hum Exp Toxicol. 15(5):369–375. 10.1177/096032719601500501 8735458
Bansal I, Waghmare CK, Anand T, Gupta AK, Bhattacharya BK. 2009. Differential mRNA expression of acetylcholinesterase in the central nervous system of rats with acute and chronic exposure of sarin & physostigmine. J Appl Toxicol. 29(5):386–394. 10.1002/jat.1424 19283689
Bhardwaj S, Musalgaonkar N, Waghmare C, Bhattacharya BK. 2012. Single dose exposure of sarin and physostigmine differentially regulates expression of choline acetyltransferase and vesicular acetylcholine transporter in rat brain. Chem Biol Interact. 198(1-3):57–64. 10.1016/j.cbi.2012.05.002 22640809
Bielavska M, Kassa J. 2000. Simultaneous determination of dopamine, serotonin and their metabolites in the rat brain by HPLC method with coulometric detection. Collect Czech Chem Commun. 65(10):1677–1682.10.1135/cccc20001677
Binns JH, Cherry N, Golomb BA, Graves JC, Haley RW, Knox ML, Meggs WJ, Pellier PJ, Robinson SL, Smithson S, et al.2004. Scientific progress in understanding Gulf War veterans' illnesses: Report and recommendations. San Francisco, CA: Research Advisory Committee on Gulf War Veterans' Illnesses.
Bloch-Shilderman E, Kadar T, Levy A, Sahar R, Rabinovitz I, Gilat E. 2005. Subcellular alterations of protein kinase C isozymes in the rat brain after organophosphate poisoning. J Pharmacol Exp Ther. 313(3):1082–1089. 10.1124/jpet.105.083469 15716382
Brown M. 2009. Military chemical warfare agent human subjects testing: Part 2— Long-term health effects among participants of US military chemical warfare agent testing. Mil Med. 174(10):1049–1054. 10.7205/MILMED-D-04-8408 19891216
Brown MA, Brix KA.1998. Review of health consequences from high‐, intermediate‐and low‐level exposure to organophosphorus nerve agents. J Appl Toxicol. 18(6):393-408. 10.1002/(SICI)1099-1263(199811/12)18:6<393:AID-JAT528>3.0.CO;2-0
Burchfiel JL, Duffy FH. 1982. Organophosphate neurotoxicity: Chronic effects of sarin on the electroencephalogram of monkey and man. Neurobehav Toxicol Teratol. 4(6):767–778. 7170041
Chaubey K, Alam SI, Nagar DP, Waghmare CK, Pant SC, Singh L, Srivastava N, Bhattacharya BK. 2017. From the cover: Proteome profile of different rat brain regions after sarin intoxication. Toxicol Sci. 160(1):136–149. 10.1093/toxsci/kfx162 28973502
Chaubey K, Rao MK, Alam SI, Waghmare C, Bhattacharya BK. 2016. Increased expression of immune modulator proteins and decreased expression of apolipoprotein A-1 and haptoglobin in blood plasma of sarin exposed rats. Chem Biol Interact. 246:36–44. 10.1016/j.cbi.2016.01.008 26778279
Chen Y. 2012. Organophosphate-induced brain damage: Mechanisms, neuropsychiatric and neurological consequences, and potential therapeutic strategies. Neurotoxicology. 33:391–400. 10.1016/j.neuro.2012.03.011 22498093
Damodaran TV, Jones KH, Patel AG, Abou-Donia MB. 2003. Sarin (nerve agent GB)-induced differential expression of mRNA coding for the acetylcholinesterase gene in the rat central nervous system. Biochem Pharmacol. 65(12):2041–2047. 10.1016/S0006-2952(03)00160-6 12787884
Defense Science Board.1994. Report of the Defense Science Board Task Force on Persian Gulf War health effects. Washington, DC.http://www.dtic.mil/dtic/tr/fulltext/u2/a281449.pdf.
Deshpande LS, Blair RE, Phillips KF, DeLorenzo RJ. 2016. Role of the calcium plateau in neuronal injury and behavioral morbidities following organophosphate intoxication. Ann N Y Acad Sci. 1374(1):176–183. 10.1111/nyas.13122 27327161
Egoz I, Nili U, Grauer E, Gore A. 2017. Optimization of the ocular treatment following organophosphate nerve agent insult. Toxicol Sci. 159(1):50–63. 10.1093/toxsci/kfx119 28903494
Fu R, Gartlehner G, Grant M, Shamliyan T, Sedrakyan A, Wilt TJ, Griffith L, Oremus M, Raina P, Ismaila A. 2011. Conducting quantitative synthesis when comparing medical interventions: AHRQ and the Effective Health Care Program. J Clin Epidemiol. 64(11):1187–1197. 10.1016/j.jclinepi.2010.08.010 21477993
Gais S, Schonauer M. 2017. Untangling a cholinergic pathway from wakefulness to memory. Neuron. 94(4):696–698. 10.1016/j.neuron.2017.05.010 28521121
Genovese RF, Benton BJ, Oubre JL, Fleming PJ, Jakubowski EM, Mioduszewski RJ. 2008. Determination of miosis threshold from whole-body vapor exposure to sarin in African green monkeys. Toxicology. 244(2-3):123–132. 10.1016/j.tox.2007.11.004 18096290
Genovese RF, Mioduszewski RJ, Benton BJ, Pare MA, Cooksey JA. 2009. Behavioral evaluation of rats following low-level inhalation exposure to sarin. Pharmacol Biochem Behav. 91(4):517–525. 10.1016/j.pbb.2008.09.006 18835292
Genovese RF, Oubre JL, Jakubowski EM, Fleming PJ, Saxena A, Rockwood GA, Tipparaju P, Willmore CB. 2007. Evaluation of cognitive and biochemical effects of low-level exposure to sarin in rhesus and African green monkeys. Toxicology. 231(1):11–20. 10.1016/j.tox.2006.10.018 17126468
Germain CM, Batsis JA, Vasquez E, McQuoid DR.2016. Muscle strength, physical activity, and functional limitations in older adults with central obesity. J Aging Res. 2016:5. 10.1155/2016/8387324
Gore A, Brandeis R, Egoz I, Peri D, Turetz J, Bloch-Shilderman E. 2012. Efficacy assessment of various anticholinergic agents against topical sarin-induced miosis and visual impairment in rats. Toxicol Sci. 126(2):515–524. 10.1093/toxsci/kfs009 22247005
Grauer E, Chapman S, Rabinovitz I, Raveh L, Weissman BA, Kadar T, Allon N. 2008. Single whole-body exposure to sarin vapor in rats: Long-term neuronal and behavioral deficits. Toxicol Appl Pharmacol. 227(2):265–274. 10.1016/j.taap.2007.11.006 18164360
Grob D. 1956. The manifestations and treatment of poisoning due to nerve gas and other organic phosphate anticholinesterase compounds. AMA Arch Intern Med. 98(2):221–239. 10.1001/archinte.1956.00250260095010 13354016
Grob D, Harvey JC. 1958. Effects in man of the anticholinesterase compound sarin (isopropyl methyl phosphonofluoridate). J Clin Invest. 37(3):350–368. 10.1172/JCI103615 13513766
Gunderson CH, Lehmann CR, Sidell FR, Jabbari B. 1992. Nerve agents. Rev Neurol. 42(5):946–950. 10.1212/WNL.42.5.946 1315942
Gupta RC. 2015. Handbook of toxicology of chemical warfare agents. London, UK: Academic Press.
Gupta RC, Patterson GT, Dettbarn WD. 1991. Comparison of cholinergic and neuromuscular toxicity following acute exposure to sarin and VX in rat. Fundam Appl Toxicol. 16(3):449–458. 10.1016/0272-0590(91)90085-I 1855618
Guyatt G, Oxman AD, Akl EA, Kunz R, Vist G, Brozek J, Norris S, Falck-Ytter Y, Glasziou P, Jaeschke R. 2011. GRADE guidelines: 1. Introduction—GRADE evidence profiles and summary of findings tables. J Clin Epidemiol. 64(4):383–394. 10.1016/j.jclinepi.2010.04.026 21195583
Hargreaves AJ. 2012. Neurodegenerations induced by organophosphorous compounds. Neurodegenerative Diseases Advances in Experimental Medicine and Biology. New York, NY: Springer.
Higgins JPT, Green S. 2011. Cochrane handbook for systematic reviews of interventions. The Cochrane Collaboration. John Wiley & Sons.
Himuro K, Murayama S, Nishiyama K, Shinoe T, Iwase H, Nagao M, Takatori T, Kanazawa I. 1998. Distal sensory axonopathy after sarin intoxication. Neurology. 51(4):1195–1197. 10.1212/WNL.51.4.1195 9781559
Institute of Medicine (IOM).2004. Gulf War and health: Updated literature review of sarin. Washington, DC: Institute of Medicine.https://www.ncbi.nlm.nih.gov/pubmed/25009884. [Accessed: Feb 20 2017]
Jones KH, Dechkovskaia AM, Herrick EA, Abdel RAA, Khan WA, Abou Donia MB. 2000. Subchronic effects following a single sarin exposure on blood-brain and blood-testes barrier permeability, acetylcholinesterase, and acetylcholine receptors in the central nervous system of rat: A dose-response study. J Toxicol Environ Health A. 61(8):695–707. 10.1080/00984100050195161 11132698
Kadar T, Shapira S, Cohen G, Sahar R, Alkalay D, Raveh L. 1995. Sarin-induced neuropathology in rats. Hum Exp Toxicol. 14(3):252–259. 10.1177/096032719501400304 7779455
Kassa J, Koupilova M, Herink J, Vachek J. 2001 a. The long-term influence of low-level sarin exposure on behavioral and neurophysiological functions in rats. Acta Med (Hradec Kralove). 44(1):21–27. 10.14712/18059694.2019.82 11367887
Kassa J, Koupilova M, Vachek J. 2001 b. Long-term effects of low-level sarin inhalation exposure on the spatial memory of rats in a T-maze. Acta Med (Hradec Kralove). 44(3):93–96. 10.14712/18059694.2019.91 11811083
Kassa J, Krejcova G, Skopec F, Herink J, Bajgar J, Sevelova L, Tichy M, Pecka M. 2004. The influence of sarin on various physiological functions in rats following single or repeated low-level inhalation exposure. Inhal Toxicol. 16(8):517–530. 10.1080/08958370490442494 15204743
Kassa J, Krejcova G, Vachek J. 2002. The impairment of spatial memory following low-level sarin inhalation exposure and antidotal treatment in rats. Acta Med (Hradec Kralove). 45(4):149–153. 10.14712/18059694.2019.72 12587782
Kassa J, Pecka M, Tichy M, Bajgar J, Koupilova M, Herink J, Krocova Z. 2001 c. Toxic effects of sarin in rats at three months following single or repeated low-level inhalation exposure. Pharmacol Toxicol. 88(4):209–212. 10.1034/j.1600-0773.2001.d01-106.x 11322180
Kawabuchi M, Cintra WM, Deshpande SS, Albuquerque EX. 1991. Morphological and electrophysiological study of distal motor nerve fiber degeneration and sprouting after irreversible cholinesterase inhibition. Synapse. 8(3):218–228. 10.1002/syn.890080308 1948671
Kawana N, Ishimatsu S, Kanda K. 2001. Psycho-physiological effects of the terrorist sarin attack on the Tokyo subway system. Mil Med. 166(12) Suppl:23–26. 10.1093/milmed/166.suppl_2.23 11778423
Koelle GB, Koelle WA, Smyrl EG. 1977. Effects of inactivation of butyrylcholinesterase on steady state and regenerating levels of ganglionic acetylcholinesterase. J Neurochem. 28(2):313–319. 10.1111/j.1471-4159.1977.tb07750.x 839215
Lazar S, Egoz I, Brandeis R, Chapman S, Bloch-Shilderman E, Grauer E. 2016. Propagation of damage in the rat brain following sarin exposure: Differential progression of early processes. Toxicol Appl Pharmacol. 310:87–97. 10.1016/j.taap.2016.09.008 27639427
Leblanc A, Taylor BA, Thompson PD, Capizzi JA, Clarkson PM, White CM, Pescatello LS. 2015. Relationships between physical activity and muscular strength among healthy adults across the lifespan. Springerplus. 4(1):557. 10.1186/s40064-015-1357-0 26435903
Lee EC. 2003. Clinical manifestations of sarin nerve gas exposure. JAMA. 290(5):659–662. 10.1001/jama.290.5.659 12902371
Lee K, Bohnert S, Wu Y, Vair C, Mikler J, Campbell Teskey G, Dunn JF. 2018. Assessment of brain oxygenation imbalance following soman exposure in rats. Neurotoxicology. 65:28–37. 10.1016/j.neuro.2018.01.007 29378300
Little PJ, Reynolds ML, Bowman ER, Martin BR. 1986. Tissue disposition of [3H]sarin and its metabolites in mice. Toxicol Appl Pharmacol. 83(3):412–419. 10.1016/0041-008X(86)90223-1 3705071
Loh Y, Swanberg MM, Ingram MV, Newmark J. 2010. Case report: Long-term cognitive sequelae of sarin exposure. Neurotoxicology. 31(2):244–246. 10.1016/j.neuro.2009.12.004 20036279
Miller A, Birnbaum L. 2015. Preparing for disasters. Science. 348(6236):766–767. 10.1126/science.348.6236.766-c 25977543
Mioduszewski R, Manthei J, Way R, Burnett D, Gaviola B, Muse W, Thomson S, Sommerville D, Crosier R. 2002. Interaction of exposure concentration and duration in determining acute toxic effects of sarin vapor in rats. Toxicol Sci. 66(2):176–184. 10.1093/toxsci/66.2.176 11896284
Miyaki K, Nishiwaki Y, Maekawa K, Ogawa Y, Asukai N, Yoshimura K, Etoh N, Matsumoto Y, Kikuchi Y, Kumagai N, 2005. Effects of sarin on the nervous system of subway workers seven years after the Tokyo subway sarin attack. J Occup Health. 47(4):299–304. 10.1539/joh.47.299 16096354
Moher D, Liberati A, Tetzlaff J, Altman DG. 2009. Preferred reporting items for systematic reviews and meta-analyses: The PRISMA statement. PLoS Med. 6(7):e1000097. 10.1371/journal.pmed.1000097 19621072
Morita H, Yanagisawa N, Nakajima T, Shimizu M, Hirabayashi H, Okudera H, Nohara M, Midorikawa Y, Mimura S. 1995. Sarin poisoning in Matsumoto, Japan. Lancet. 346(8970):290–293. 10.1016/S0140-6736(95)92170-2 7630252
Muggleton NG, Bowditch AP, Crofts HS, Scott EA, Pearce PC. 2003. Assessment of a combination of physostigmine and scopolamine as pretreatment against the behavioural effects of organophosphates in the common marmoset (Callithrix jacchus). Psychopharmacology (Berl). 166(3):212–220. 10.1007/s00213-002-1324-7 12589520
Munroe NB, Talmage SS, Griffin GD, Waters LC, King JF, Hauschild V. 1999. The sources, fate, and toxicity of chemical warfare agent degradation products. Environ Health Perspect. 107:933–974. 10.1289/ehp.99107933 10585900
Murata K, Araki S, Yokoyama K, Okumura T, Ishimatsu S, Takasu N, White RF. 1997. Asymptomatic sequelae to acute sarin poisoning in the central and autonomic nervous system 6 months after the Tokyo subway attack. J Neurol. 244(10):601–606. 10.1007/s004150050153 9402534
Nakajima T, Ohta S, Fukushima Y, Yanagisawa N. 1999. Sequelae of sarin toxicity at one and three years after exposure in Matsumoto, Japan. J Epidemiol. 9(5):337–343. 10.2188/jea.9.337 10616267
Nakajima T, Ohta S, Morita H, Midorikawa Y, Mimura S, Yanagisawa N. 1998. Epidemiological study of sarin poisoning in Matsumoto City, Japan. J Epidemiol. 8(1):33–41. 10.2188/jea.8.33 9575693
Namba T, Nolte CT, Jackrel J, Grob D. 1971. Poisoning due to organophosphate insecticides: Acute and chronic manifestations. Am J Med. 50(4):475–492. 10.1016/0002-9343(71)90337-8 4324629
National Research Council (NRC).1997. Review of acute human-toxicity estimates for selected chemical-warfare agents. Washington, DC: National Research Council.https://www.nap.edu/catalog/5825/review-of-acute-human-toxicity-estimates-for-selected-chemical-warfare-agents. [Accessed: Jan 15 2017]
National Toxicology Program (NTP).2015. Handbook for conducting a literature-based health assessment using OHAT approach for systematic review and evidence integration. Research Triangle Park, NC: National Institute of Environmental Health Sciences, National Toxicology Program, Office of Health Assessment and Translation.https://ntp.niehs.nih.gov/go/38673. [Accessed: 25 Jan 2016]
National Toxicology Program (NTP).2019a. Handbook for conducting a literature-based health assessment using OHAT approach for systematic review and evidence integration. Research Triangle Park, NC: National Institute of Environmental Health Sciences, National Toxicology Program, Office of Health Assessment and Translation.https://ntp.niehs.nih.gov/go/systematic_review. [Accessed: 29 March 2019]
National Toxicology Program (NTP).2019b. Health Assessment Workspace Collaborative (HAWC) page on sarin.https://hawcproject.org/assessment/302/.
National Toxicology Program (NTP).2019c. MGRAPH-6: Sarin: Potential long-term neurological effects supplementary files. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program.10.22427/NTP-DATA-MGRAPH-6
National Toxicology Program (NTP).2019d. Updates and clarification to the OHAT approach for systematic review and evidence integration. Research Triangle Park, NC: National Institute of Environmental Health Sciences, National Toxicology Program, Office of Health Assessment and Translation.https://ntp.niehs.nih.gov/go/systematic_review. [Accessed: 29 March 2019]
Nieminen SA, Lecklin A, Heikkinen O, Ylitalo P. 1990. Acute behavioural effects of the organophosphates sarin and soman in rats. Pharmacol Toxicol. 67(1):36–40. 10.1111/j.1600-0773.1990.tb00778.x 2395814
Nishiwaki Y, Maekawa K, Ogawa Y, Asukai N, Minami M, Omae K. 2001. Effects of sarin on the nervous system in rescue team staff members and police officers 3 years after the Tokyo subway sarin attack. Environ Health Perspect. 109(11):1169–1173. 10.1289/ehp.011091169 11713003
Nohara M, Segawa K. 1996. Ocular symptoms due to organophosphorus gas (Sarin) poisoning in Matsumoto. Br J Ophthalmol. 80(11):1023. 10.1136/bjo.80.11.1023 8976734
Ogawa Y, Yamamura Y, Ando H, Kadokura M, Agata T, Fukumoto M, Satake T, Machida K, Sakai O, Miyata Y, et al.1999. An attack with sarin nerve gas on the Tokyo subway system and its effects on victims. ACS Symp Ser. 745:333-355. 10.1021/bk-2000-0745.ch022
Ohbu S, Yamashina A, Takasu N, Yamaguchi T, Murai T, Nakano K, Matsui Y, Mikami R, Sakurai K, Hinohara S. 1997. Sarin poisoning on Tokyo subway. South Med J. 90(6):587–593. 10.1097/00007611-199706000-00002 9191733
Ohtani T, Iwanami A, Kasai K, Yamasue H, Kato T, Sasaki T, Kato N. 2004. Post-traumatic stress disorder symptoms in victims of Tokyo subway attack: A 5-year follow-up study. Psychiatry Clin Neurosci. 58(6):624–629. 10.1111/j.1440-1819.2004.01313.x 15601387
Ohtomi S, Takase M, Kumagai F. 1996. Sarin poisoning in Japan. A clinical experience in Japan Self Defense Force (JSDF) Central Hospital. Rev Int Serv Sante Forces Armees. 69(4-6):97–102.
Okudera H. 2002. Clinical features on nerve gas terrorism in Matsumoto. J Clin Neurosci. 9(1):17–21. 10.1054/jocn.2001.1020 11749011
Okumura T, Hisaoka T, Naito T, Isonuma H, Okumura S, Miura K, Maekawa H, Ishimatsu S, Takasu N, Suzuki K. 2005. Acute and chronic effects of sarin exposure from the Tokyo subway incident. Environ Toxicol Pharmacol. 19(3):447–450. 10.1016/j.etap.2004.12.005 21783510
Okumura T, Takasu N, Ishimatsu S, Miyanoki S, Mitsuhashi A, Kumada K, Tanaka K, Hinohara S. 1996. Report on 640 victims of the Tokyo subway sarin attack. Ann Emerg Med. 28(2):129–135. 10.1016/S0196-0644(96)70052-5 8759575
Pearce PC, Crofts HS, Muggleton NG, Ridout D, Scott EA. 1999. The effects of acutely administered low dose sarin on cognitive behaviour and the electroencephalogram in the common marmoset. J Psychopharmacol. 13(2):128–135. 10.1177/026988119901300203 10475717
Pearson JN, Patel M. 2016. The role of oxidative stress in organophosphate and nerve agent toxicity. Ann N Y Acad Sci. 1378(1):17–24. 10.1111/nyas.13115 27371936
Pomara C, Neri M, Bello S, Fiore C, Riezzo I, Turillazzi E. 2015. Neurotoxicity by synthetic androgen steroids: Oxidative stress, apoptosis, and neuropathology: A review. Curr Neuropharmacol. 13(1):132–145. 10.2174/1570159X13666141210221434 26074748
Pope CN.2006. Chapter 20 – Central nervous system effects and neurotoxicity. Toxicology of Organophosphate and Carbamate Compounds. p. 271-291.
RamaRao G.Acharya JN, Bhattacharya BK. 2011. Changes of protein oxidation, calpain and cytoskeletal proteins (alpha tubulin and pNF-H) levels in rat brain after nerve agent poisoning. Toxicol Lett. 203(3):227-236. 10.1016/j.toxlet.2011.03.020
Ray DE. 1998. Chronic effects of low level exposure to anticholinesterases—a mechanistic review. Toxicol Lett. 102-103:527–533. 10.1016/S0378-4274(98)00260-4 10022307
Raz L, Knoefel J, Bhaskar K. 2016. The neuropathology and cerebrovascular mechanisms of dementia. J Cereb Blood Flow Metab. 36(1):172–186. 10.1038/jcbfm.2015.164 26174330
Rengstorff RH. 1985. Accidental exposure to sarin: Vision effects. Arch Toxicol. 56(3):201–203. 10.1007/BF00333427 3977601
Rooney AA, Boyles AL, Wolfe MS, Bucher JR, Thayer KA. 2014. Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 122(7):711–718. 10.1289/ehp.1307972 24755067
Rooney AA, Cooper GS, Jahnke GD, Lam J, Morgan RL, Ratcliffe JM, Kraft AD, Schünemann HJ, Schwingl P, Walker TD, 2016. How credible are the study results? Evaluating and applying internal validity tools to literature-based assessments of environmental health hazards. Environ Int. 92-93:617–629. 10.1016/j.envint.2016.01.005 26857180
Scaife JF, Shuster J. 1960. Tissue cholinesterase levels in sarin poisoning. Can J Biochem Physiol. 38:1087–1093. 10.1139/o60-135 13747022
Sekijima Y, Morita H, Shindo M, Okudera H, Shibata T. 1995. [A case of severe sarin poisoning in the sarin attack in Matsumoto--one-year follow-up of clinical findings, and laboratory data]. Rinsho Shinkeigaku. 35(11):1241–1245. 8720336
Sekijima Y, Morita H, Yanagisawa N. 1997. Follow-up of sarin poisoning in Matsumoto. Ann Intern Med. 127(11):1042. 10.7326/0003-4819-127-11-199712010-00028 9412293
Sellström A, Cairns S, Barbeschi M. 2013. United Nations mission to investigate allegations of the use of chemical weapons in the Syrian Arab Republic: Report on the alleged use of chemical weapons in the Ghouta Area of Damascus on 21 August 2013. United Nations.
Sidell FR. 1974. Soman and sarin: Clinical manifestations and treatment of accidental poisoning by organophosphates. Clin Toxicol. 7(1):1–17. 10.3109/15563657408987971 4838227
Singer AW, Jaax NK, Graham JS, McLeod CG Jr. 1987. Cardiomyopathy in soman and sarin intoxicated rats. Toxicol Lett. 36(3):243–249. 10.1016/0378-4274(87)90192-5 3590220
Spradling KD, Dillman JF. 2011. The molecular toxicology of chemical warfare nerve agents. Advances in Molecular Toxicology; Chapter 3; p. 111–144. 10.1016/B978-0-444-53864-2.00003-7
Stockholm International Peace Research Institute (SIPRI).1975. Delayed toxic effects of chemical warfare agents. Stockholm International Peace Research Institute. 9185114294
Suzuki J, Kohno T, Tsukagosi M, Furuhata T, Yamazaki K. 1997. Eighteen cases exposed to sarin in Matsumoto, Japan. Intern Med. 36(7):466–470. 10.2169/internalmedicine.36.466 9240494
Tochigi M, Otani T, Yamasue H, Kasai K, Kato T, Iwanami A, Kato N, Sasaki T. 2005. Support for relationship between serum cholinesterase and post-traumatic stress disorder; 5-year follow-ups of victims of the Tokyo subway sarin poisoning. Neurosci Res. 52(2):129–131. 10.1016/j.neures.2005.03.012 15876465
Tochigi M, Umekage T, Otani T, Kato T, Iwanami A, Asukai N, Sasaki T, Kato N. 2002. Serum cholesterol, uric acid and cholinesterase in victims of the Tokyo subway sarin poisoning: A relation with post-traumatic stress disorder. Neurosci Res. 44(3):267–272. 10.1016/S0168-0102(02)00146-3 12413655
Tokuda Y, Kikuchi M, Takahashi O, Stein GH. 2006. Prehospital management of sarin nerve gas terrorism in urban settings: 10 years of progress after the Tokyo subway sarin attack. Resuscitation. 68(2):193–202. 10.1016/j.resuscitation.2005.05.023 16325985
Tonni G, Leoncini S, Signorini C, Ciccoli L, De Felice C. 2014. Pathology of perinatal brain damage: Background and oxidative stress markers. Arch Gynecol Obstet. 290(1):13–20. 10.1007/s00404-013-2899-4 24643805
Tripathi HL, Dewey WL. 1989. Comparison of the effects of diisopropylfluorophosphate, sarin, soman, and tabun on toxicity and brain acetylcholinesterase activity in mice. J Toxicol Environ Health. 26(4):437–446. 10.1080/15287398909531267 2709438
Whalley CE, Shih TM. 1989. Effects of soman and sarin on high affinity choline uptake by rat brain synaptosomes. Brain Res Bull. 22(5):853–858. 10.1016/0361-9230(89)90030-0 2765946
White RF, Steele L, O’Callaghan JP, Sullivan K, Binns JH, Golomb BA, Bloom FE, Bunker JA, Crawford F, Graves JC. 2016. Recent research on Gulf War illness and other health problems in veterans of the 1991 Gulf War: Effects of toxicant exposures during deployment. Cortex. 74:449–475. 10.1016/j.cortex.2015.08.022 26493934
Wolthuis OL, Groen B, Busker RW, van Helden H. 1995. Effects of low doses of cholinesterase inhibitors on behavioral performance of robot-tested marmosets. Pharmacol Biochem Behav. 51(2-3):443–456. 10.1016/0091-3057(95)00006-I 7667367
Yamasue H, Abe O, Kasai K, Suga M, Iwanami A, Yamada H, Tochigi M, Ohtani T, Rogers MA, Sasaki T, 2007. Human brain structural change related to acute single exposure to sarin. Ann Neurol. 61(1):37–46. 10.1002/ana.21024 17187377
Yanagisawa N, Morita H, Nakajima T. 2006. Sarin experiences in Japan: Acute toxicity and long-term effects. J Neurol Sci. 249(1):76–85. 10.1016/j.jns.2006.06.007 16962140
Yokoyama K, Araki S, Murata K, Nishikitani M, Okumura T, Ishimatsu S, Takasu N. 1998 a. Chronic neurobehavioral and central and autonomic nervous system effects of Tokyo subway sarin poisoning. J Physiol Paris. 92(3-4):317–323. 10.1016/S0928-4257(98)80040-5 9789830
Yokoyama K, Araki S, Murata K, Nishikitani M, Okumura T, Ishimatsu S, Takasu N. 1998 b. A preliminary study on delayed vestibulo-cerebellar effects of Tokyo Subway Sarin Poisoning in relation to gender difference: Frequency analysis of postural sway. J Occup Environ Med. 40(1):17–21. 10.1097/00043764-199801000-00006 9467116
Yokoyama K, Araki S, Murata K, Nishikitani M, Okumura T, Ishimatsu S, Takasu N, White RF. 1998 c. Chronic neurobehavioral effects of Tokyo subway sarin poisoning in relation to posttraumatic stress disorder. Arch Environ Health. 53(4):249–256. 10.1080/00039899809605705 9709988