# Conclusions

Hazard conclusions were considered for the four main health effect categories at all three time periods after exposure. The conclusions with the highest level of evidence for each time period were used to reach the overall conclusions. NTP concludes that acute sarin exposure is known to be a neurological hazard to humans for effects in the initial period of 1–7 days after exposure based on ChE data. NTP concludes that acute sarin exposure is suspected to be a neurological hazard to humans for multiple effects in the intermediate period of 1 week to 12 months after exposure based on the ChE, visual and ocular, and morphology and histological data. NTP concludes that acute sarin exposure is suspected to be a neurological hazard to humans for multiple effects in the extended period ≥1 year after exposure based on learning and memory and morphology and histological data.

This evaluation identified data gaps that contribute to lower confidence in the bodies of evidence for some endpoints and time periods. Multiple other symptoms and neurological effects have been reported in the days, months, and years after acute sarin exposure, but the evidence was inadequate to reach a hazard conclusion. Future targeted research to assess the long-term neurological effects of sarin exposure could help to address areas with lower confidence, including the use of well-characterized human exposure data with neurological tests compared to a control population and research in animal models addressing the inconsistencies and key data gaps identified in this review using study design and conduct practices to minimize bias. Given the breadth of health effect data supporting the hazard conclusions, potential endpoints identified for further research include ChE, visual and ocular effects, effects on learning and memory, and morphological and histological changes in nervous system tissues.