# Discussion

The systematic review of the evidence led NTP to reach conclusions on long-term neurotoxicity following acute sarin exposure that are specific for the length of time following sarin exposure. NTP concludes that sarin is known to be a neurological hazard to humans in the initial time period (>24 hours–7 days) after exposure based on a high level of evidence that sarin inhibits cholinesterase (ChE) in the days after exposure in humans and a moderate level of evidence in the animal studies in the same time period. NTP concludes that sarin is suspected to be a neurological hazard to humans in the intermediate time period (8 days–1 year) after exposure based on ChE (inadequate level of evidence from studies in humans and moderate level of evidence from studies in animals); visual and ocular (moderate level of evidence from studies in humans and inadequate level of evidence from studies in animals); and morphology and histological changes (inadequate level of evidence from studies in humans and moderate level of evidence from studies in animals). NTP concludes that sarin is suspected to be a neurological hazard to humans in the extended time period (≥1 year) after exposure based on learning, memory, and intelligence (moderate level of evidence from studies in humans and inadequate level of evidence from studies in animals); and morphology and histological changes (moderate level of evidence from studies in humans and inadequate level of evidence from studies in animals). These conclusions represent the bodies of evidence with the greatest confidence and therefore the strongest conclusions for each time period after exposure. There is additional weaker or limited evidence of other sensory effects, self-reported symptoms (including but not limited to sleep disruption, depression, anxiety, and fear), and activity and strength, supported by some evidence of disruption in electroencephalograms (EEGs) (see Appendix E). Although biological plausibility of effects was considered, mechanistic data did not significantly impact the conclusions. The mechanism(s) of long-term neurological effects of sarin are not clearly understood.

The high level of evidence in the human data was primarily based on controlled trials with support from case report studies. Although there were risk-of-bias concerns in the controlled trials (i.e., lack of reporting for the key risk-of-bias questions regarding outcome assessment and, in one study, randomization and exposure characterization), these studies provided evidence of a large magnitude of effect, which increased the confidence in the body of evidence and resulted in a high level of evidence. The moderate level of evidence in the human data was primarily based on cross-sectional studies that did not have serious risk-of-bias concerns. Although the human body of evidence mainly consisted of case reports and case series, there were sufficient cross-sectional studies with supporting evidence from the case reports/series to reach a moderate level of evidence. The moderate level of evidence from animal studies is supported by moderate confidence in the body of evidence from animal studies of sarin exposure on ChE and morphology and histopathology. These confidence ratings are based on results that consistently showed an effect during a specific time period after exposure. Animal data were limited mainly due to the heterogeneity of the outcomes measured. In addition, the animal data generally had serious risk-of-bias issues related to lack of information provided on randomization, blinding of outcome assessor, and exposure assessment.

The systematic review format in this evaluation adds transparency (e.g., clear statement of the objective, PECO criteria, and literature search terms) and rigor (e.g., risk-of-bias assessment of individual studies) to the process for reviewing evidence of long-term neurological effects of sarin. This review focuses on the four main health effect categories of neurological response with sufficient data to reach hazard conclusions and clearly outline the evidence forming the basis of those conclusions: (1) ChE levels; (2) visual and ocular effects; (3) effects on learning, memory, and intelligence; and (4) morphology and histopathology in nervous system tissues. The conclusions of this systematic review align with conclusions from a published narrative review of long-term neurological effects following exposure to sarin by the National Academies of Sciences in concluding that there is strong evidence for effects of sarin on cholinergic effects (e.g., ChE) in the period covering hours to days after exposure and less conclusive evidence for visual effects and other symptoms over longer time periods (IOM 2004). In 2004, the Institute of Medicine (IOM) of the National Academies of Sciences, Engineering, and Medicine published a review of long-term health effects of Gulf War veterans associated with sarin as the only suspected exposure and concluded that there was sufficient evidence of a causal relationship between exposure to sarin and a dose-dependent acute cholinergic syndrome that is evident seconds to hours following sarin exposure and resolves in days to months. The 2004 IOM report also concluded that there was limited/suggestive evidence of an association between exposure to sarin at doses sufficient to cause acute cholinergic signs and symptoms and a variety of subsequent long-term (i.e., longer than several months following exposure) neurological effects including visual disturbances, visual evoked potential, symptoms of PTSD, psychomotor performance, EEG records of sleep, headache, and other endpoints (IOM 2004). The data on PTSD, headaches, sleep, anxiety, and other neurological effects were evaluated and considered inadequate evidence to reach hazard conclusions in this systematic review (see Appendix E).

## Limitations of the Evidence Base

A number of serious limitations in the body of evidence from human studies apply across the different neurological outcomes. The major limitation in the epidemiological studies is study design. Most studies followed subjects from two terrorist attacks (Matsumoto and Tokyo subway attacks) without including any control groups. The case series following the Tokyo subway attack victims were also limited because many of the studies followed only the subjects who were brought to one hospital (St. Luke’s International Hospital) after the attack, which only accounted for 640 of the approximate 5,000 potentially exposed subjects (Okumura et al. 1996). In addition, subjects were lost over time with no information provided on subjects lost, including the reasons why they were lost (e.g., because of death, nonparticipation in follow-up surveys) and whether the subjects lost to follow-up were more likely to be milder cases. Of the 640 subjects brought to St. Luke’s, it has been reported that 111 were admitted to the hospital and 528 were discharged and considered mild cases (Morita et al. 1995); however, most of studies did not report any details on the exposure of the subjects. Most studies only indicated that they were victims of the attacks. In some cases, subjects self-reported if they had been admitted to the hospital or not, which was used as a proxy for level of exposure. This can lead to exposure misclassification, even based on a never/ever exposure scenario. Few studies provided details on cholinergic symptoms and ChE levels immediately after exposure for all subjects in the study to indicate sarin exposure or levels of sarin exposure, which could be used to qualitatively demonstrate exposure gradient. It is recognized that the subjects of the sarin attacks were likely exposed to some level of sarin, and that controls would not have been exposed, as sarin is not found in the environment. Although exposure details are a limitation, it is the lack of controls for comparison that is the major limitation in the body of evidence. Even when a study included a control, exposure was mainly assessed as a never/ever scenario. This is a limitation because it may be the level of exposure that is associated with prolonged neurological effects, and there are few if any studies that address this limitation.

Another limitation to the epidemiology evidence base is that many of the studies only included self-reported symptoms. Because the subjects knew they were exposed, there is potential bias in the reporting of symptoms. In some of the studies that followed subjects over time, symptoms were added to questionnaires after they had been noted to occur by some of the subjects as a “write-in” symptom. This presents a limitation in the information available for each time period and decreases the potential to follow the symptom for resolution over time. Even in studies for which results were not self-reported, there is no indication that the outcome assessors were blind to the exposure group. Most of the studies also did not account for any potential confounders such as age. Although these limitations were true across most of the endpoints, the cross-sectional studies on memory did account for potential confounders, which made these limitations less of an issue for the memory effects. Regarding morphology and histopathology data in humans, this information would only be evaluated during an autopsy or if subjects had lingering effects after the exposure, which decrease the likelihood that information would be available to evaluate these effects in the initial period.

Many of the epidemiological studies do not fully address potential confounders and, therefore, the human evidence as a whole includes multiple challenges with confounding. As noted in the risk-of-bias sections of this report, confounders related to the outcome (e.g., age, sex, socioeconomic status) are rarely considered in case reports or case series. Although there is no evidence to suggest that the likelihood of the attack was associated with any specific confounder, most studies did not describe the subjects in terms of these potential confounders and it is possible that either attack occurred in a specific demographic (although these would be different in the different attacks). In addition, because most of studies in humans report effects following two terrorist attacks, results may be confounded by PTSD. Separating the effects of sarin exposure from the potential effects of PTSD related to a terrorist attack can be difficult, especially because subjects may also experience PTSD related to the severity of the effects from the sarin exposure. For the main endpoints examined in this review (ChE levels; visual and ocular effects; effects on learning, memory, and intelligence; and morphology and histopathology in nervous system tissues), PTSD is not considered a major confounder. For several of the other neurological effects described in Appendix E (e.g., anxiety and fear; avoidance and depression), PTSD could be a major confounder, making it difficult to separate the effects of sarin exposure from the effects due to a traumatic event.

Similarly, there are limitations in the body of evidence from experimental animal studies. The principal limitation is the lack of reporting details for determining risk of bias and failure of author response to address the lack of reporting, for which a conservative approach was followed (i.e., when there was not enough information to assess the potential bias for a risk-of-bias question and authors did not respond to an inquiry for further information, studies were rated probably high risk of bias for that question). The majority of animal studies did not report if the animals were randomized to treatment. One set of authors for several of the animal studies (i.e., all Kassa et al. studies) reported that they did not randomize their animals to treatment. More than half of the animal studies did not report the purity of the sarin, or they used sarin of 90% purity without providing information on the remaining 10% to indicate that there were no impurities that could affect the results. However, 21% (9 of 43) of the animal studies used sarin of sufficient purity and reported verification of the purity. Most of the studies also did not report if the outcome assessors were blinded to the experimental condition or did not report enough details to indicate that the lack of blinding would likely not bias the results. Kassa et al. (2004; 2002) responded to NTP’s inquiry and indicated that the outcome assessors were not blinded to experimental conditions. However, in two of their memory studies, a Y-maze test noted to be fully automated was used, which reduced the potential risk of bias.

Another limitation in the animal data is the heterogeneity of the data. Few studies used similar endpoints and several of the endpoints were subjective FOB scores. These limitations occurred across all of the endpoints making the data inadequate for reaching hazard conclusions for many of the long-term neurological effects. In addition, due to the limited number of studies and heterogeneity of the data in both the human and animal bodies of evidence, NTP was unable to thoroughly evaluate the data by additional variables that are known to affect organophosphate toxicity and neurotoxicity, including strain/species differences, genetics and epigenetic effects, body temperature, and presence of physiological stressors.

The staining methods employed during histopathological examinations is also considered a limitation in the animal data. While the staining methods used (e.g., H&E staining or Nissl) allowed the authors to detect morphologic changes in nervous tissue, modern techniques that provide a more comprehensive assessment of underlying neuropathology not revealed by classical Nissl/H&E staining were not employed (even in the most recent study in 2017), and therefore the full extent of the morphological changes may not have been detected and reported.

Targeted research that addresses improving human characterization of exposure with neurological tests compared to a control population, in addition to targeted research in animal models that addresses the inconsistencies identified in this review regarding study design and conduct practices to minimize bias, would help improve the body of evidence to critically assess the long-term neurological effects from an acute exposure to sarin.

### Key Data Gaps

Considering the context in which humans are typically exposed to sarin (i.e., during wartime situations and terrorist attacks), researchers are somewhat limited in their opportunities to study human populations acutely exposed to sarin in comparison to appropriate control groups, which can make the data gaps identified in this review difficult to address. Although there were two terrorist attacks in Japan, they both occurred more than 20 years ago, so additional studies on any remaining subjects are not likely to provide the additional data needed as age is an important confounder for many of the outcomes detailed in this report. Because these are rare and unpredictable events, there could be value to developing a rapid research response capability so that emergency response would include the latest treatment knowledge for the victims (Miller and Birnbaum 2015). The response could also collect vital human clinical data soon after chemical exposures. Well designed, pre-planned, epidemiological studies would add valuable data to the body of evidence that would be likely to impact conclusions or the confidence in the conclusions reached in this systematic review, given the lack of human data on many endpoints and time periods.

More rigorous human data would add greater confidence to conclusions reached in this evaluation across all outcomes described above except in the body of evidence for suppression of ChE activity in the initial time period, which already is rated as high confidence and a high level of evidence. Human evidence for sarin-related health effects that would benefit from additional data include visual and ocular effects, learning and memory effects, and morphology and histological changes in nervous system tissues following acute sarin exposure in the three time periods (i.e., initial, intermediate, extended) and alterations of ChE activity in the intermediate and extended periods. Data on other persistent symptoms and neurological effects would also be valuable, as a range of effects have been reported, but the evidence was inadequate to evaluate these health outcomes due to serious limitations in the bodies of evidence (e.g., heterogeneity in the endpoints examined, too few human or animal studies, small sample sizes, serious risk-of-bias concerns). The ability to separate the effects of the sarin exposure from the stress of the terror event would also be useful.

Prospective longitudinal cohort studies would be the most informative to better assess neurological effects associated with sarin exposure. Studies that assess visual and ocular effects ≥1 year after exposure in humans would address a data gap in reaching conclusions. However, studies that evaluate measurable results beyond pupil size and self-reported symptoms would add value to the assessment of potential visual and ocular effects resulting from acute sarin exposure. Human cohort studies would be invaluable in characterizing the relationship between ChE activity and neurological effects over time, as well as the potential relationship between acute sarin exposure and the development of PTSD as it relates to other neurological effects. Only one available study (Tochigi et al. 2002) addressed subjects with PTSD symptoms as a subgroup and found evidence of a long-term depression in serum ChE levels in the PTSD subset of patients (n = 8) compared with controls, whereas the same association was not seen in the entire study population compared to controls.

Because of the ability to conduct controlled exposure studies, experimental animal studies are particularly important for addressing research gaps identified by this systematic review, especially for identifying specific effects that could be targeted for medical mitigation. Animal studies indicate differences in inhibition and recovery of ChE activity, as well as histological changes, in different areas of the brain; however, the data are insufficient to determine if these differences correlate with the effects observed (e.g., whether the changes observed occur in areas that are known to be involved in learning and memory). Future research could focus on these effects to help identify potentially vulnerable areas that could be targeted. Studies in appropriate animal models are also needed for rigorous, well-controlled experimental assessments of the dose-response relationship between sarin exposure and long-term neurological effects. Research is needed to further characterize the morphological and histological effects of sarin observed in humans and animals to determine their clinical significance and the potential therapeutic approaches that may preclude these effects (e.g., neuroprotectants). Research is also needed to address the heterogeneity in the behavioral tests and study design among studies evaluating the learning and memory effects of sarin observed in animals. Studies in this area are also needed to include tests that separate out learning and memory effects from effects on motor and sensory function. Another gap in both the human and animal data is the effects of sarin on the developing and aging brain. It currently cannot be assessed if children, the very young, or the very old are more susceptible populations.

Most human studies provide self-reported symptoms. Although it was attempted to match animal tests to the human symptoms, animal studies that specifically attempt to examine endpoints in animals that directly correspond to commonly self-reported symptoms in humans would strengthen the evaluation of human and animal data together. Comprehensive and rigorous studies are also needed to characterize the neuropathy and underlying mechanisms caused by acute exposure to sarin. These are important to identify a mechanistic basis for the outcomes and drug indications being proposed for new therapeutics.

## Limitations of the Systematic Review

The hazard identification conclusions in this evaluation were developed for long-term neurological effects associated with acute sarin intoxication based on integrating levels of evidence from human and animal studies. However, the available mechanistic data were not sufficient to impact the confidence ratings. Although there were a few in vivo studies that evaluated mechanistic data, they were very limited in number and there was no overlap in endpoints evaluated (none of the studies evaluated the same endpoints or potential mechanisms). The NTP literature search was focused on mechanistic data that were clearly relevant for evaluating the biological plausibility of neurological outcomes reported from in vivo studies in animals or humans. The literature search only included in vitro data if the endpoint was directly relevant to survival or morphology of neuronal or glial cells. This focused approach may have missed mechanistic studies of earlier events such as inhibition of neuropathy target esterase (Brown and Brix 1998) or broader mechanistic categories such as oxidative stress, neuroinflammation, or other mechanisms separate from the cholinergic pathway that may inform the overall evaluation of potential neurotoxicity associated with exposure to sarin.

The NTP systematic review did not consider unpublished data for this review. Publicly available, unpublished data were identified from the literature search. Data from the identified unpublished studies were either subsequently published (and therefore included in this review) or were from authors who had published several other studies on the topic. A review of the identified unpublished data led to the determination that the inclusion of the unpublished data to the body of evidence would not change any of the hazard conclusions; therefore, unpublished data were not included in the review. However, because sarin is a nerve agent used in chemical warfare, there are likely to be unpublished studies that are not publicly available that might provide additional support for the effects observed and discussed in this review. Therefore, not including unpublished data from sources that are not publicly available may be a limitation of the systematic review.

This systematic review also was limited to acute sarin exposure. Although the intent of the review was to evaluate the effects of acute sarin exposure on long-term neurological effects, data may have been available from short-term or chronic exposures that may have relevance to the findings described in this report. In addition, there is a very large literature base on the effects of other OP nerve agents and pesticides. There may be information on these other OP agents that could support the findings in this review that were not considered.

Exposure characterization and dose-response assessment were beyond the scope of this review. The evaluation did not attempt to quantitatively characterize exposure or identify exposure levels of sarin at which long-term neurological effects occur. In general, there was a lack of quantitative exposure data in the human studies identified, and there may not be sufficient data from these studies to identify a threshold or exposure level for long-term neurological effects of sarin.