# Results and Evidence Synthesis

## Literature Search Results

The electronic database searches retrieved 6,837 references. None of the databases searched contains confidential unpublished data; therefore, no confidential unpublished data were retrieved from these searches. Of the total references retrieved, 93% (6,340) were excluded during the title and abstract screening and 412 references were excluded during the full-text review for not satisfying the PECO criteria. The screening results are outlined in the study selection diagram with reasons for exclusion documented at the full-text review stage (Figure 6) [using reporting practices outlined in Moher et al. (2009)]. After full-text review, 85 studies were considered relevant, which included 34 human studies and 51 animal studies. However, two of the human publications and four of the animal publications included data published in another study, so there were 32 human data sets within the 34 human studies and 47 animal data sets within the 51 animal studies. When multiple publications presented the same data, a single study was selected for extraction (e.g., the first or most complete reporting) and all of the studies were included in the Health Assessment Workspace Collaborative (HAWC) project database for this sarin evaluation (https://hawcproject.org/assessment/302/) and were reviewed to answer risk-of-bias questions regarding the data sets that were extracted (NTP 2019b). The list of included references is provided in Appendix C.

Figure 6

Study Selection Diagram

Eight studies were identified that included data that were publicly available but did not have a clear peer-review process. These studies were considered unpublished data and were reviewed for potential impact on conclusions. All eight studies were determined not to have any data that would change the hazard conclusions because the data were either subsequently published or were not published by authors who had published several other studies on the topics; the data did not add any useful evidence to the sections; or the data only added to the heterogeneity of the data. Therefore, these studies were not extracted or included in the assessment.

Twenty-four studies were identified that were published in a language other than English and appeared to meet the evidence selection criteria during the title and abstract screen. The titles, abstracts (if in English), data tables and figures, and study designs for these non-English studies were reviewed and determined to have data that would potentially add to data sets already considered (e.g., additional case reports/series in humans) but were unlikely to have data that would change the hazard conclusions. Therefore, these non-English studies were not translated or included in the assessment.

## Health Effects Results

The human and animal neurological data across all studies were sorted into four main health effect categories of neurological response: (1) cholinesterase (ChE) levels; (2) visual and ocular effects; (3) effects on learning, memory, and intelligence; and (4) morphology and histopathology in nervous system tissues. As the objective of this assessment was to focus on long-term neurological effects following acute sarin exposure, data pertaining to all non-neurological health outcomes associated with sarin exposure were not categorized and synthesized in this report. Results were grouped across studies within each category to develop bodies of evidence or collections of studies with data on the same or related outcomes. Human and animal studies were identified on potential effects of sarin in all four neurological categories. Specific endpoints were comparable for some effects (e.g., memory), but not all cases (e.g., P100 latency to measure visual evoked potential, and self-reported difficulty seeing). The human evidence described a range of neurological symptoms. To the extent possible, neurological symptoms in humans were related to neurological observations in animals, although for many human symptoms there are no data on a similar endpoint in experimental animals. These specific symptom data are provided in Figure F-1. In some cases, the neurological effects observed in humans did not fit in any larger category and preclude any synthesis of the data. For the animal data, a set of data had no human equivalent. Brain chemical changes in animals are presented in Table F-7, but these data are not discussed in detail because the heterogeneity of the data precludes an informative synthesis of the data.

There were many additional neurological health outcomes reported for which the evidence was inadequate to determine whether there is an association with acute sarin exposure. These outcomes included activity and strength, anxiety and fear, avoidance and depression, EEG data, sensory effects other than visual, sleep disruption, and other neurological symptoms. The body of evidence was inadequate to evaluate potential effects for these health outcomes because of heterogeneity in the endpoints examined, too few human or animal studies to make any conclusions due to inconsistencies, small sample sizes (e.g., a single case report), difficulty in separating effects associated with sarin exposure from effects associated with experiencing a traumatic event (e.g., post-traumatic stress disorder [PTSD] from a terrorist attack), or serious risk-of-bias concerns that contributed to very low confidence in the data. The results, evidence synthesis, and risk-of-bias assessment for the health outcomes with inadequate evidence are in Appendix E.

Due to the nature of exposure to sarin (i.e., rare events that, when they occur, are most often a result of occupational accidents or terror attacks), the majority of available studies are case reports or case series—both of which are descriptive studies that report on a group of exposed subjects followed over time but are often without known levels of exposure or controls for comparison—and cross-sectional studies. These types of study designs are generally considered to be of lesser quality than cohort studies due to a lack of control group or baseline data and an inability to demonstrate that exposure occurred prior to the development of the health outcome; however, data from these study types are still considered highly useful for assessing long-term neurological effects following acute sarin exposure. Regarding the uncertainty related to temporality of exposure and outcome, sarin exposures that occurred during terror attacks occurred during a known time period prior to the assessment of the outcome, and it is unlikely that sarin exposure would occur in control populations in cross-sectional studies. The case reports and case series may not have included controls for comparison, but are representative of larger exposed populations, and the results can generally be compared with some standard normal value. Although this may not be ideal when the standard normal encompasses a range, which would make it difficult to determine individual-level effects, some determination can be made based on these standard values as would typically be done by doctors in a clinical setting. Uniquely, a major advantage of the human data for sarin is the availability of two controlled trials in addition to the cross-sectional studies and case reports/series. The inclusion of these two controlled trials in this assessment provides strong evidence of an effect in the initial time period following exposure. These controlled trials provide valuable insight that is not available in most assessments.

Although this systematic review collected and considered mechanistic data, limited information was identified to support the biological plausibility of corresponding neurological outcomes. The mechanisms that explain how chemicals produce many neurological effects are unknown. Although ChE inhibition is evaluated in this review as a neurological effect from acute sarin exposure, ChE can potentially be a mechanism for the other neurological effects evaluated. However, there are insufficient data to determine if the ChE effects are responsible for the other neurological effects (e.g., secondary neuronal damage occurring in cholinergic regions of the brain due to prolonged over activation of the cholinergic receptors) or if other noncholinergic mechanisms are involved (Pope 2006). For example, disruption of the glutamatergic pathway is another potential mechanism for neurological effects of sarin; this pathway is related to seizures and neurotoxicity, possibly leading to long-term neurological effects including memory impairment (Chen 2012; Pope 2006; Ray 1998). Other noncholinergic mechanistic pathways may include mitochondrial dysfunction and oxidative stress (leading to cell death) (Abou-Donia et al. 2016; Chen 2012; Hargreaves 2012; Ray 1998). Overall, data are insufficient to identify a clear mechanism by which sarin causes long-term neurological effects in humans.

### Organization of the Results

Each section is organized to present and explain the rating of confidence in the body of evidence that sarin exposure is associated with the health effect described in that section for human and animal data separately. The confidence in the data was determined as described in Figure 3. Human data are discussed before animal data. Sections with sufficient data are structured so that the first paragraph discusses the confidence in the data, the second paragraph provides a brief overview of the available studies and of overall risk-of-bias concerns, and subsequent paragraphs summarize the data organized by time frames when appropriate.

#### Consideration of Health Effects by Time after Exposure

Although any effect observed more than 24 hours after exposure is considered long-term for this assessment (see Introduction for description), review of the data determined that this covered several different time periods after exposure. Because results may vary across these ranges of time, the evaluation of hazard conclusions was evaluated for three different time periods (see Table 5). The time periods were selected based on the available data from human studies; however, it is recognized that the selected time frames for the intermediate and extended time periods for humans are not appropriate for rodents. To address this distinction, the durations of the intermediate and extended times periods are defined differently for animals versus humans and nonhuman primates (considered more like humans in terms of life span) as shown in Table 5.

Table 5 Definition of Time Periods after Exposure

Time Period after Exposure | Humans and Nonhuman Primates | Animals except Nonhuman Primates
Initial Time Period | >24 hours–7 days | >24 hours–7 days
Intermediate Time Period | 8–364 days | 8 days–90 days (or 3 months)
Extended Time Period | ≥1 year | >90 days

Effects observed after 24 hours through 7 days are considered effects over the initial time period after exposure. Due to variation in the duration of cholinergic effects, this time range was selected as the initial time period for humans and animals. The initial time period likely includes cholinergic effects as well as side effects related to cholinergic hyperstimulation.

The intermediate period after exposure is considered to be from 8 days through 364 days (<1 year) after exposure in humans and nonhuman primates. It is expected that cholinergic effects would have entirely subsided either prior to or during the initial time period after exposure and would not be included in the intermediate time period. Because rodents have a different life span, the intermediate period was considered to be 8 days through 90 days. The 90-day time point was selected based on standard subchronic study dosing guidelines because of the lack of any common comparison for time-after-exposure guidelines. Rodent studies sometimes report the timing of outcome assessment in terms of months instead of days. In these cases, 3 months was considered to be the equivalent to 90 days and was therefore included as part of the intermediate period.

The extended period after exposure is considered any time ≥1 year in humans and nonhuman primates and >90 days (or 3 months) in rodents. As human studies that evaluate health effects years after exposure often define time after exposure in terms of years (i.e., 1 year, 2 years) and not a precise day (e.g., 365 days after exposure), ≥1 year after exposure for humans and nonhuman primates was considered to be the extended period.

### Risk-of-bias Considerations

Risk-of-bias ratings for all of the individual studies for all questions are available in Appendix D. The risk of bias of individual studies in the body of evidence was considered in developing the confidence ratings for each health effect. The key risk-of-bias questions (e.g., confounding, exposure characterization, and outcome assessment for human studies and randomization, exposure characterization, and outcome assessment for experimental animal studies) are discussed within the consideration of the body of evidence for each health effect. They are key questions for this assessment because they address issues in study design and conduct with the potential to have the greatest impact on the results if not addressed appropriately. No study was excluded based on concerns for risk of bias, but confidence conclusions were considered, if present, with and without high risk-of-bias studies (e.g., studies rated probably high or definitely high risk of bias for two key risk-of-bias questions) to assess the effect of the high risk-of-bias studies. However, it was determined that none of the time period-specific bodies of evidence evaluated in this assessment contained a sufficient number of higher quality studies to be able to stratify and evaluate studies based on quality (i.e., lower quality studies versus higher quality studies). Confidence in the bodies of evidence was downgraded twice if studies were consistently rated probably high or definitely high risk of bias for all three key risk-of-bias questions. Confidence in the bodies of evidence was downgraded once if studies were consistently rated probably high or definitely high risk of bias for two of the three key risk-of-bias questions. Although risk-of-bias ratings for the non-key risk-of-bias questions were considered in the evaluation, confidence in the bodies of evidence were only downgraded based on the ratings for the key risk-of-bias questions unless specific studies had serious issues in other areas.

When assessing study quality, it is very important to consider how the design and conduct of the study may have increased or decreased the validity of the study results. Bias is a systematic error that occurs in results or inferences. Biases can operate in either direction, leading to an underestimation or overestimation of the true effect. Biases can vary in magnitude. Some biases are small (and trivial compared with the observed effect) and others are substantial (so that an apparent finding may be entirely due to bias). Even a particular source of bias may vary in direction. Bias due to a particular design flaw (e.g., lack of allocation concealment) may lead to underestimation of an effect in one study but overestimation in another study. It is usually impossible to know to what extent biases have affected the results of a given study, although there is good empirical evidence that particular flaws in the design, conduct, and analysis of randomized studies lead to bias. Given on these factors, it is important that all studies are evaluated for risk for bias (NTP 2015; NTP 2019a).

### Cholinesterase

Sarin is an organophosphate that causes inhibition of acetylcholinesterase (AChE) (Lee 2003). This inhibition leads to an increase in acetylcholine, which leads to cholinergic hyperstimulation (i.e., overstimulation of the muscarinic and nicotinic acetylcholine receptors in the central and peripheral nervous system due to excess acetylcholine). The signs and symptoms of acute exposure are generally referred to as cholinergic crisis (e.g., miosis, salivation, lacrimation, rhinorrhea, difficulty breathing, convulsions, seizures, diarrhea), which generally subside in a few days. Sarin is known to inhibit AChE related to cholinergic crisis, and studies addressing effects on ChE within the first 24 hours are beyond the scope of the review and not addressed in the following text. This section provides a summary of studies addressing effects of sarin on ChE that occur more than 24 hours after exposure. Given the well-established role of AChE and ChE in cholinergic crisis, inhibition of these enzymes can be considered an effect of sarin as well as a potential mechanism for other effects; however, there are insufficient data to determine if the inhibition of AChE or ChE is responsible for the other neurological effects (e.g., secondary neuronal damage occurring in cholinergic regions of the brain due to prolonged over activation of the cholinergic receptors) or if other noncholinergic mechanisms are involved (Pope 2006). Therefore, for this evaluation, changes in AChE or ChE after sarin exposure will be considered as a health effect.

The human studies generally measured total blood ChE with only a few studies specifically reporting AChE measurements. The animal studies primarily measured AChE in the blood or brain. Many animal studies also evaluated butyrylcholinesterase (BChE), but these results are not discussed because the physiological function of BChE related to neurological effects is unclear and, in general, these studies also measured AChE. For consistency throughout the section, “ChE” is the term used for all ChE measurements discussed. Although tests for ChE are considered standard, there are different kits and methodologies used to determine ChE (or AChE more specifically) that may vary depending on the medium in which ChE was tested.

Ideally, ChE measurements after exposure would be compared with a baseline measurement (i.e., before exposure) for an individual, as ChE levels can vary by individual. These baseline data are unlikely to be available for many subjects unless they were specifically working with anticholinesterases; therefore, the ChE levels of subjects were likely compared with a “normal” value. Although many of the studies did not state the value that was used to calculate percent of control, percent of normal is considered to be valid in determining inhibition; however, it may affect the results depending on where the subjects’ initial baseline values fell in the range of “normal” and which value was used as the control. Subjects with baseline values on the lower end of normal may indicate a greater ChE inhibition than what actually occurred. On the contrary, ChE inhibition in subjects with baseline values on the higher end of normal may have been understated or not detected.

#### Human Cholinesterase Data

##### Summary

There is high confidence in the body of evidence that acute sarin exposure suppresses ChE blood levels in humans over the initial period of 1–7 days following initial exposure, with low confidence that suppression continues over a period of months after exposure. The studies that provide data on ChE response in blood for a period of days, including two nonrandomized controlled trials (Baker and Sedgwick 1996; Grob and Harvey 1958) and two case reports (Grob 1956; Sidell 1974), reported consistent evidence of ChE inhibition following acute sarin exposure (Figure A-1). Similarly, the studies that provide data on ChE response for a period of weeks to months, including six case reports (Grob 1956; Ohtomi et al. 1996; Okumura et al. 1996; Rengstorff 1985; Sekijima et al. 1995; Sidell 1974), showed consistent lowering of blood levels of ChE following acute sarin exposure (see Figure A-2 and Figure A-3). One cross-sectional study that evaluated ChE blood levels 5 years after exposure did not observe a difference in ChE compared to controls (Tochigi et al. 2002). Although results show consistent lowering of blood levels of ChE for a period of days to months following acute sarin exposure, there are limitations in the body of evidence including small sample sizes (n = 8–10 for the controlled exposure studies), risk-of-bias concerns, and uncertainties related to study design for the case reports.

High confidence in the body of evidence for the initial period following acute sarin exposure is primarily based on the two controlled trials with support from two case report studies. The high initial confidence from the controlled trials was downgraded once for risk-of-bias concerns (i.e., lack of reporting for the key risk-of-bias questions regarding outcome assessment and, in one study, randomization and exposure characterization) and upgraded for evidence of large magnitude of effect (i.e., mean RBC ChE levels were 60.5% of control values at 3 days) to support a final rating of high confidence in the body of evidence for the initial period following acute sarin exposure. This high confidence rating for suppressed ChE in the days following acute exposure is also supported by the well-established response for immediate ChE inhibition in the first 24 hours following acute sarin exposure (Abu-Qare and Abou-Donia 2002; Gupta 2015; Lee 2003; NRC 1997; Tokuda et al. 2006; Yanagisawa et al. 2006).

There is biological support for consistency of sarin-related suppression of ChE over the period of weeks to months, but the body of evidence is limited to six case report studies. These case reports result in a low initial confidence rating for the body of evidence for the intermediate time period. Although a downgrade in confidence for risk-of-bias concerns and an upgrade for magnitude of effect were considered, applying both would still result in a rating of low confidence. These studies were given a final rating of low confidence in the body of evidence for the intermediate period following sarin exposure. The body of evidence for the extended time period following acute sarin exposure consists of one cross-sectional study and is considered inadequate to evaluate whether sarin exposure is associated with changes in ChE ≥1 year after exposure due to the limited number of studies, small sample size, and risk-of-bias concerns (see Figure 7).

Figure 7

Cholinesterase Evidence Profile for Sarin

References: Human: Baker and Sedgwick (1996),^a^ Grob and Harvey (1958),^a^ Grob (1956),^b^ Ohtomi et al. (1996),^b^ Okumura et al. (1996),^b^ Rengstorff (1985),^b^ Sekijima et al. (1995),^b^ Sidell (1974),^b^ Tochigi et al. (2002).^c^ Animal: Abou-Donia et al. (2002),[underlined: ^e^] Bansal et al. (2009),[underlined: ^d^] Chaubey et al. (2016),[underlined: ^d^] Chaubey et al. (2017),^d,e^ Damodaran et al. (2003),[underlined: **] Genovese et al. (2007),[underlined: ^d,e^] Gupta et al. (1991),[underlined: ^d^] Jones et al. (2000),[underlined: ^e^] Koelle et al. (1977),[underlined: ^d,e^] Nieminen et al. (1990),[underlined: ^d^] Pearce et al. (1999),[underlined: ^e^] RamaRao et al. (2011),[underlined: ^d,e^] Scaife and Shuster (1960),[underlined: ^d,e^] Tripathi and Dewey (1989),[underlined: ^d,e^] Whalley and Shih (1989).[underlined: ^d^]

*There are also data from two case reports (Grob 1956; Sidell 1974), but confidence is based on the two nonrandomized control trials.

**Evaluated AChE mRNA in the brain.

The available epidemiological studies that evaluated the association between acute exposure to sarin and ChE effects varied greatly in the timing of the outcome measurement (ranging from 26 hours to 5 years after exposure). Two nonrandomized controlled trials and two case reports of accidental occupational exposure report ChE effects 1–7 days after exposure; six case reports of accidental occupational exposure or from the Matsumoto or Tokyo subway sarin attacks report ChE effects weeks to months after exposure; and one cross-sectional analysis reports ChE levels 5 years after the terrorist attack in the Tokyo subway system (see Table 6 for study details). Studies were all conducted in adults with a range in sample size from a single case report to 68 subjects (34 exposed and 34 control subjects). Exposure scenarios varied greatly and included accidental occupational exposures; exposures resulting from two separate terrorist attacks that varied in location, population, and exposure conditions; and two controlled trials—one that used an inhalation chamber and the other that used oral administration. Sarin exposure levels were known only for the two controlled trials. For effects, some studies measured ChE in red blood cells (RBCs) or plasma or serum, whereas others specifically measured AChE in RBCs.

Table 6 Studies on Activity of Circulating Cholinesterase in Humans

Study | Study Design (Location/ Subjects) [n] | Exposure Measure Timing | ChE Assessment Timing | Analysis | ChE Activity Summary
Initial Time Period after Exposure (>24 hours–7 days)
Baker and Sedgwick (1996) | Nonrandomized controlled trial (United Kingdom/male servicemen) [8] | Inhalation (experimental chamber) for 30 min, 0.5 mg/m^3^ | 3 days | RBC ChE activity % of control values | Depression of RBC ChE activity (57.9–66.1% of control values; mean 60.5% of control values) at 3 days
Grob and Harvey (1958) ^a^ | Nonrandomized controlled trial (United States/adult volunteer subjects) [10] | Oral, initial dose range 0.0005–0.022 mg/kg (dose within 24 hours) | 26 hours | Plasma and RBC ChE activity % of control values | Depression of ChE activity of RBCs (17.5% of control values at 26 hours) greater than that of the plasma (41.2% of control values at 26 hours)
Grob (1956) | Case reports (unspecified location/males) [3] | Accidental occupational exposures (each a separate occasion; not measured) | 1.5, 2, 2.5, 3, 4, 5, 6, 7 days | Plasma and RBC ChE activity % of control values | Depression of ChE activity of RBCs (as low as 3% and 8% of control values at 2 days and 6 days, respectively) greater than that of the plasma (as low as 7.5% and 28% of control values at 2 days and 7 days, respectively)
Sidell (1974) | Case reports (United States/ males) [3] | Accidental occupational exposures (not measured) | 3, 6 days | Plasma and RBC ChE activity % of control values | Depression of ChE activity of RBCs (as low as 38.1% of control values at 3 days) and plasma (as low as 64.8% of control values at 3 days)
Intermediate Time Period after Exposure (8 days–1 year)
Grob (1956) | Case reports (unspecified location/males) [3] | Accidental occupational exposures (each a separate occasion; not measured) | 8–14 (daily), 16–24 (daily), 26–34 (daily), 42, 43, 52, 53, 55, 56, 60, 74, 88 days | Plasma and RBC ChE activity % of control values | Depression of ChE activity of RBCs ranged from 10 to 21% of control values at 8 days and gradually returned to normal activity over a period of 3 months; depression of ChE activity of plasma ranged from 30 to 65% of control values at 8 days and gradually returned to normal activity over a period of 3–8 weeks
Rengstorff (1985) | Case reports (United States/ males) [2] | Single accidental occupational exposure (not measured) | 13, 34, 62, 90 days | Mean plasma and RBC ChE activity µM/mL/min | Depression of ChE activity of RBCs (4.5 µM/mL/min at 13 days vs. 13 µM/mL/min at 90 days for higher exposed individual) and plasma (4.2 µM/mL/min at 13 days vs. 5.4 µM/mL/min at 90 days for higher exposed individual); gradual increase to baseline over period of up to 90 days
Sekijima et al. (1995) | Case report (Japan/ Matsumoto sarin attack victim) [1] | Terrorist attack, single exposure (not measured) | 10–90 days, every 10 days | RBC ChE and serum ChE activity % of normal values | Depression of ChE activity of RBCs (13.2% of normal values at 10 days) and serum (52.7% of normal values at 10 days); returned to normal at approximately 3 months
Sidell (1974) | Case reports (United States/ males) [3] | Accidental occupational exposures (not measured) | 13, 20, 27, 41, 62, 69, 90 days | Plasma and RBC ChE activity % of control values | Gradual return to normal activity over period of up to 90 days (see initial effect above under 1–7 days)
Okumura et al. (1996) | Case reports (Japan/Tokyo subway attack, St. Luke’s Hospital) [4] | Terrorist attack, single exposure (not measured) | 2 months | RBC ChE, plasma ChE | RBC ChE increased over time in 4 severe cases with resolution taking about 2 months; in 1 patient that died, it returned to normal in 13 days with treatment
Ohtomi et al. (1996) | Case series (Japan/Tokyo subway attack, SDF Central Hospital) [62] | Terrorist attack, single exposure (not measured) | 3–4 months | RBC ChE, plasma ChE | RBC ChE: all patients back to normal range by 3 months; plasma ChE 7 patients still below normal range by 3–4 months
Extended Time Period after Exposure (≥1 year)
Tochigi et al. (2002) | Cross-sectional (Japan/Tokyo subway sarin attack, adult victims, and controls) [68] | Terrorist attack, single exposure (not measured) | 5 years | Mean serum ChE activity IU/L | No significant difference in mean serum ChE (313 IU/L at 5 years vs. 347 IU/L for control); ChE was significantly lower among victims with PTSD compared with controls

^a^ Grob and Harvey (1958) administered multiple exposures and assessed ChE levels at multiple time points; however, the ChE assessment at 26 hours after the first sarin exposure but before the subsequent sarin exposures are the only data that satisfy the PECO statement.

##### Overall Risk-of-bias Discussion of the Body of Evidence

Confidence in the body of evidence for the human studies was downgraded because of serious concern for risk of bias in the initial and extended time periods. Risk-of-bias ratings for individual studies for all questions are available in Figure A-6 through Figure A-9. There are a number of risk-of-bias issues in the evidence relating to design and conduct of individual studies, in addition to general limitations (i.e., not risk-of-bias issues) based on the case report study design. Most of the human studies were case reports and were rated as probably high risk of bias for the key risk-of-bias question regarding confounding. For the controlled trials, risk-of-bias concerns were due to a lack of reporting for the key risk-of-bias questions regarding randomization, exposure assessment (for the oral study), and blinding during outcome assessment. Attempts to contact the study authors to obtain additional information when information pertinent for determining risk of bias was not reported were generally not successful, likely because the publications are more than 20 years old. When information was lacking to assess the potential bias for a risk-of-bias question, a conservative approach was followed, and the studies were rated probably high risk of bias for that question. Because the time period-specific bodies of evidence contain few higher quality studies, the studies were not stratified based on quality (i.e., lower quality studies versus higher quality studies). For the same reason, NTP was unable to compare the results of lower risk-of-bias studies with higher risk-of-bias studies as a way to assess the impact of the unreported information.

For the intermediate time period, six case reports provided consistent evidence of decreased ChE. Three of six case reports (Grob 1956; Sekijima et al. 1995; Sidell 1974) were lower risk-of-bias studies and were rated probably high risk of bias for only one key risk-of-bias question (failure to address potential confounders). The other three higher risk-of-bias studies in this time period (Ohtomi et al. 1996; Okumura et al. 1996; Rengstorff 1985) were rated probably high risk of bias for confounding and potential lack of blinding during the outcome assessment. When considered together, the confidence in the body of evidence was primarily based on the three lower risk-of-bias studies (Grob 1956; Sekijima et al. 1995; Sidell 1974) and was not downgraded for risk-of-bias concerns.

Lack of information on specific exposure measures was a principal issue in many of the studies. The two controlled trials had known administered levels of exposure; however, Grob and Harvey (1958) administered different dose levels of sarin to each of the 10 subjects without discussing if they were randomly assigned. In addition, the solution containing sarin was 90% pure with the remaining 10% consisting of other ChE inhibitors. The authors did not report which ChE inhibitors made up the remaining 10%. Although it is likely that sarin caused the initial ChE inhibition reported in the study, it is unknown if the remaining 10% of ChE inhibitors was associated with long-term effects; however, this study only measures ChE through 26 hours after exposure. Most of the studies were based on accidental occupational exposure or one of the two terror attacks. For these studies, it is acknowledged that exposure to sarin occurred despite lack of information on level or exposure, and many of the studies provide some information on initial symptoms indicative of exposure. These are considered to not pose a risk-of-bias concern and were assigned a rating of probably low risk of bias because there is little concern for exposure misclassification. Sarin is not found in the general population and can be evaluated as ever/never exposed in any of the scenarios (occupational exposure or terror attack). Controls would not have been exposed to sarin, but there is potential concern about exposure to other organophosphates, which was considered a confounder of concern.

Failure to address potential confounders was a main issue in the case reports and cross-sectional study. None of the studies addresses potential exposure to other anticholinesterases (such as drugs used for Alzheimer’s disease or dementia), which could occur in an occupational setting, or other potential confounders (e.g., age, sex, race/ethnicity, smoking, body mass index, alcohol consumption, and variables that represent socioeconomic status). Although it is recognized that sarin may be a more potent anticholinesterase than other anticholinesterases, assessing sarin’s long-term effects could be biased away from or toward the null depending on the long-term effects in controls exposed to other anticholinesterases. Although Tochigi et al. (2002), the one cross-sectional study, generally matched the controls by age and sex, the authors did not indicate that controls potentially exposed to anticholinesterases were excluded, and no other potential confounders were considered (e.g., smoking, alcohol consumption, body mass index [BMI]). The majority of the case reports compared ChE levels to a normal or control level, but no information was provided on whether the normal/control level was standardized for the sex and age of the subjects. Although the studies did not address potential confounders, there is not enough information available to indicate how this would impact the results. No studies were excluded based on concerns for risk of bias, but the lack of information available on the potential confounders adds to the serious concerns for risk of bias.

The main limitation in the outcome assessment was the lack of reporting if the outcome was assessed without knowledge of exposure. Neither of the controlled trials provided information on whether the outcome assessors were adequately blinded to the study group or exposure level, or if samples were sent to an independent laboratory or were coded and stored for analysis all at the same time. Regarding biases in the outcome assessment of ChE levels in case reports, testing conducted as part of a hospital examination is considered probably low risk of bias because it is unlikely that the lab technician would have knowledge of exposure or knowledge of specific results that may be associated with the exposure; however, many of the studies did not state that the ChE testing was part of routine hospital examinations and may be biased due to lack of blinding if the assessors were aware of the possible exposure. The cross-sectional study by Tochigi et al. (2002) also did not report if the outcome assessors were blinded, and it is unlikely that the test was conducted as part of a routine hospital exam, as both the exposed and control groups were evaluated 5 years after the exposure. This lack of data on blinding during outcome assessment adds to the serious concern for risk of bias and, combined with the lack of information on potential confounders, caused the confidence rating in the body of evidence to be downgraded once.

##### Effects in the Initial Period after Exposure

The results from two controlled trials (8–10 participants) and two case reports (three subjects in each publication all on accidental occupational exposure) provided consistent results for depressed ChE through 7 days after exposure. Two controlled trials reported evidence of ChE inhibition following acute sarin exposure 1–3 days after exposure. In both controlled trials, subjects were used as their own controls (Baker and Sedgwick 1996; Grob and Harvey 1958), and this body of evidence supports a high initial confidence based on study design considerations. One controlled trial administered sarin vapor with an ambient concentration of 0.5 mg/m3 for 30 minutes and measured ChE in RBCs 3 hours and 3 days after exposure in eight subjects (Baker and Sedgwick 1996). Three hours after exposure, the mean RBC ChE levels were 57.5% of the baseline values. By 3 days post-exposure, the RBC ChE levels were largely unchanged with a mean value of 60.5% of the baseline. Grob and Harvey (1958) administered a solution containing sarin (90% purity with 10% other compounds with anticholinesterase activity) at varying concentrations (initial dose ranged from 0.0005–0.022 mg/kg with an average value of 0.012 mg/kg). ChE levels at 26 hours were reduced by at least 40% after oral exposure (Grob and Harvey 1958). Although the study provided known levels of sarin to the subjects, each subject appeared to have received a different dose of sarin. The authors noted that doses of 0.002 to 0.022 mg/kg resulted in 15–75% reduction in plasma and RBC ChE activity decreasing in a dose-related manner. Maximum depression occurred within 1–2 hours, but RBC and plasma ChE levels were not restored within 26 hours and were still depressed by approximately 17.5% and 40% by 26 hours, respectively.

The limitations of the two controlled trials include the risk-of-bias concerns discussed above and small sample size. Confounding is less likely to cause bias in the controlled trials because the subjects were used as their own controls; however, because blinding of the outcome assessors was not reported, this could increase the likelihood of bias because baseline levels of the subjects were used as control levels, and the outcome assessors could know which ChE assessment took place before and after the sarin exposure. In addition, there are risk-of-bias concerns about exposure in one of the controlled trials (Grob and Harvey 1958) because different doses were administered to the subjects without reporting if the subjects were randomly selected for the different exposures, and the study used sarin that was 90% pure with other anticholinesterases in the remaining 10%. These risk-of-bias issues support a single downgrade from the initial confidence; however, the large magnitude of effect supports an upgrade in confidence. Therefore, the final high confidence rating for the body of evidence considers risk-of-bias concerns but also the large magnitude of effect, robust study design, and substantial support from evidence of acute ChE effects within the first 24 hours after sarin exposure (Abu-Qare and Abou-Donia 2002; Gupta 2015; Lee 2003; NRC 1997; Tokuda et al. 2006; Yanagisawa et al. 2006), and reflects the consistency in the results regardless of exposure route.

Case reports of accidental occupational exposures also demonstrated decreases in ChE 1–7 days after acute sarin exposure, but the levels and lengths of depressions varied by subject and by exposure scenario (Grob 1956; Sidell 1974). In addition, recovery rates for RBC ChE levels were consistently longer than those for plasma ChE levels. Grob (1956) details three different case reports of accidental exposure to sarin (presumably occupational). In each case, there was established exposure to an unknown amount of sarin, but each case had suppression of ChE ranging from 8 to 30% of normal levels through 7 days after exposure. Sidell (1974) reports on four cases of accidental exposure to sarin, but ChE measurements were only taken in three of the cases. The three cases all worked in an area where sarin was stored, and exposure occurred after one of the sarin containers leaked. Initial ChE levels ranged from approximately 55 to 80% of control for plasma ChE and from 30 to 55% of control for RBC ChE. All three cases had reduced RBC and plasma ChE at 3 and 6 days following exposure with a reduction of at least 40% depending on subject, time, and type of ChE. The variation in ChE levels could be related to differences in exposure, but the lack of exposure information precludes a determination. RBC ChE levels for all three cases in Sidell (1974) decreased further from normal levels from day 3 to day 6, whereas plasma ChE levels recovered closer to normal levels during the same time period. A similar trend in RBC and plasma ChE levels was reported for two of the three cases reported on in Grob (1956).

These case reports provide supporting evidence to the controlled trials that ChE levels are depressed 1–7 days after exposure to sarin. In both case reports, it is unclear what the control levels were and whether they represented baseline levels for the subjects or if they were based on an assumed “normal” range, as results were only presented as percent control. In addition, as exposure occurred in both case reports via occupational accidents, it is possible that the subjects experienced lower, asymptomatic chronic exposure to sarin.

##### Effects in the Intermediate Period after Exposure

The results from six case reports/series (1–62 cases per publication) demonstrated that decreases in ChE can last weeks to months after the exposure, but the levels and lengths of depressions varied by subject and by exposure scenario (Grob 1956; Ohtomi et al. 1996; Okumura et al. 1996; Rengstorff 1985; Sekijima et al. 1995; Sidell 1974). The body of evidence for this time period is limited to case reports and therefore supports a low initial confidence based on study design considerations. In the cases discussed by Grob (1956) mentioned above, each case had suppression of ChE ranging from 8 to 30% of normal levels with a gradual return to normal at 3–8 weeks for plasma ChE and at 3 months for RBC ChE. In cases from the Sidell (1974) study discussed above, it took between 10 and 90 days after exposure for plasma ChE to return to normal and at least 90 days for RBC ChE to return to normal in all subjects. Rengstorff (1985) reported on two of the Sidell (1974) cases. The subject closest to the sarin exposure experienced an initial depression of RBC ChE level at 19% of baseline levels and plasma ChE levels at 35% of baseline. The plasma ChE levels returned to normal within 30 days, whereas the RBC ChE levels took 90 days to return to normal. The other exposed coworker experienced little change in plasma ChE and an initial depression of RBC ChE at 84% of baseline. The RBC ChE level for this worker gradually increased and reached baseline around 60 days. A case report of a victim of the Matsumoto sarin attack was found to have depressed serum and RBC ChE by at least 50% 10 days after sarin exposure (Sekijima et al. 1995). Serum ChE levels returned to normal approximately 30 days following exposure, but the RBC ChE took 80 days to return to normal. Okumura et al. (1996) described four of the 640 subjects who were admitted into St. Luke’s International Hospital after the Tokyo subway attack. These four subjects all exhibited signs of severe sarin poisoning. In the patient that died, RBC ChE did not return to normal for 13 days even though plasma ChE was noted to return to normal within 7 hours of treatment. The other three cases were all unresponsive when admitted to the hospital, and it was noted that it took between 51 and 72 days for RBC ChE values to return to normal. All of these subjects were stated to have no evidence of sequelae when they were discharged. Cases brought to the SDF Central Hospital were described by Ohtomi et al. (1996). Twenty-seven of the 62 patients (44%) admitted had plasma ChE levels below normal range. Recovery was slow with or without treatment with seven patients still below normal levels 3–4 months after exposure. Twenty-eight of 53 patients (53%) had RBC ChE levels below normal range at admission. All patients had levels return to normal range by 3 months after exposure.

These case reports provide consistent evidence that acute sarin exposure causes ChE suppression that can last up to 90 days before returning to normal levels. Each case report was established to have been exposed to sarin, but the levels of exposure are unknown and therefore cannot be related to the severity in depression of ChE or the length of time for ChE levels to return to normal.

##### Effects in the Extended Period after Exposure

Only a single study was available that evaluated ChE levels several years after sarin exposure, but ChE levels were not reported to be significantly depressed. Tochigi et al. (2002), a cross-sectional study with a control group for comparison, evaluated ChE levels 5 years after exposure during the Tokyo subway attack. Controls were selected from the staff at the Tokyo University Hospital, and although they were age-matched and mostly sex-matched, there was no information provided to indicate that they had not been exposed to substances that could have altered their ChE levels. Tochigi et al. (2002) found that victims of the Tokyo subway attack did not have decreased serum ChE levels 5 years after the attack when compared with control subjects; however, a significant decrease in serum ChE level was observed in subjects who developed PTSD (n = 8) compared with controls 5 years after exposure.

The Tochigi et al. (2002) study had several limitations. The sample size was small (34 exposed and 34 control subjects), which may have limited the power of the study to detect an effect. No information was provided as to the selection of exposed participants from the cohort of Tokyo terror attack victims, except that they had been treated in the emergency room after the attack and were followed up at a general hospital in Tokyo. It was noted that serum ChE levels were available in 25 of the exposed subjects within 1–3 days of exposure. The mean ChE levels in these 25 subjects were lower 1–3 days after the attack than they were at 5 years, which provides evidence of exposure in at least 25 of the 34 subjects, but the authors did not report any symptoms. Although the controls were generally matched to the victims by age and sex, the authors did not indicate that controls potentially exposed to anticholinesterases were excluded, and no other potential confounders (e.g., smoking, alcohol consumption, BMI) were considered.

Taken together, epidemiological studies provide evidence that acute sarin exposure is associated with decreased ChE from 1 day through 12 months. The data present a consistent pattern of findings from 26 hours to 90 days after exposure with different levels of confidence depending on the time period after exposure. There is high confidence in the body of evidence in the initial period and low confidence in the body of evidence in the intermediate period. There is inadequate evidence to evaluate whether there are effects in the extended period, based on a single study that showed no significant effects in 68 subjects (34 controls and 34 exposed) evaluated at 5 years.

#### Animal Cholinesterase Data

##### Summary

There is moderate confidence in the body of evidence that acute sarin exposure suppressed ChE blood and brain levels in animals over a period of days to months after the initial exposure. The results show a consistent lowering of ChE blood levels following acute sarin exposure across multiple studies and at different time periods following exposure (see Figure A-4 and Figure A-5). However, there are limitations in the body of evidence, including small sample sizes (n = 2–6 for several studies) and risk-of-bias concerns. The consistent evidence supports suppression of ChE within days following acute sarin exposure, but the length of the suppression varied by study, and there was less evidence for suppression 1 week to 90 days (which is considered relevant for humans 1 week to 12 months after exposure). Downgrades by one or two levels were considered for the probably high risk-of-bias ratings on one key question as well as other questions. Upgrades were considered for several factors: large magnitude of effect (10–85% suppression of ChE), evidence for dose response in some studies, and consistency of effect across species (both rodents and nonhuman primates). Considering these opposing factors, the serious risk-of-bias concerns resulted in a downgrade of one level, and no upgrades were applied given the extent of the risk-of-bias concern. Therefore, confidence in the body of evidence for the animal studies was downgraded for both the initial period and intermediate period (up to 90 days) from an initial high confidence to support the final confidence rating of moderate (see Figure 7).

There are 15 experimental studies in the animal body of evidence that evaluated the association between acute exposure to sarin and ChE effects. Experimental animal studies used various species, strains, methods of exposure, and locations from which ChE levels were measured (e.g., blood, plasma, different areas of the brain). The studies primarily measured AChE in the blood, plasma, or in sections of the brain (see Figure A-4 and Figure A-5). Activity in the blood was measured from 26 hours to 90 days after exposure in rats or monkeys. Activity in the brain was measured in the brainstem, cerebellum, corpus striatum, cortex, and hippocampus 3–90 days after exposure in rats (Sprague Dawley or Wistar). Of the studies measuring ChE, varying injection methods for administering the sarin were used (i.e., subcutaneous, intramuscular, intraperitoneal, or intravenous). Studies that measured AChE mRNA (Damodaran et al. 2003) were included in the body of evidence for completeness but did not drive the hazard conclusions.

##### Overall Risk-of-bias Discussion of Body of Evidence

Confidence in the body of evidence for the animal studies was downgraded because of serious concern for risk of bias (see Figure A-10 and Figure A-11). The main risk-of-bias concern with the animal studies was lack of reporting of important details for key risk-of-bias questions (i.e., questions regarding randomization, exposure assessment, and outcome assessment). Only three of the 15 studies indicated that the animals were randomized to treatment. None of the other studies provided details on randomization or how animals were assigned to treatment. In one study in monkeys (Genovese et al. 2007), animals had been treated with other compounds more than 6 months prior to treatment with sarin, but the compounds were not reported nor was it reported if they were ChE inhibitors. The lack of information regarding previous exposures coupled with the lack of information on randomization results in the possibility of serious risk of bias. On the other hand, the strength of the exposure in the animal studies is that they have a known administered sarin dose. Because the sarin was administered via injection, the animals are known to receive that specific dose; however, most of the animal studies (9 of 15) lacked information on the purity of the sarin administered or other possible contaminants (such as other ChE inhibitors) that may have biased the results. Four studies administered sarin with >98% purity, of which three studies stated that the purity was verified. ChE levels were measured using acceptable methods in all studies; however, none of the studies reported that the outcome assessors were adequately blinded to the study group. Because the time period-specific bodies of evidence contain few higher quality studies, the studies were not stratified based on quality (i.e., lower quality studies versus higher quality studies). For the same reason, NTP was unable to compare the results of lower risk-of-bias studies to higher risk-of-bias studies as a way to assess the impact of the unreported information. Although the kinetics and re-synthesis of ChE after exposure may differ in rodents compared with humans, this was not considered a factor, as the time period for rodents was also modified.

##### Effects in the Initial Period after Exposure

The results from 11 experimental studies in animals demonstrated depressed ChE 1–7 days after exposure. Experimental studies in male and female rats demonstrated relatively consistent decreases in blood and plasma ChE levels 1–7 days after exposure. In female rats, RamaRao et al. (2011) found that acute subcutaneous sarin exposure at 120 μg/kg decreased plasma ChE up to 3 days after exposure, but levels normalized by day 7. Decreased blood ChE was also observed in male rats 3 days after intraperitoneal sarin exposure to 12.5 or 50 μg/kg, but the authors did not evaluate blood ChE levels after 3 days (Nieminen et al. 1990). Chaubey et al. (2016) and Chaubey et al. (2017) observed a statistically significant decrease in blood ChE activity through day 7 in male rats exposed subcutaneously to sarin at 80 μg/kg. Although Chaubey et al. (2016) did not measure the levels after day 7 to determine if or when levels returned to control levels, Chaubey et al. (2017) measured blood ChE activity at 11 and 90 days and reported that levels returned to normal by day 11. In contrast to studies that reported depressed ChE 1–7 days after sarin exposure, one study (Bansal et al. 2009) did not observe a decrease in plasma ChE in female rats 3 days after subcutaneous sarin exposure to 80 μg/kg. Experimental studies in monkeys also demonstrated consistent decreases in blood ChE levels 1–7 days after exposure. In monkeys (both African green and rhesus), Genovese et al. (2007) observed a decrease in blood ChE activity from 26 hours to 7 days after exposure. Results for this study were not statistically significant, however, this is not unexpected, as there were only 2–3 monkeys per treatment group.

There is also evidence that tissue ChE activity is decreased in the initial time period of 1–7 days after exposure, although not all studies found a decrease. Gupta et al. (1991) observed a statistically significant decrease in brain ChE levels in the brainstem, cortex, hippocampus, and striatum of Sprague Dawley rats 7 days after exposure to 110 µg/kg sarin. Similarly, Chaubey et al. (2017) observed a statistically significant decrease in brain ChE levels in the cortex, corpus striatum, and hippocampus of male Wistar rats 1 and 7 days after exposure to 80 µg/kg sarin. Brain ChE levels returned to normal in the hippocampus by day 11 but remained depressed in the cortex and corpus striatum. RamaRao et al. (2011) also observed a statistically significant decrease in brain ChE levels in the cerebellum and cortex of Wistar rats 3 days after exposure to sarin at 120 µg/kg, but levels were back to control levels by day 7. Whalley and Shih (1989) measured ChE activity in the brain of male albino rats after exposure to sarin at 120 µg/kg. ChE activity was depressed in the hippocampus and cortex of the brain by approximately 35% at 168 hours (i.e., 7 days). In the striatum, ChE levels were near control levels by day 7. Lower sarin doses of 12.5 and 50 µg/kg caused a significant decrease in brain ChE only in the striatum of Wistar rats 3 days after exposure (Nieminen et al. 1990). This was the only time period evaluated. Decreases were observed in other sections of the brain but were not statistically significant. Tripathi and Dewey (1989) reported decreases in brain ChE levels in mice 1–7 days after exposure to sarin at 80 μg/kg. Scaife and Shuster (1960) observed a decrease in brain ChE in rats (90 μg/kg) and guinea pigs (30 or 35 μg/kg). The authors described the effect as reactivation (or regeneration) and also reported lower-than-normal brain ChE levels in rats at 48 hours and in guinea pigs at 50 and 150 hours. In contrast, another study did not find decreased ChE in brain tissue at similar doses. Bansal et al. (2009) did not observe a change in brain ChE in Wistar rats 3 days after exposure to 80 μg/kg, but they did observe a decrease in brain ChE mRNA. Koelle et al. (1977) observed a decrease in ChE in various nerves and muscle tissue in cats 2–6 days after exposure to 2 μmol/kg.

##### Effects in the Intermediate Period after Exposure

The nine experimental studies that described effects on ChE during this time period also provide evidence of effects on blood ChE in the weeks and months after exposure, but the evidence is less consistent. In rats, as noted above, RamaRao et al. (2011) observed that blood ChE levels were back to control levels by day 7 and were unchanged at 14 and 30 days. Similarly, Chaubey et al. (2017) observed that blood ChE activity in rats returned to normal by day 11 and were unchanged at day 90 after being depressed through day 7. In monkeys, Genovese et al. (2007) observed a decrease in blood ChE activity that was maintained at week 2 following acute exposure to sarin; however, ChE levels began normalizing by week 6. In the rhesus monkey, blood ChE levels were not back to control levels in the 5.87-µg/kg group at 10 weeks following exposure; however, they were back to control levels for the African green monkey at 10 weeks. Results for this study were not statistical significance because there were only 2–3 monkeys per treatment group. Pearce et al. (1999) also studied monkeys, but only provided qualitative results indicating that mean erythrocyte ChE inhibition was 51.3% at 3 hours but returned to baseline 4–45 weeks later and was not statistically significant at 3 months post-exposure.

As noted above, there is evidence that acute sarin exposure alters ChE activity in different regions of the brain in rats during the first week following exposure, but there may be compensatory upregulation of activity because increases were statistically significant in ChE observed in the brainstem, cerebellum, and midbrain of rats 15 days after exposure (Abou-Donia et al. 2002). Conversely, levels in the cortex were significantly decreased. Jones et al. (2000) only evaluated ChE activity 90 days after exposure in the cortex and brainstem of rats administered sarin via intramuscular injection. Cortex ChE was inhibited by about 30% in the animals receiving 100 μg/kg sarin, although the effect was not statistically significant due to high variability. The brainstem ChE, however, was significantly increased 90 days after exposure. Chaubey et al. (2017) observed statistically significant decreases in brain ChE levels in the cortex and corpus striatum of rats at 11 and 90 days following exposure to 80 μg/kg sarin via subcutaneous injection. ChE levels in the hippocampus were depressed through day 7 but returned to normal by day 11 (Chaubey et al. 2017). For mice, decreases in ChE levels in the brain were maintained 2 weeks after exposure to 80 μg/kg (Tripathi and Dewey 1989). Scaife and Shuster (1960) observed lower-than-normal brain ChE (described as reactivation) in rats at 90 μg/kg at 312 hours. Koelle et al. (1977) observed a decrease in ChE levels in various nerves and muscle tissue in cats through 18 days. Although significance was not measured in terms of control levels, ChE levels were <10% of the control within 30 minutes and increased gradually through the 18 days.

##### Effects in the Extended Period after Exposure

There is no animal evidence to evaluate the potential association between sarin exposure and effects >90 days after exposure in rodents or 1 year in nonhuman primates.

#### Integration of Evidence for Cholinesterase

There is consistent evidence that ChE levels are reduced in humans and animals after acute exposure to sarin, however, the evidence varies based on the length of time after exposure. There is high confidence in the human data in the initial period after exposure, but lower confidence in the intermediate period after exposure based on limitations in the body of evidence largely due to the relative paucity of clinical studies other than case reports. The data in the extended period after exposure are inadequate to evaluate potential effects based on the limited number of studies and the limitations in the one study that was available. There is moderate confidence in the animal data for both the initial period and intermediate period with no data for the extended period after exposure. The uncertainty in the animal evidence is mainly due to lack of reporting information necessary to evaluate risk-of-bias concerns and the heterogeneity of the data concerning the outcomes measured, when the outcomes were measured, the species or strain used, and the method for administering sarin. These confidence ratings translate directly into level-of-evidence conclusions and support an initial hazard identification conclusion based on the different times as detailed below.

##### Effects in the Initial Period after Exposure

- Human body of evidence: High confidence = High level of evidence
- Animal body of evidence: Moderate confidence = Moderate level of evidence
- Initial hazard conclusion (High Human × Moderate Animal) = Known to be a neurological hazard to humans
- Final hazard conclusion for the initial period (after consideration of biological plausibility) = Known to be a neurological hazard to humans

##### Effects in the Intermediate Period after Exposure

- Human body of evidence: Low confidence = Low level of evidence
- Animal body of evidence: Moderate confidence = Moderate level of evidence
- Initial hazard conclusion (Low Human × Moderate Animal) = Suspected to be a neurological hazard to humans
- Final hazard conclusion for the intermediate period (after consideration of biological plausibility) = Suspected to be a neurological hazard to humans

##### Effects in the Extended Period after Exposure

- Human body of evidence: Low confidence with no evidence = Inadequate level of evidence
- Animal body of evidence: No studies = Inadequate level of evidence
- Initial hazard conclusion (Inadequate Human × Inadequate Animal) = Not classifiable
- Final hazard conclusion for extended period (after consideration of biological plausibility) = Not classifiable

Taken together, the human and animal bodies of evidence provide a consistent pattern of findings in the initial period after exposure that acute sarin exposure is associated with decreased ChE levels. The body of evidence for the intermediate period is more limited as it is based primarily on case reports in humans, and the data are less consistent in the animal literature during this time period. The body of evidence is inadequate in the extended period due to only a single study in humans, which did not observe an effect at 5 years after exposure. It is well established that sarin binds to and inactivates AChE (Gunderson et al. 1992; Hargreaves 2012; Spradling and Dillman 2011).

The buildup of the acetylcholine is associated with the cholinergic effects observed with higher exposures to organophosphates including sarin. Treatment for people exposed to sarin typically includes oximes to break the bond between sarin and AChE before the dealkylation process referred to as aging has occurred, which results in irreversible enzyme inhibition. The half-life for sarin aging is 5 hours (Brown and Brix 1998). It can take up to 3 months for the ChE to regenerate (Brown and Brix 1998), which correlates to the time period covered by much of the human data evaluated for this assessment. Although this ChE inhibition and regeneration may explain the ChE findings through 3 months after exposure, there are no mechanistic data available to help determine if there are potential effects longer than 3 months. Although ChE was evaluated in multiple studies at longer time periods, as it is a known acute effect of sarin, potential health effects due to prolonged ChE inhibition are unknown.

### Visual and Ocular

Initial signs of acute intoxication with OP nerve agents include narrowing of the pupil of the eye (miosis). This is considered a sensitive and early presentation of acute exposure (Brown and Brix 1998). Miosis is also used as the basis for establishing threshold exposure limits for military occupational exposure and is considered as a sign of possible high-level exposure (Brown and Brix 1998). This section describes long-term visual or ocular effects (e.g., miosis or narrowing of the pupil) that are reported to occur after acute sarin exposure. The data include outcomes from medical evaluations (e.g., pupillary response, miosis, pupil diameter, visual evoked potential [VEP]) and self-reported symptoms (e.g., blurred vision, dimmed vision, double vision, ocular pain).

#### Human Visual and Ocular Data

##### Summary

The available studies support a rating of moderate confidence in the body of evidence that acute sarin exposure is associated with visual or ocular effects in humans over the initial period of 1–7 days following initial exposure, moderate confidence that visual or ocular effects persist over the intermediate period of 8 days to 1 year, and low confidence over the extended period of ≥1 year. The studies that provide visual or ocular data 1–7 days after acute exposure to sarin, including five case reports/series (Morita et al. 1995; Nohara and Segawa 1996; Ohtomi et al. 1996; Sekijima et al. 1995; Sidell 1974), showed consistent effects of miosis and other visual or ocular parameters (e.g., visual field abnormalities, conjunctival hyperaemia). The studies that provide data on visual or ocular effects for a period of weeks to months, including eight case series (Morita et al. 1995; Nakajima et al. 1998; Nohara and Segawa 1996; Ogawa et al. 1999; Ohtomi et al. 1996; Okudera 2002; Rengstorff 1985; Sidell 1974) and two cross-sectional studies (Murata et al. 1997; Yokoyama et al. 1998a), showed consistent evidence that miosis occurred but recovered within the first 1–2 months after exposure, whereas other visual or ocular effects persisted from weeks to months in some of the study subjects, and VEPs were found to be significantly slower 6 to 8 months following exposure. The studies that provide data on visual or ocular effects for a period of years, including four case reports/series (Kawana et al. 2001; Ohtani et al. 2004; Okumura et al. 2005; Sekijima et al. 1997) and one prospective cohort study (Nakajima et al. 1999), showed evidence that other visual or ocular effects (e.g., ocular pain, blurred vision) persisted 1–5 years following exposure. Although results provide evidence of visual or ocular effects from days to years following acute sarin exposure, there are limitations in the human body of evidence due to risk-of-bias concerns and uncertainties related to the availability of only case reports/series. Moderate confidence in the body of evidence for the initial period following exposure is primarily based on the consistent pattern of findings of miosis from the five case series/reports. Although the prevalence of miosis and the magnitude of pupil constriction in the initial time period following acute sarin exposure is considered fairly consistent and large, respectively [e.g., Ohtomi et al. (1996) reported that 95% of 62 subjects had miosis 1 day following exposure with 39% of subjects having miotic pupils of ≤1 mm, and Morita et al. (1995) observed pupil diameters ≤1.5 mm during the first 2 days following exposure in approximately 50% of 219 subjects], these factors alone might not warrant an upgrade in confidence due to the limited number of studies and limitations due to study design (i.e., case reports/series only); however, when considered collectively and supported by the well-established response of immediate constriction of the pupils in the first 24 hours following acute sarin exposure, the initial low confidence was upgraded once to support a final rating of moderate confidence in the body of evidence for the initial period. Moderate confidence in the body of evidence of visual or ocular effects for the intermediate period following exposure is based on two cross-sectional studies with an initial and final confidence of moderate. This finding is supported by data from eight case series, which also reported visual or ocular effects. The case series that reported effects at the intermediate period had an initial confidence of low and were downgraded once for serious risk-of-bias concerns. Low confidence in the body of evidence for visual or ocular effects for the extended period following exposure is based on one cohort study with support from four case reports/series. The initial confidence of moderate for the cohort study was downgraded once for serious risk-of-bias concerns (i.e., potential biases in outcome assessment from self-reporting of symptoms via questionnaires and loss of subjects over time) to support a final rating of low confidence in the body of evidence for extended period following acute sarin exposure. This is supported by data from four case reports/series, which also reported visual or ocular effects. These case reports/series had an initial confidence rating of low that was downgraded once for serious risk-of-bias concerns.

The available epidemiologic studies in the human body of evidence that evaluated the association between acute exposure to sarin and visual or ocular effects varied in the timing of the outcome measurement (>24 hours to up to 5 years), the parameters that were measured, and study design (see Table 7). Most of the data are from case reports/series, and therefore there is lower confidence in much of the data due to limitations in that study design (e.g., no controlled exposure and generally no concurrent control). Exposure scenarios varied greatly and included accidental occupational exposures and exposures resulting from two separate terrorist attacks. However, specific exposure levels were not known in any of the studies and were often based on initial symptoms (including the ocular effects) in some subjects, which were obtained via questionnaire in some cases. The data set included one prospective cohort study (Nakajima et al. 1999) conducted on all inhabitants in the area around the Matsumoto sarin release site, two cross-sectional studies that report on the same subjects from the Tokyo subway attack (Murata et al. 1997; Yokoyama et al. 1998a), and 13 case series/reports on subjects involved in the Matsumoto and Tokyo attacks (Kawana et al. 2001; Morita et al. 1995; Nakajima et al. 1998; Nohara and Segawa 1996; Ogawa et al. 1999; Ohtani et al. 2004; Ohtomi et al. 1996; Okudera 2002; Okumura et al. 2005; Sekijima et al. 1995; Sekijima et al. 1997) or exposed accidentally in the workplace (Rengstorff 1985; Sidell 1974). Studies were all conducted in adults with a range in sample sizes of 2–1,743 subjects. The only studies with control groups were the cohort study, Nakajima et al. (1999) (318 exposed, 919 control—grouped based on self-reported diagnosis of sarin-related symptoms immediately following sarin release), and the two cross-sectional studies (18 of the approximately 5,000 passengers exposed to sarin during the Tokyo subway attack and 15 to 18 sex- and age-matched control subjects) (Murata et al. 1997; Yokoyama et al. 1998a). The visual effects reported included outcomes diagnosed by a clinician (e.g., miosis), measurements during a medical exam (e.g., pupil diameter), and self-reported symptoms via questionnaires.

Table 7 Studies on Visual or Ocular Effects in Humans

Study | Study Design (Location/Study) [n] | Exposure Measure Timing | Assessment Timing | Analysis | Visual/Ocular Outcome Summary
Initial Time Period after Exposure (>24 hours–7 days)
Morita et al. (1995) | Case series (Japan/Matsumoto) [219] | Terrorist attack, single exposure (not measured) | 2 days | Miosis (pupil size measured in 219 people with 49 examined by an ophthalmologist) | Pupil diameter was <1 mm for 21 individuals, 1.5 mm for 87, 2 mm for 6, and 2.5 mm for 32 during the first 2 days after exposure; 124 patients had decreased visual acuity with miosis; examination revealed a decreased amplitude of accommodation which recovered within several days; 39 people complained of visual field abnormalities
Nohara and Segawa (1996) | Case series (Japan/ Matsumoto sarin attack victims) [51] | Terrorist attack, single exposure (not measured) | 1, 2, 3, 4, and 7 days | Pupil diameter as measured during medical examination [n = 4–15]; self-reported symptoms and ocular signs | Pupillary diameter was small (mean 1.55 mm day 1) and appeared to increase over time (mean 3.9 mm day 7); several ocular symptoms, but the timing is unclear; conjunctival hyperaemia and concentric contraction of the visual fields were common within the first 4 days
Ohtomi et al. (1996) | Case series (Japan/ Tokyo sarin attack victims) [62] | Terrorist attack, single exposure (not measured) | 1 day, 1 week | Miotic pupils ≤1 mm (right eye) as measured during medical examination | Day 1: 95% of victims had miosis, although 39% of victims had miotic pupils ≤1 mm; other ocular manifestations at 1 week: ciliary and conjunctival congestion (16 subjects), ocular and periorbital pain (28 subjects), dim vision (6 subjects), blurred vision (33 subjects), ocular irritation (8 subjects), and visual field abnormality (8 subjects)
Sekijima et al. (1995) | Case report (Japan/Matsumoto) [1 19-year-old man] | Terrorist attack, single exposure (not measured) | 1 week | Pupil diameter | Pupil effects diminished after approximately 1 week
Sidell (1974) | Case series (United States/accidental occupational exposure) [3 men; 27, 50, and 52 years old] | Accidental exposure to vapors while working, single exposure (not measured); symptoms included respiratory distress and marked miosis with slight eye pain | 3 and 6 days following sarin exposure | Ratio of diameter of the pupil to diameter of the iris calculated from a greatly enlarged photograph; calculated as % of the ratio obtained 3–4 months after exposure | All men had marked miosis during the first 24 hours; recovery of miosis reported to be prolonged; pupil/iris diameter was 50.5–53.9% (mean 52.1%) of control values at 3 days and 64.1–75.5% (mean 69.8%) of control values at 6 days; about 60–70% of the lost ability to dark adapt returned in two weeks
Intermediate Time Period after Exposure (8 days–1 year)
Morita et al. (1995) | Case series (Japan/Matsumoto) [219] | Terrorist attack, single exposure (not measured) | 2 days, 1 month | Miosis (pupil size measured in 219 people with 49 examined by an ophthalmologist) | Only qualitative statement indicating that miosis disappeared within a month in all people examined
Murata et al. (1997) | Cross-sectional (Japan/Tokyo subway attack victims) [36] | Terrorist attack, single exposure (not measured) | 6 months | VEP | P100 latency in sarin cases were significantly prolonged when compared with matched controls
Nakajima et al. (1998) ^a^ | Case series (Japan/Matsumoto) [1,743 at 3 weeks and 105 at 4 months] | Terrorist attack, single exposure (not measured) | 3 weeks and 4 months | Self-reported symptoms | Diplopia (i.e., double vision): 3 subjects at 3 weeks and 4 months (presumably the same subjects)
Nohara and Segawa (1996) | Case series (Japan/Matsumoto sarin attack victims) [51] | Terrorist attack, single exposure (not measured) | 9 days following sarin exposure | Pupil diameter as measured during medical examination | Pupillary diameter was small during the first week (mean 1.55 mm day 1) and appeared to increase over time (mean 4 mm day 9)
Ogawa et al. (1999) | Case series (Japan/Tokyo subway attack) [681] | Terrorist attack, single exposure (not measured) | 2 months | Self-reported symptoms | At 2 months subjects still reported: dimness of vision (2.6%), constricted visual field (2.2%), eye irritation (4.4%), blurred vision (6.5%), eye pain (4.6%), increased lacrimation (0.4%), and double vision (1%)
Ohtomi et al. (1996) | Case series (Japan/Tokyo subway attack victims) [62] | Terrorist attack, single exposure (not measured) | 4, 8 weeks and 3 months | Miotic pupils ≤1 mm (right eye) as measured during medical examination | Recovery of miosis was complete within 2 months; other ocular manifestations still reported to occur at 3 months: ciliary and conjunctival congestion (5 subjects), ocular and periorbital pain (10 subjects), dim vision (1 subject), blurred vision (5 subjects), ocular irritation (3 subjects), and visual field abnormality (2 subjects)
Okudera (2002) | Case series (Japan/Matsumoto) [155] | Terrorist attack, single exposure (not measured) | 3 weeks | Examination most results self-reported symptoms | Ocular symptoms reported after 3 weeks include: ocular pain (14 subjects), darkness of visual field (13 subjects), and eye weakness (10 subjects); the pupil size was smaller in subjects complaining of eye weakness, but no measurements were provided; although blurred vision was noted at 1 year, no details including number of subjects with effect were reported
Rengstorff (1985) | Case series (United States/accidental occupational exposure) [2 men; 46 and 53 years old] | Accidental exposure to vapors while working, single exposure (not measured); exposure confirmed by depressed ChE activity and miotic pupils | Over 90-day period (starting at 11 days after exposure) | Pupil diameter and reaction assessed in darkened room using “black light” (ultraviolet) stimulation and mm ruler, a procedure sensitive to ± 0.5 mm | Both men had fixed, slightly irregular pupils (<1 mm in diameter) which remained unchanged for 24 hours; 11 days after exposure, pupils widened to about 2 mm; pupils continued to increase in size and stabilized between 30 and 45 days
Sidell (1974) | Case series (United States/accidental occupational exposure) [3 men; 27, 50, and 52 years old] | Accidental exposure to vapors while working, single exposure (not measured); symptoms included respiratory distress and marked miosis with slight eye pain | 13, 20, 27, 41, and 62 days following sarin exposure | Ratio of diameter of the pupil to diameter of the iris calculated from a greatly enlarged photograph; calculated as % of the ratio obtained 3–4 months after exposure | About 60–70% of the lost ability to dark adapt returned in 2 weeks, but complete recovery took 2 months; pupil/iris diameter was 78.4–89.7% (mean 83.9%) of control values at 13 days and gradually returned to approximately 100% of control values by 62 days
Yokoyama et al. (1998a) ^a^ | Cross-sectional (Japan/Tokyo subway attack victims) [36] | Terrorist attack, single exposure (not measured) | 6–8 months | VEP | P100 latency in sarin cases were significantly prolonged when compared with matched controls
Extended Time Period after Exposure (≥1 year)
Kawana et al. (2001) | Case series (Japan/Tokyo subway attack victims) [191–283 depending on survey year] | Terrorist attack, single exposure (not measured) | 2, 3, 5 years after exposure | Self-reported symptoms | Subjects reported tiredness of eye (33.5–39.3%), dim vision (23.3–25.7%), difficulty seeing distance (18.0–21.5%), and difficulty seeing close (13.1–17.7%), eye discharge (8.9–11.0%), strange feeling in eyes (5.3–9.4%), and other eye symptoms (3.9–5.2%)
Nakajima et al. (1999) | Prospective cohort (Japan/Matsumoto) [1,237 at 1 year and 836 at 3 years] | Terrorist attack, single exposure (not measured, and self-reported exposure based on hospital patient status) | 1 and 3 years after exposure | Self-reported symptoms | Blurred vision, narrowing of visual field, and asthenopia (not significantly different between patients and nonpatients at 1 year, but significantly increases in victims at 3 years)
Ohtani et al. (2004) | Case series (Japan/Tokyo subway attack victims) [34] | Terrorist attack, single exposure (not measured) | 5 years | Self-reported symptoms | Eyes tend to become easily tired (19 subjects), blurred vision (20 subjects), difficulty seeing far (17 subjects), difficulty seeing nearby objects (13 subjects), difficulty in focusing (23 subjects), eye mucus (11 subjects), feeling of a foreign object in the eye (9 subjects), other eye symptoms (2 subjects)
Okumura et al. (2005) | Case series (Japan/Matsumoto) [303] | Terrorist attack, single exposure (not measured) | 1 year | Self-reported symptoms | 18.5% reported eye symptoms after 1 year
Sekijima et al. (1997) | Case report (Japan/Matsumoto) [1 46-year-old man] | Terrorist attack, single exposure (not measured) | 12–17 months | Self-reported symptoms | One subject reported visual field defects at the 1-year follow-up exam, but was noted to be completely recovered by 17 months

VEP = visual evoked potential.

^a^ The data from these two studies for this effect appear to be from the same subjects.

##### Overall Risk-of-bias Discussion of Body of Evidence

Confidence in the body of evidence for the human studies was downgraded because of serious concern for risk of bias. Risk-of-bias ratings for individual studies for all questions are available in Figure A-15 through Figure A-18. There are a number of risk-of-bias issues in the evidence relating to design and conduct of individual studies as well as general limitations (i.e., not risk-of-bias issues) based on the case report/series study design. All but three of the human studies are case reports/series, and most of the human studies were rated as probably high risk of bias across multiple key risk-of-bias questions including confounding and lack of blinding of outcome assessors. The prospective cohort study (Nakajima et al. 1999) was also rated probably high risk of bias for loss of subjects over time (the first survey had a response rate of 60.3% [1,237/2,052], and the second survey excluded 52 rescuers and had a response rate of 41.8% [836/2,000], and no comparison was made between those lost to follow-up and those remaining in the study). The two cross-sectional studies had little potential for bias, but they apparently reported on the same subjects.

As discussed previously for the studies on ChE, confounding and lack of blinding of outcome assessors were the principal risk-of-bias issues in most of studies, which were based on one of the two terror attacks or accidental exposures. The majority of studies do not address potential exposure to other organophosphates or potential confounders to address prolonged visual and ocular effects. Blinding of outcome assessors was also a general limitation. For self-reported symptoms, blinding is not possible. Doctors would also not have been blind to exposure. The potential bias of doctor evaluation based on knowledge of exposure cannot be determined. However, in the two cross-sectional studies, blinding of outcome was not an issue because it was reported that assessors were blind or the test was computerized. The lack of addressing potential confounders and the lack of data on blinding at outcome assessment lead to the serious risk-of-bias concern and the single downgrade in the confidence in the body of evidence. Lack of information or specific exposure measures was an issue in many of the studies, but this is not considered to pose a risk-of-bias concern. Most of the studies were based in accidental occupational exposure or one of the two terror attacks. Some of the studies based exposure status on self-reported diagnosis and/or hospital admission, and only in some of the severe cases was the exposure based on the initial decrease in ChE, miosis, or on other initial symptoms at examination. However, it is acknowledged that exposure to sarin occurred in these studies, and therefore, they are considered to not pose a risk-of-bias concern and were assigned a rating of probably low risk of bias for exposure characterization because there is little concern for exposure misclassification, as sarin is not found in the environment.

##### Effects in the Initial Period after Exposure

Case reports/series (336 total subjects) provided consistent results for visual or ocular effects 1–7 days after acute exposure to sarin (Morita et al. 1995; Nohara and Segawa 1996; Ohtomi et al. 1996; Sekijima et al. 1995; Sidell 1974). Miosis was consistently diagnosed in almost all subjects by examination within hours of exposure and generally persisted during the first week (later resolved by 1–2 months; for some of the studies it is not clear when the miosis resolved as it was only noted to be resolved by a specific time). Ohtomi et al. (1996) reported that 95% of 62 subjects had miosis 1 day following exposure with 39% of subjects having miotic pupils of ≤1 mm. Nohara and Segawa (1996) reported miosis in subjects (<4 mm: 80% of 51 subjects; <2 mm: 41% of 51 subjects) following acute sarin exposure (presumably within the first 24 hours following exposure). In subjects who received pupil examinations over time, pupillary diameter gradually increased through day 7 (mean 1.55 mm at 1 day [n = 13]; mean 3.9 mm at day 7 [n = 5]) (see Figure A-12). A case report on one severe case from the Matsumoto attack did not report quantitative results on pupil effects, but reported that pupil effects were resolved within a week of exposure (Sekijima et al. 1995). Morita et al. (1995) reported that miosis was the most common sign in 219 subjects evaluated, with a diameter <1 mm for 21 subjects, 1.5 mm for 87 subjects, 2 mm for six subjects, and 2.5 mm for 32 subjects during the first 2 days after exposure. A case series on three subjects with occupational exposures to sarin reported marked miosis during the initial examinations following exposure (within the first 24 hours) with “prolonged recovery” (recovery time not reported). Three days after exposure, the mean ratio of diameter of the pupil to diameter of the iris was 52.1% of control values, which increased to 69.8% of control values by 6 days following exposure (Sidell 1974) (see Figure A-13).

In addition to miosis and pupil-related ocular effects, the available studies consistently reported other visual or ocular effects (e.g., visual field abnormalities, conjunctival hyperaemia) in subjects 1–7 days after acute exposure to sarin; however, the data were more heterogeneous and in many cases based on self-reported symptoms. Morita et al. (1995) reported that 124 of 219 patients (57%) had decreased visual acuity with miosis. Some subjects showed concentric defects that recovered within a few days despite continued miosis, and examinations revealed decreased amplitude of accommodation which recovered within several days. Thirty-nine of 219 patients (18%) also complained of visual field abnormalities. Nohara and Segawa (1996) reported qualitatively that conjunctival hyperaemia and concentric contraction of the visual fields were common within the first 4 days following the acute exposure, but these conditions generally improved. Contrary to Morita et al. (1995)[underlined: ,] visual acuity did not appear to be diminished in most subjects (Nohara and Segawa 1996). At 1 week following the Tokyo subway sarin attack, Ohtomi et al. (1996) reported that 33 of 62 hospital patients (53%) reported blurred vision (compared with 87% of the 62 patients initially after exposure), 28 of 62 patients (45%) reported ocular and periorbital pain (76% initially), and 16 of 62 patients (26%) reported ciliary and conjunctival congestion (87% initially). In addition, some patients still reported decreased intraocular pressure (15% at 1 week; 48% initially), ocular irritation (13% at 1 week; 58% initially), visual field abnormality (13% at 1 week; 31% initially), and dim vision (10% at 1 week; 87% initially) (Ohtomi et al. 1996).

These case reports/series provide a consistent pattern of findings that miosis and other visual or ocular parameters persist 1–7 days after acute exposure to sarin. Other ocular and visual effects were not examined or reported in all studies, but additional ocular and visual effects beyond miosis are consistently reported to persist over the first week following exposure. The limitations of the case reports/series include the risk-of-bias concerns discussed above and small sample sizes in two of the studies. However, risk of bias was not considered serious because two of the five studies (Sekijima et al. 1995; Sidell 1974) were assigned a rating of probably low risk of bias for outcome assessment as hospital tests would not likely be biased based on knowledge of exposure.

##### Effects in the Intermediate Period after Exposure

The results from eight case series (2,916 total subjects) and two cross-sectional studies (n = 36, assuming both studies report on the same participants) provided consistent results for recovery of miosis within the first 2 months after exposure, the persistence of other ocular and visual effects (e.g., ocular pain, blurred vision) in some of the study subjects, for weeks to at least months after exposure, and for slower VEPs, 6–8 months following exposure. The studies that followed sarin-exposed subjects diagnosed with miosis beyond the first 1–2 weeks reported complete recovery or stabilization within 1–2 months (Morita et al. 1995; Ohtomi et al. 1996; Rengstorff 1985; Sidell 1974). The findings on miosis from the case series include five occupationally exposed subjects, 62 individuals involved in the Tokyo sarin attack, and 4–15 subjects involved in the Matsumoto attack.

Most visual and ocular symptoms reported were generally reduced from 3 weeks to at least 4 months following acute sarin exposure; however, small percentages of individuals involved in the Tokyo and Matsumoto sarin attacks reported one or more remaining ocular and visual symptoms during this time period. Rengstorff (1985)reported that visual acuity and amplitude of accommodation improved within 3–5 weeks in two subjects accidentally exposed to sarin. Nakajima et al. (1998) reported that 3 weeks after exposure, blurred vision persisted in 25% of the 87 subjects who reported blurred vision immediately after the terror attack. In addition, blurred vision was reported by Ohtomi et al. (1996)in 17 of 62 subjects (27%) at 4 weeks; by Ohtomi et al. (1996) and Ogawa et al. (1999) in 10 of 62 subjects (16%) at 8 weeks and in 44 of 681 subjects (6.5%) at 2 months, respectively; by Ohtomi et al. (1996) in 5 of 62 subjects (8.1%) at 3 months; and by Nakajima et al. (1998) in 5 of 105 subjects (4.8%) at 4 months after exposure. Nakajima et al. (1998) reported that 3 weeks after exposure, ocular pain persisted in 21% of the 114 subjects who reported ocular pain immediately after the terror attack. Ocular pain was also reported by Okudera (2002) in 14 of 155 subjects (9.0%) at 3 weeks; by Ohtomi et al. (1996) in 9 of 62 subjects (15%) at 4 weeks; by Ohtomi et al. (1996) and Ogawa et al. (1999) in 6 of 62 subjects (9.7%) at 8 weeks and in 31 of 681 subjects (4.6%) at 2 months, respectively; by Ohtomi et al. (1996) in 10 of 62 subjects (16%) at 3 months; and by Nakajima et al. 1998 in 4 of 105 subjects (3.8%) at 4 months after exposure. Other visual or ocular effects that persisted in small percentages of subjects from 3 weeks to at least 4 months after exposure include dimness of vision, eye irritation or weakness, increased lacrimation, ciliary and conjunctival congestion, and visual field abnormalities including constricted or narrowing of visual field, darkness of visual field, flickering of vision, and double vision (Nakajima et al. 1998; Ogawa et al. 1999; Ohtomi et al. 1996; Okudera 2002). The gradual decline in these other reported visual and ocular effects in subjects involved in the Tokyo and Matsumoto sarin attacks also supports recovery over several months following exposure, although some of subjects continued to report symptoms beyond 4 months (Figure 8). In the only two studies with controls that reported effects <1 year after acute sarin exposure, VEPs were found to be significantly (p < 0.05) slower in sarin cases compared with unexposed controls 6 to 8 months following exposure (Murata et al. 1997; Yokoyama et al. 1998a).

Figure 8

Visual and Ocular Evidence Profile for Sarin

References: Human: Kawana et al. (2001),^e^ Morita et al. (1995),^a,b^ Murata et al. (1997),^c^ Nakajima et al. (1998),^b^ Nakajima et al. (1999),^d^ Nohara and Segawa (1996),^a,b^ Ogawa et al. (1999),^b^ Ohtani et al. (2004),^e^ Ohtomi et al. (1996),^a,b^ Okudera (2002),^b^ Okumura et al. (2005),^e^ Rengstorff (1985),^b^ Sekijima et al. (1995),^a^ Sekijima et al. (1997),^e^ Sidell (1974),^a,b^ Yokoyama et al. (1998a).^c^Animal: Egoz et al. (2017),^f^ Gore et al. (2012),^f^ Kassa et al. (2001a),^g^ Mioduszewski et al. (2002).^f^

These case series and cross-sectional studies provide a consistent pattern of findings that miosis persists past 1 week and recovers within 1–2 months after exposure, other visual or ocular parameters (e.g., ocular pain, blurred vision) generally recover but persist in small percentages of subjects from 3 weeks to at least 4 months after exposure, and that slower VEPs persist 6–8 months following acute exposure to sarin. The limitations of the case series include the risk-of-bias concerns discussed above. The two cross-sectional studies had little potential for bias, but they apparently reported on the same subjects.

##### Effects in the Extended Period after Exposure

The results from four case reports/series (621 total subjects) and one prospective cohort (n = 1,237) provide evidence of the persistence of other ocular and visual effects (e.g., ocular pain, blurred vision) in participants for 1–5 years after exposure. Nakajima et al. (1999) found that blurred vision, asthenopia, and narrowing of visual field were significantly higher among sarin victims (those diagnosed with, or reporting, sarin symptoms immediately after the attack) than nonvictims (those not reporting symptoms immediately after exposure) at 3 years after the Matsumoto sarin attack. Small percentages of participants reported blurred vision, asthenopia, and narrowing of visual field 1 year after the sarin attack as well, but the prevalence was not statistically different compared with controls. Four case reports/series reported visual or ocular symptoms in exposed subjects 1, 2, 3, and 5 years after sarin exposure in the Tokyo and Matsumoto attacks (Kawana et al. 2001; Ohtani et al. 2004; Okumura et al. 2005; Sekijima et al. 1997). In all of the studies, symptoms were self-reported via survey. Okumura et al. (2005) reported that 56 of 303 subjects (18.5%) reported eye symptoms 1 year after the Matsumoto attack. Sekijima et al. (1997) reported on one subject following the Matsumoto attack who reported visual field defects 1 year following the sarin exposure with complete recovery by 17 months. Kawana et al. (2001) reported higher rates of eye symptoms (tiredness of eyes, dim vision, difficulty focusing, difficulty seeing distance) compared with other physical symptoms at 2, 3, and 5 years after exposure. However, the authors suggested the physical symptoms may be related to PTSD. Ohtani et al. (2004) reported eye effects in 34 victims of the Tokyo subway attack by questionnaire 5 years after the incident, which included difficulty focusing (n = 23 of 34; 68%), blurred vision (n = 20 of 34; 59%), eyes tend to become easily tired (n = 19 of 34; 56%), difficulty seeing far (n = 17 of 34; 50%), difficulty seeing nearby objects (n = 13 of 34; 38%), eye mucus (n = 11 of 34; 32%), feeling of a foreign object in the eye (n = 9 of 34; 26%), and other eye symptoms (n = 2 of 34; 5.9%).

These case reports/series and prospective cohort study provide a consistent pattern of findings that visual and ocular parameters (e.g., blurred vision, difficulty focusing) persist in subjects 1–5 years after exposure. The limitations of the case reports/series and prospective cohort include the risk-of-bias concerns discussed above, which include failure to control for confounding and potential biases in outcome assessment from self-reporting of symptoms via questionnaires, as well as loss of subjects over time.

Collectively, epidemiological studies provide evidence that acute sarin exposure is associated with miosis 1–7 days after exposure with complete recovery in most cases 1–2 months after exposure, slower VEPs 6–8 months following exposure, and the persistence of other ocular and visual effects (e.g., ocular pain, blurred vision, difficulty focusing) in small percentages of subjects from days to several years after exposure. The data present a consistent pattern of findings with different levels of confidence depending on the time period after exposure. Most of the studies are from case reports/series, which results in less confidence in the association between sarin and visual effects. There is moderate confidence in the body of evidence in the initial period based on the consistency of the evidence of miosis from case reports/series, moderate confidence in the body of evidence in the intermediate period based on two cross-sectional studies, and low confidence in the body of evidence in the extended period based on one prospective cohort study and four case reports/series.

#### Animal Visual and Ocular Data

##### Summary

There is very low confidence in the body of evidence that acute sarin exposure is associated with visual or ocular effects in animals over the intermediate and extended periods. The animal body of evidence consists of three studies (Egoz et al. 2017; Gore et al. 2012; Mioduszewski et al. 2002) that evaluated pupil diameter over the initial period of 1–7 days (Egoz et al. 2017; Gore et al. 2012; Mioduszewski et al. 2002) and one study (Kassa et al. 2001a) that evaluated visual functional observational battery (FOB) scores 3–12 months after acute sarin exposure. In the initial period of 1–7 days following exposure, two studies did not find statistically significant sarin-related ocular effects (Egoz et al. 2017; Gore et al. 2012). One study did observe a sarin-related effect on pupil diameter in the initial period following exposure (Mioduszewski et al. 2002); however, the pattern of effect (i.e., a reduction in pupil diameter during the first hour followed by an increase above normal after 24 hours, which mostly diminished by 7 days after exposure) was not consistent with other animal data or the human data (see Figure A-14). In the intermediate and extended periods following exposure, one study explored visual parameters 3–12 months after an acute exposure and reported no effect in visual FOB scores (Kassa et al. 2001a). There are multiple limitations in the body of evidence, including a small number of available studies and risk-of-bias concerns. As described below, the judgement was reached to downgrade the bodies of evidence for the intermediate and extended periods by three levels to reflect overall concerns across multiple downgrade factors (i.e., risk of bias and inconsistency).

For the initial time period, the initial rating of high confidence for the animal body of evidence was downgraded once for unexplained inconsistencies. Although it is recognized that study results differed by strain and method of exposure, there are too few studies to definitively explain the inconsistency in results. Overall, because two of three studies in the initial period did not observe statistically significant sarin-related ocular effects after 24 hours following exposure, and the pattern of effect observed in the one study that reported an ocular effect after 24 hours did not correspond with other animal data or the human data, the body of evidence for the initial time period following acute sarin exposure is considered inadequate to evaluate whether sarin exposure is associated with ocular effects. For the intermediate and extended periods, the initial high confidence ratings for the animal body of evidence were downgraded twice for very serious risk of bias including the following key questions: lack of randomization, lack of blinding of outcome assessors, lack of information regarding methods for inhalation exposure, and the use of sarin with 90% purity without providing information on the remaining 10% to indicate that there were no impurities that could affect the results. Confidence in the body of evidence for intermediate and extended periods was also downgraded once for the inability to evaluate consistency based on a single study available to support a final confidence rating of very low for the intermediate and extended periods (see Figure 8).

Four animal studies in the animal body of evidence evaluated the association between acute sarin exposure and long-term ocular effects (Egoz et al. 2017; Gore et al. 2012; Kassa et al. 2001a; Mioduszewski et al. 2002). All studies were conducted in rats, but different strains were used. Three studies evaluated ocular effects over the initial period of 1–7 days following sarin exposure (Egoz et al. 2017; Gore et al. 2012; Mioduszewski et al. 2002). All three studies evaluated changes in pupil diameter but differed by the strain of rats used and methods of exposure (two male Long-Evans rat topical exposure studies and one male and female Sprague Dawley rat inhalation study). One study evaluated ocular effects in male albino SPF rats 3, 6, and 12 months following a single inhalation exposure to sarin (Kassa et al. 2001a). Effects included pupil size, pupillary response to light, endo-exophthalmos, palpebral closure, or lacrimation as part of a FOB designed to evaluate behavioral and neurophysiological function in exposed animals (Kassa et al. 2001a).

##### Overall Risk-of-bias Discussion of Body of Evidence

Confidence in the body of evidence for the animal study that evaluated ocular effects over the intermediate and extended periods (Kassa et al. 2001a) was downgraded because of very serious risk-of-bias concerns (see Figure A-19 and Figure A-20). Risk-of-bias concerns included a lack of (or lack of reporting of) randomization of animals, lack of information regarding methods for inhalation exposure, lack of blinding of outcome assessors, and the use of sarin with 90% purity without providing information on the remaining 10% to indicate that there were no impurities that could affect the results. In addition, details on how the pupil diameter measurements were taken as part of the FOB were not reported. Although there were some risk-of-bias concerns in the animal studies that evaluated ocular effects over the initial period following exposure, including a lack of (or lack of reporting of) randomization of animals and lack of blinding of outcome assessors in the inhalation study, the concerns were not considered serious enough to downgrade the confidence in the body of evidence for the initial period following exposure.

##### Effects in the Initial Period after Exposure

Three experimental studies in rats examined sarin-related effects on pupil diameter within the first 7 days after sarin exposure and reported inconsistent results. Mioduszewski et al. (2002) evaluated pupil diameter in male and female Sprague Dawley rats (n = 10/sex/treatment group) prior to and up to 7 days after a single inhalation exposure to sarin of varying durations. Pupil constriction was evident within the first hour of exposure. This was followed by increased pupil size to almost pre-exposure size by 24 hours and continued dilation above pre-exposure levels by day 2 (see Figure 8). The expansion in pupil diameter was reduced but was still larger than pre-exposure size by day 7, and the effect was observed at all time points and was dose dependent (Mioduszewski et al. 2002). The exposure levels used in the study were selected for the purpose of deriving an LC_50_, and high incidences of sublethal signs of toxicity were often observed (Mioduszewski et al. 2002). Exposures and associated effects on pupil size may, therefore, not be directly comparable to those in humans.

Gore et al. (2012) and Egoz et al. (2017) evaluated pupil diameter in male Long-Evans rats (n = 12/treatment group) up to 3 days after varying topical sarin exposures ranging from 0.002 to 10 μg (Gore et al. 2012) or up to 7 days after a single topical sarin exposure of 1 μg (Egoz et al. 2017). Gore et al. (2012) and Egoz et al. (2017) observed pupil constriction during the first few hours after exposure; however, neither study reported an increase in pupil size above pre-exposure levels after pupil size returned to baseline. After the initial pupil constriction in the hours following exposure, both studies continued to observe some pupil width reduction at 24 hours [statistically significant in Gore et al. (2012) at 24 hours but not in Egoz et al. (2017)], which fully returned to baseline by 48 hours with no measurement between 24 and 48 hours. Differences in exposure methods (i.e., inhalation versus direct ocular exposure) and/or animal model (Sprague Dawley versus Long-Evans rats) could contribute to the variability of results between studies although these factors alone are unlikely to account for the increase in pupil size observed in Mioduszewski et al. (2002).

##### Effects in the Intermediate Period after Exposure

Only one study evaluated ocular effects in rats (male albino SPF rats; n = 10/treatment group) 3 months after a single exposure (Kassa et al. 2001a). The study found no effects on pupil size, pupillary response to light, endo-exophthalmos, palpebral closure, or lacrimation based on FOB scores after a single inhalation exposure up to 2.5 μg/L. Endpoints were scored as part of an FOB designed to evaluate behavioral and neurophysiological function in exposed animals.

##### Effects in the Extended Period after Exposure

Only one study evaluated ocular effects in rats (male albino SPF rats; n = 10/treatment group) at 6 and 12 months after a single exposure (Kassa et al. 2001a). The study found no effects on pupil size, pupillary response to light, endo-exophthalmos, palpebral closure, or lacrimation based on FOB scores after a single inhalation exposure up to 2.5 μg/L. Endpoints were scored as part of an FOB designed to evaluate behavioral and neurophysiological function in exposed animals.

#### Integration of Evidence for Visual and Ocular Effects

There is evidence that pupil size is reduced (i.e., miosis) in humans 1–7 days after acute exposure to sarin, VEPs are reduced 6–8 months after acute exposure, and other visual and ocular effects (e.g., blurred vision, ocular pain, difficulty focusing) persist in humans during the first week and remain for several months to years after exposure. Although there are limitations in the body of evidence in the initial period largely due to study design (i.e., case reports/series only), there is moderate confidence in the human data in the initial period following acute sarin exposure based on the consistent pattern of findings that miosis occurs 1–7 days after exposure with data supporting miosis persisting for the first several weeks. Across all time points, the evidence for other visual or ocular effects is less consistent due to the limited data and considerable heterogeneity between studies on the visual or ocular parameters that were measured. There is moderate confidence for sarin-associated reductions in VEPs 6–8 months after acute exposure in humans based on two cross-sectional studies with little potential for bias; however, the two studies are presumed to have reported on the same subjects. There is low confidence in the persistence of other visual or ocular effects in the extended period after exposure based on one perspective cohort and four case reports/series due to risk-of-bias concerns.

There is very low confidence in the animal data for the intermediate and extended periods following exposure based on one animal study that evaluated ocular effects (e.g., pupil size, pupillary response to light) and did not find evidence of an effect. The animal body of evidence in the initial period following exposure is considered inadequate to evaluate potential sarin-related effects based on the limited number of studies and no evidence of an effect that corresponds with the human data. Although a decrease in pupil diameter 1–7 days was consistently observed in the human data, this effect was harder to assess in the animal data. Two experimental animal studies found no effect on pupil diameter 48 hours or more after exposure (with no measurement available between 24 and 48 hours after exposure), and one experimental animal study observed an increase in pupil diameter 2–7 days following exposure. These confidence ratings for human and animal bodies of evidence translate directly into level-of-evidence conclusions and support an initial hazard identification conclusion based on the different times as detailed below.

##### Effects in the Initial Period after Exposure

- Human body of evidence: Moderate confidence = Moderate level of evidence
- Animal body of evidence: Moderate confidence with no evidence of an effect that corresponds to the human data = Inadequate level of evidence
- Initial hazard conclusion (Moderate Human × Inadequate Animal) = Suspected to be a neurological hazard to humans
- Final hazard conclusion for the initial period (after consideration of biological plausibility) = Suspected to be a neurological hazard to humans

##### Effects in the Intermediate Period after Exposure

- Human body of evidence: Moderate confidence = Moderate level of evidence
- Animal body of evidence: Very low confidence = Inadequate level of evidence
- Initial hazard conclusion (Moderate Human × Inadequate Animal) = Suspected to be a neurological hazard to humans
- Final hazard conclusion for the intermediate period (after consideration of biological plausibility) = Suspected to be a neurological hazard to humans

##### Effects in the Extended Period after Exposure

- Human body of evidence: Low confidence = Low level of evidence
- Animal body of evidence: Very low confidence = Inadequate level of evidence
- Initial hazard conclusion (Low Human × Inadequate Animal) = Not classifiable
- Final hazard conclusion for extended period (after consideration of biological plausibility) = Not classifiable

### Learning, Memory, and Intelligence

Acetylcholine is a major neurotransmitter involved in learning, memory, and intelligence (Chen 2012; Gais and Schonauer 2017). Acetylcholinesterase (AChE) is responsible for the breakdown of acetylcholine in the synapses of nerve cells. As described earlier in this report, organophosphates— including sarin—inhibit AChE, which disrupts cholinergic neurotransmission (Chen 2012; Lee 2003). This inhibition leads to increased levels of synaptic acetylcholine and subsequent cholinergic hyperstimulation. Because sarin interacts with the cholinergic pathway, based on mechanism alone, it is expected that sarin may affect a variety of behavioral measures. Evidence presented by Chen (2012) suggests that exposure to sarin results in secondary neuronal damage in the cholinergic regions of the brain, and this secondary damage is thought to be a major contributor to neurological impairments related to memory and other cognitive functions.

Learning, memory, and intelligence are considered related cognitive functions; therefore, endpoints related to these cognitive functions in humans and animals are discussed together in the section. Tests in humans that are specific for learning (e.g., California Verbal Learning Test [CVLT]), memory (e.g., digit span, self-reported memory loss, memory function tests), and intelligence (e.g., Wechsler Adult Intelligence Scale [WAIS-III]) are considered relevant. Other tests that include a learning or memory component (e.g., digit symbol test, Thurstone word fluency test, Boston naming test) are also considered. For animals, studies that assess maze performance and discrimination learning activities are included. The differential-reinforcement-of-low-rate (DRL) test measures various components of cognition of which short-term memory is only a small portion. The DRL measurement of cognition also involves vigilance, patience, time estimation, excitability of the animal, and other measures. This test is not discussed here, although it is recognized that it might provide some supporting data. It is also recognized that lack of attention or concentration is a symptom in humans or animals that could affect learning and memory, but these endpoints are not considered in this section, as they were not specifically evaluated in relation to learning and memory issues.

#### Human Learning, Memory, and Intelligence Data

##### Summary

There is low confidence in the body of evidence that acute sarin exposure is associated with impairments to learning, memory, and intelligence in humans over the intermediate period of 8 days to 1 year after exposure and moderate confidence in the body of evidence for the extended period of ≥1 year after exposure. The studies that provide memory data for the intermediate period, including one cross-sectional study (Yokoyama et al. 1998c) and two case reports (Loh et al. 2010; Sekijima et al. 1995), demonstrated some effect on memory or cognitive function, but there is no consistency in the endpoints measured across studies. The studies that provide memory data for the extended period, including two case series studies (Kawana et al. 2001; Ohtani et al. 2004) and two cross-sectional studies (Miyaki et al. 2005; Nishiwaki et al. 2001), report evidence of effects on memory and cognitive function years after sarin exposure using different tests for evaluating memory and cognitive function. Although results show a pattern of findings of impaired learning, memory, and intelligence for a period of weeks to years following acute sarin exposure, there are limitations in the body of evidence including risk-of-bias concerns and uncertainties related to study design of case reports. There is low confidence in the body of evidence for the intermediate period following acute sarin exposure based on one cross-sectional study with a small sample size (n = 18) and two case report studies. None of the studies were downgraded for risk-of-bias concerns. The final rating of low confidence in the intermediate period was supported by heterogeneity of the endpoints evaluated, small sample sizes, and the small number of available studies. Moderate confidence in the body of evidence for the extended period following acute sarin exposure is primarily based on the two cross-sectional studies, which had an initial and final confidence of moderate with support from two case report studies. The two case reports had an initial low confidence rating, which was downgraded to very low confidence for serious risk-of-bias concerns (i.e., failure to control for confounding, potential biases in outcome assessment from self-reporting of symptoms, and few of the initial subjects responded or were included in the study). For the initial period covering 1–7 days following acute sarin exposure, no studies were available; therefore, the body of evidence for this time period is considered inadequate to evaluate whether acute sarin exposure is associated with impairments to learning, memory, and intelligence (see Figure 9).

Figure 9

Learning and Memory Evidence Profile for Sarin

References: Human: Yokoyama et al. (1998c),^a^ Loh et al. (2010),^b^ Sekijima et al. (1995),^b^ Nishiwaki et al. (2001),^c^ Miyaki et al. (2005),^c^ Ohtani et al. (2004),^d^ Kawana et al. (2001).^d^ Animal: Allon et al. (2011),^f,g^ Genovese et al. (2009),^e^ Grauer et al. (2008),^f,g^ Kassa et al. (2001b),^e,f^ Kassa et al. (2002),^e,f^ Kassa et al. (2004),^e,f^ Muggleton et al. (2003),^e,f^ Pearce et al. (1999),^e,f^ Wolthuis et al. (1995).^e^

*The body of evidence was downgraded for inability to evaluate consistency based on the single cross-sectional study (Yokoyama et al. 1998c) with small sample size (n = 18), positive results in a single test, and no other study characteristics that would provide confidence in the effect such as large magnitude or dose response.

The available epidemiological studies in the human body of evidence that evaluated the association between acute exposure to sarin and effects on learning, memory, and intelligence generally evaluated the outcomes months to years after the initial exposure (see Table 8). There are no studies that specifically evaluated these outcomes in the initial period of 1–7 days after exposure. Most studies were conducted in adults who were exposed during the terrorist attack on the Tokyo subway. One case report study reports on an individual exposed during the Matsumoto attack, and one case report study reports on a military man exposed while disarming an improvised explosive device (IED) containing sarin. Studies used different methods for determining effects on learning, memory, and intelligence (e.g., self-reported memory effects as well as memory and other cognitive function tests). Although it cannot be known if the same subjects participated in more than one study evaluating the Tokyo subway attack, two studies were identified that focused on subway workers and rescue personnel, which would indicate that these subjects are different from the studies evaluating the hospital victims.

Table 8 Studies on Learning and Memory Functions in Humans

Study | Study Design (Location/Study) [n] | Exposure Measure Timing | Assessment Timing | Analysis | Learning/Memory Outcome Summary
Initial Time Period after Exposure (>24 hours–7 days)
No studies available.
Intermediate Time Period after Exposure (8 days–1 year)
Sekijima et al. (1995) | Case report (Japan/Matsumoto) [1 19-year-old man] | Terrorist attack, single exposure (not measured) | 10 days | Not reported | Forgetfulness persisted until the 10th day
Yokoyama et al. (1998c) | Cross-sectional (Japan/Tokyo subway system attack victims) [33] | Terrorist attack, single exposure (not measured) | 6 to 8 months | Forward, backward digit span test, paired-associate learning, digit symbol, picture completion | Digit symbol test score significantly lower in sarin cases than in controls; no significant differences in digit span test, paired-associate learning, and picture completion scores
Loh et al. (2010) | Case report (U.S. Military) [1] | Disarming an IED containing colorless liquid determined to be sarin, subject had decreased RBC ChE and symptoms | 8 months | Wechsler memory scale-III, Rey complex figure recall T-scores, self-reported symptoms of memory loss WRAT-III reading test; Boston naming test; Thurstone verbal fluency test; WAIS-III IQ test, PSI, and subtest scaled-arithmetic; California Verbal Learning Test | Self-reported short-term memory loss; although was not noted to have an impairment in any of the memory scores, subject was noted to have impaired recall of words and numbers Decreased verbal fluency T-score; reduced WAIS-III PSI; impaired WAIS-III subtest scaled-arithmetic score; impaired CVLT performance; no IQ impairments/ inefficiencies
Extended Time Period after Exposure (≥1 year)
Kawana et al. (2001) | Case series (Japan/Tokyo subway system attack victims) [582] | Terrorist attack, single exposure (not measured) | 2, 3, and 5 years | Self-reported difficulty with memory; of 582 (St. Luke’s Hospital), 283 questionnaires received in 1997, 206 in 1998, and 191 in 2000; % incidence | 1997–11.7%; 1998–11.2%; 2000–12.6% Data from other cohorts provided for comparison: 24.3% (Tokyo NGO), 19.5% (Matsumoto victims), 12.6% (Matsumoto controls)
Ohtani et al. (2004) | Case series (Japan/Tokyo subway system attack victims) [34] | Terrorist attack, single exposure (not measured) | 5 years | Self-reported forgetfulness count of subjects reporting symptom | Severity of self-reported forgetfulness: 18 none; 14 mild; 2 severe
Miyaki et al. (2005) | Cross-sectional (Japan/Tokyo subway system attack victims–subway workers) [36] Cross-sectional (Japan/Tokyo subway system attack victims–subway workers, rescue staff, and police) [145] | Terrorist attack, single exposure (not measured) | 7 years 3 years (rescue staff, police); 7 years (subway workers) | Memory function tests (forward, backward digit span test; Benton visual memory retention test) | Exposed group performed less well on memory function tests; differences not statistically significant; ORs were generally increased, but had large 95% CI
Nishiwaki et al. (2001) | Cross-sectional (Japan/Tokyo subway system attack victims–rescue staff and police) [106] | Terrorist attack, single exposure (not measured) | 2 years, 10 months to 3 years, 9 months | Memory function tests (forward, backward digit span tests; Benton visual memory retention test) | Effects related to exposure suggested (although not significant) for backward digit span tests; dose-response increase in adjusted OR

OR = odds ratio; CI = confidence interval.

##### Overall Risk-of-bias Discussion of Body of Evidence

Confidence in the body of evidence for the human case series studies was downgraded because of serious concern for risk of bias. Risk-of-bias ratings for individual studies for all questions are available in Figure A-25 through Figure A-28. There are a number of risk-of-bias issues in the evidence relating to design and conduct of individual studies as well as general limitations (i.e., not risk-of-bias issues) based on the case report/series study design. Most of the human studies were rated as probably high risk of bias for lack of blinding of outcome assessors, and two of the four studies had confounding issues.

As discussed previously for the studies on ChE, confounding and lack of blinding of outcome assessors were the principal risk-of-bias issues in the majority of studies, which were based on one of the two terror attacks or accidental exposures. Most studies do not address potential confounders for learning, memory, or intelligence effects. Blinding of outcome assessors was also a general limitation. For self-reported symptoms, blinding is not possible. The lack of addressing potential confounders and the lack of data on blinding at outcome assessment lead to the serious risk-of-bias concern for some time points and a single downgrade in the confidence in the body of evidence; however, for some time points these are not considered to be serious concerns, and the studies were not downgraded.

Lack of information or specific exposure measures was an issue in many of the studies, but this is not considered to pose a risk-of-bias concern. The victims of the terrorist attack are recognized as being exposed to sarin, although the levels of exposure or the proximity of the victims to the release of sarin were not reported. One study (Yokoyama et al. 1998c) was rated as definitely low risk of bias for exposure characterization, because all subjects were admitted to the hospital after the Tokyo subway attack and had signs and symptoms indicative of sarin exposure. The authors provided data indicating that subjects had decreased pupil diameter and serum ChE activity when they arrived at the hospital after the attack to provide supporting data on exposure and also stated that controls were not exposed to sarin. Loh et al. (2010) provided data on ChE levels in the subject based on the subjects’ own baseline levels. Although the study did not report the purity of the sarin (i.e., if there were other anticholinesterases in IED), the decreased ChE and sarin identified in the IED are sufficient evidence of exposure. The other reports may have indicated that the subjects were hospitalized after the attack, but in many cases, this was based on questioning of the victims and not from hospital records.

##### Effects in the Initial Period after Exposure

There is no human evidence to evaluate effects on learning and memory at 1–7 days after exposure.

##### Effects in the Intermediate Period after Exposure

Results from one cross-sectional study (33 subjects) and two case reports (one terrorist attack victim; one Army sergeant with accidental exposure) provided some evidence of impaired learning and memory during the intermediate period after sarin exposure, but the data are limited to a single significant test and a general memory issue in a case report (Loh et al. 2010) that was not supported by test results. Yokoyama et al. (1998c) evaluated learning and memory function in a cross-sectional study 6–8 months after exposure from the Tokyo subway attack. Eighteen patients who had been admitted to St. Luke's International Hospital compared with 15 unexposed individuals had a significantly lower digit symbol test score; however, the victims of the Tokyo subway attack did not have a significant decrease in memory function as measured by the digit span score. There were also no significant differences in paired-associate learning or picture completion scores for the victims versus controls. The confidence in the study is limited by a small sample size and because only one of the three tests showed an effect. Two case reports (Loh et al. 2010; Sekijima et al. 1995) indicated that the two subjects had some memory loss during this time period. A 19-year-old male with severe initial symptoms after the Matsumoto terrorist attack had forgetfulness (not reported how determined) through 10 days after exposure (Sekijima et al. 1995). A 34-year-old male senior Army sergeant who was exposed to sarin when disarming an IED containing sarin complained of short-term memory loss 8 months after exposure (Loh et al. 2010). Although many of the memory tests did not observe levels that were considered impaired, the man was noted to have issues recalling words and numbers within minutes and had issues recalling words that began with the letter F. No IQ impairments or inefficiencies were noted for this individual; however, he demonstrated reduced speed of information processing and impaired performance on the CVLT, Thurstone verbal fluency test, and one of the WAIS-III verbal subtests. The results were generally considered within normal range, and there are no previous results in this subject for comparison. Although the human body of evidence suggests that acute sarin exposure may result in neurological impairments related to learning and memory in the intermediate period, there is generally low confidence in the body of evidence because of limitations such as small sample size, lack of overlap in endpoints evaluated, and lack of strong or consistent evidence of effect.

##### Effects in the Extended Period after Exposure

The results in the two case series studies (Kawana et al. 2001; Ohtani et al. 2004) and two cross-sectional studies (Miyaki et al. 2005; Nishiwaki et al. 2001), which evaluated learning and memory function in victims of the 1995 Tokyo subway sarin attack in the extended period of years after sarin exposure, provided more consistent evidence. Again, however, many different tests were used and results did not always achieve significance. Kawana et al. (2001) found 11–12% of subjects reported difficulty with memory 2–5 years after exposure. Although, when the study authors compared results from the 191 respondents in 2000 (at 5 years) to 87 controls identified from the Matsumoto sarin attack, they found a similar incidence of difficulty with memory: 12.6% for both groups. However, no information was provided to indicate that controls identified after the Matsumoto sarin attack would be appropriate to compare to the Tokyo subway victims. Ohtani et al. (2004) investigated the mental and somatic symptoms of 34 Tokyo subway system sarin attack victims 5 years after the attack and found that severity of forgetfulness was none for 18 cases, mild for 14 cases, and severe for two cases. In the two cross-sectional studies (Miyaki et al. 2005; Nishiwaki et al. 2001), the authors examined memory function in Tokyo subway sarin attack victims who were subway workers and rescue personnel (including police officers) at 3 or 7 years after exposure. Miyaki et al. (2005) reported that exposed subway workers (in 1998) and rescue personnel (in 2002) performed less well on memory function tests, although differences were not statistically significant (80 total exposed, 65 total referents). Similarly, Nishiwaki et al. (2001) evaluated memory function for 56 exposed rescue personnel who had worked at the disaster site compared with 52 referent subjects matched for age and occupation approximately 3 years after the attack. The investigators used the same memory function tests as Miyaki et al. (2005) and also found a suggested (but not statistically significant) relationship between sarin exposure and memory disturbance based on effects observed on the backward digit span test.

The case series studies had several limitations. Both studies were rated as probably high risk of bias for the key question regarding outcome assessment due to lack of blinding because all outcomes were self-reported and participants would have been aware of their exposure. One of the two studies (Kawana et al. (2001) was rated as probably high risk of bias for the key question regarding confounding (authors reported demographic information for survey respondents [gender ratio, age, employment status, and marital status]; however, this information was not accounted for when evaluating the symptoms) (see Figure A-25 and Figure A-26). In addition, there were risk-of-bias concerns due to attrition in both case series, as no information was provided on the subjects who participated compared with those who did not, and few participated in either study [Kawana et al. (2001) received a 33% to 49% response rate depending on the assessment year, and Ohtani et al. (2004) had 34 out of 565 victims of the Tokyo subway attack that visited St. Luke's International Hospital participate]. The cross-sectional studies were rated as probably high risk of bias for one key question—outcome assessment, due to lack of blinding for outcome assessors (see Figure A-27 and Figure A-28).

Taken together, the epidemiological evidence suggests that acute sarin exposure is associated with impaired learning and memory in the intermediate period and extended period after sarin exposure. There are no human studies available to evaluate the potential association between sarin exposure and effects on learning and memory in the initial period after exposure.

#### Animal Learning and Memory Data

##### Summary

There is low confidence in the animal body of evidence that acute sarin exposure affects learning and memory over all three time periods. In rats, the results show some evidence of impaired learning and memory following acute sarin exposure across multiple studies and at different time periods following exposure. The studies in monkeys showed little to no effect, but in many cases, were of limited utility due to small sample sizes. There are limitations in the body of evidence, including small sample sizes and risk-of-bias concerns for the key risk-of-bias questions regarding randomization, exposure assessment, and outcome assessment. The initial high confidence ratings for the animal body of evidence were downgraded once for all time periods for risk-of-bias concerns. For the initial and intermediate time periods, confidence ratings for the animal body of evidence were also downgraded once for imprecision (due to wide ranges in confidence intervals and large standard deviations in the data) to support a final rating of low confidence. The body of evidence for the animal studies in the extended time period was downgraded for inconsistency to support a final rating of low confidence (see Figure 9). An additional downgrade for indirectness was considered for the animal studies given that the tests used as indicators of learning and memory may not have adequately ruled out the role of impaired motor or sensory function. Although multiple downgrade factors (i.e., risk of bias, inconsistency, indirectness, and imprecision) were considered for all three time periods, the judgement was reached to downgrade each body of evidence by two levels to reflect the overall concerns.

Nine experimental studies in the animal body of evidence evaluated the association between acute exposure to sarin and effects related to learning and memory (see Table F-2 through Table F-4). The heterogeneity in the behavioral tests and study design presented some challenges to evaluating the body of evidence. Health endpoints related to learning and memory in experimental animal studies included maze performance (using water maze, T-maze, Y-maze, and radial-arm maze) and discrimination learning activities. The studies focused on rats (Sprague Dawley or Wistar) or marmoset monkey. While the monkey studies used both sexes, the studies in rats all used male rats. While the rat studies administered sarin via inhalation, the monkey studies administered sarin via intramuscular injection. Doses and timing of outcome measure varied by study.

##### Overall Risk-of-bias Discussion of Body of Evidence

Confidence in the body of evidence for the animal studies was downgraded because of serious concern for risk of bias (see Figure A-29 and Figure A-30). The main risk-of-bias concern with the animal studies was lack of reporting of important details for key risk-of-bias questions (i.e., questions regarding randomization, exposure assessment, and outcome assessment). None of the nine studies indicated that the animals were randomized to treatment, but one author responded to inquiry and indicated that animals were randomized to treatment (Grauer et al. 2008). Two of the studies discussed balancing the groups based on task performance (Genovese et al. 2009; Muggleton et al. 2003). None of the remaining six studies provided details on randomization or how animals were assigned to treatment. While most of authors did not respond to inquiries on whether animals were randomized, Kassa et al. responded that the animals were not randomized to treatment. In one study in monkeys (Wolthuis et al. 1995), animals served as their own controls, but five of the 154 animals had already been trained on hand-eye coordination and had been injected once at least 2 months previously with other ChE inhibitors (stated to be highly reversible).

The main limitation of the exposure characterization in most of the animal studies (five of nine) was lack of data on the purity of the sarin administered. Five studies administered sarin with ≥95% purity, but only two of the studies stated that the purity was verified and provided methods. Of the inhalation studies, Genovese et al. (2009) was the only study to provide data on chamber measurements. The Kassa et al. studies indicated target doses and provided information on symptoms and AChE levels to indicate the differences in the doses. Although correspondence with the study authors indicated that they measured the concentrations in the chamber, they were not able to provide us with the levels in the chambers. The information provided in the study indicated that the animals likely received different levels of sarin, but this cannot be confirmed. In addition, the study authors indicated that purity of the sarin was 90%.

Memory-related endpoints were measured using acceptable methods in most studies. Most of the endpoints can be subjective and none of the studies reported that the outcome assessors were adequately blinded to the study group; however, for eight of the nine studies, blinding was not expected to appreciably bias the results because the tests were automated or used a visual tracking system.

There is an additional consideration for animal studies of learning and memory because many of the tests rely on a motor response (e.g., latency to achieve the desired effect). Changes in motor function or activity levels associated with sarin exposure could complicate the interpretation of the results on learning and memory test performance depending on the outcome measured. These considerations are not explicitly a risk-of-bias or internal validity issue, but more appropriately addressed as indirectness. The directness of the measure as an indicator of learning and memory (i.e., the ability to rule out impaired motor or sensory function) was considered when addressing confidence in the animal data.

##### Effects in the Initial Period after Exposure

Experimental studies in rats (Genovese et al. 2009; Kassa et al. 2001b; Kassa et al. 2004; Kassa et al. 2002) and common marmoset (Muggleton et al. 2003; Pearce et al. 1999; Wolthuis et al. 1995) found some evidence of sarin-related effects related to memory within the first week after sarin exposure. Results from three studies in rats for this time period suggest that there are potentially learning and memory issues associated with sarin that can occur within the first week after the acute exposure (Genovese et al. 2009; Kassa et al. 2004; Kassa et al. 2002). In monkeys, results of discrimination learning tasks within 1 week following acute sarin exposure were inconsistent. In monkeys, most of the results did not achieve statistical significance even if the results demonstrated a change from control. This is likely due to the small number of animals used (n = 2–5) and may also be related to potential differences by sex that were not controlled for with such small sample sizes. Genovese et al. (2009) exposed male rats to sarin vapor and evaluated performance on an operant conditioning task and radial-arm maze spatial memory task after 48 hours. Single sarin exposures did not affect performance on the VI56 and had little effect on acquisition of the radial-arm maze task. The only statistically significant results for the radial-arm maze task occurred during the first 5-block session (out of 11 total 5-block sessions), in which reference memory errors and working memory errors significantly increased in a dose-dependent manner. Kassa et al. studies (2001b; 2004; 2002) exposed male rats to sarin vapor and evaluated learning and spatial memory using a T-maze or Y-maze (see Figure A-21 and Figure A-22). Kassa et al. (2001b) tested cognitive function using the T-maze and observed no significant effect on T-maze completion time at 1 week. Kassa (2004; 2002) evaluated cued discrimination (time of reaction; referred to as spatial discrimination in the study, but more likely an assessment of cued memory) using the Y-maze and observed a dose-dependent increase in reaction time at week 1, with a significant increase in reaction time at the highest dose. It was noted, however, that there were no significant differences in the number of entry errors. Kassa et al. (2004) also reported a significant alteration in motor activity (measured as mobility score and activity) at the highest dose at 3 months, which could partly explain some of the other significant results observed at this dose, although there was a dose-dependent increase in the reaction time without similar effects on motor activity at the lower concentrations.

In monkeys, results are considered inconsistent because some studies found little or no effect on learning and memory, although there was also some indication of improved function. Pearce et al. (1999) and Wolthuis et al. (1995) conducted discrimination performance tests and found no statistically significant learning deficits in the week following exposure. Conversely, using a discrimination serial reversal task, Muggleton et al. (2003) found improved reversal learning (i.e., statistically significant fewer mean errors) in monkeys following sarin administration at 0–12 days after exposure. Although Pearce et al. (1999) did not find any significant learning deficits, they also noted that sarin-treated monkeys did better at shape discrimination than did the controls.

The body of evidence in rats suggests that acute sarin exposure may result in neurological impairments related to learning and memory within the initial period after exposure; however, there was heterogeneity in the behavioral tests used across studies. Results in monkeys did not support this finding but may be of limited utility due to small sample sizes.

##### Effects in the Intermediate Period after Exposure

Experimental studies in the rat (Allon et al. 2011; Grauer et al. 2008; Kassa et al. 2001b; Kassa et al. 2004; Kassa et al. 2002) observed some sarin-related effects related to learning and memory 2 weeks to 6 weeks after sarin exposure. Results from three studies in rats for this time period suggest that there are possibly learning and memory issues associated with sarin that can last for weeks after the acute exposure (Grauer et al. 2008; Kassa et al. 2004; Kassa et al. 2002) (see Figure A-21 through Figure A-24. In monkeys (Muggleton et al. 2003; Pearce et al. 1999), results of discrimination learning tasks after 1 week following acute sarin exposure were inconsistent.

Allon et al. (2011) exposed male rats to sarin vapor and evaluated latency to reach the platform in a water maze working/reference memory task. At 1 month following exposure, no significant differences between the groups were detected. Water maze acquisition of both control and exposed rats showed a decrease in latency to reach the platform, indicating no effect of sarin on working and reference memory. In another water maze study, Grauer et al. (2008) exposed male rats to sarin vapor and evaluated latency to reach the platform at 5 weeks. Sarin-exposed rats showed an increased latency to reach the platform, indicating that both working memory and reference memory were impaired; however, the statistical significance of these results is unclear. The increase in latency could not be explained by effects on motor activity because swimming speed did not significantly change. The sarin level in the study was high enough to cause 35% mortality in the first 24 hours with overt toxicity ranging from no overt signs to severe (i.e., prolonged convulsions). The authors noted that histological brain damage correlated with the severity of the initial symptoms but learning and memory effects were not evaluated in relation to initial severity. Kassa et al. studies (2001b; 2004; 2002) exposed male rats to sarin vapor and evaluated learning and spatial memory using a T-maze or Y-maze. Kassa et al. (2001b) tested cognitive function using the T-maze and observed no significant effect on T-maze completion time at week 2 through week 5. Kassa et al. (2004; 2002) evaluated spatial discrimination (time of reaction) using the Y-maze and observed a dose-dependent increase in reaction time at weeks 2 and 3, with significant increases in time of reaction at the highest dose; however, as noted previously, motor activity was affected at the highest dose at 3 months, but there was no significant change in the number of entry errors. At 4–6 weeks, times of reaction were more consistent among doses, and no significant results were observed at any dose.

In monkeys, Pearce et al. (1999) observed no deleterious effects on discrimination performance tasks (number of errors to reach criterion) at 2–6 weeks after exposure with some indication of improved discrimination of shapes compared with controls. As noted above, using a discrimination serial reversal task, Muggleton et al. (2003) found improved reversal learning (i.e., fewer mean errors) in monkeys following sarin administration (11.15 μg/kg) at 0–12 days after exposure.

Consistent with the initial period after exposure, the body of evidence in rats for the intermediate period suggests that there are learning and memory issues associated with sarin that can last for weeks after exposure; however, the evidence in monkeys did not support the data in rats and may be of limited utility due to small sample sizes.

##### Effects in the Extended Period after Exposure

Results were inconsistent from the two experimental studies in the rat studies (Allon et al. 2011; Grauer et al. 2008) evaluating sarin-related effects related to working memory and reference memory 4 or 6 months after sarin exposure. Results from one of the two studies suggest that there are memory issues associated with sarin that can last for months after the acute exposure (Grauer et al. 2008) (see Figure A-23 and Figure A-24). Allon et al. (2011) exposed male rats to sarin vapor and evaluated latency to reach the platform in a water maze working/reference memory task. At 6 months following exposure, the authors found no effect of sarin on working and reference memory. The lack of an effect of sarin by Allon et al. (2011) is consistent with what the study found for the intermediate period. In another water maze study, Grauer et al. (2008) exposed male rats to sarin vapor and evaluated latency to reach the platform at 4 months and 6 months. At both extended-period time points (as well as during the intermediate period), sarin-exposed rats showed an increased latency to reach the platform with no effect on swimming speed, indicating that both working memory and reference memory were impaired (statistical significance not indicated). The animals in Allon et al. (2011), which found no effects on learning and memory, experienced less cholinergic symptoms than did the animals in Grauer et al. (2008), which suggests a less severe response and may be related to the difference in results from the two studies.

#### Integration of Evidence for Learning, Memory, and Intelligence

There is some evidence that indicates learning and memory impairments in humans and animals following acute exposure to sarin. In humans, evidence suggests effects on learning and memory (with no clear evidence to suggest deficits in intelligence as measured by IQ) in the intermediate and extended periods after sarin exposure, with low to moderate confidence in the body of evidence, respectively. In animals, there is low confidence that acute sarin exposure is associated with learning and memory effects across all time periods after exposure, with some evidence of effects in the initial and intermediate periods and inconsistent results from two studies in the extended time period. These confidence ratings for human and animal bodies of evidence translate directly into level-of-evidence conclusions and support an initial hazard identification conclusion based on the different times as detailed below.

##### Effects in the Initial Period after Exposure

- Human body of evidence: No studies = Inadequate level of evidence
- Animal body of evidence: Low confidence = Low level of evidence
- Initial hazard conclusion (Inadequate Human × Low Animal) = Not classifiable
- Final hazard conclusion for the initial period (after consideration of biological plausibility) = Not classifiable

##### Effects in the Intermediate Period after Exposure

- Human body of evidence: Low confidence = Low level of evidence
- Animal body of evidence: Low confidence = Low level of evidence
- Initial hazard conclusion (Low Human × Low Animal) = Not classifiable
- Final hazard conclusion for the intermediate period (after consideration of biological plausibility) = Not classifiable

##### Effects in the Extended Period after Exposure

- Human body of evidence: Moderate confidence = Moderate level of evidence
- Animal body of evidence: Low confidence = Low level of evidence
- Initial hazard conclusion (Moderate Human × Low Animal) = Suspected to be a neurological hazard to humans
- Final hazard conclusion for extended period (after consideration of biological plausibility) = Suspected to be a neurological hazard to humans

Collectively, the human and animal bodies of evidence provide some evidence that acute exposure to sarin may be associated with long-term issues with learning and memory. The human data are mainly based on cross-sectional studies evaluating subjects from the Tokyo subway attack. The animal data in rats support that an acute sarin exposure may affect memory in the initial, intermediate, and extended periods following exposure.

A mechanism by which organophosphates—and sarin in particular—could cause learning and memory effects has been suggested (Chen 2012; Gais and Schonauer 2017; Lee 2003) and could be related to secondary neuronal damage occurring in the cholinergic regions of the brain. Although there are data to suggest that ChE levels are affected (increased and decreased) in different regions of the brain, there are not sufficient data to indicate that this was associated with neuronal damage to the cholinergic regions of the brain. One study (Yamasue et al. 2007) noted a decrease in regional white matter volume in victims from the Tokyo subway attack. The study, however, did not indicate that this was associated with damage in the cholinergic region of the brain or that the subjects were tested for learning, memory, or intelligence. Given this information, it is unlikely that there is sufficient mechanistic information to increase or change the hazard determination.

### Nervous System Morphological and Histological Changes

Morphological or histological changes in neural tissue are direct measures of neurological damage. It is important to note that the types of pathology observed in the human nervous system are readily modeled in experimental mammalian models. There is a general paucity of relevant human data, in part because the resources required—such as magnetic resonance imaging (MRI) or positron emission tomography (PET)—are not routinely available for assessing neurological damage in living individuals, and because histopathological analyses, which can only be performed after death, are difficult to conduct in such a way as to obtain high-quality data. However, some human studies are available that examined morphological and histological changes in nervous system tissues (including brain, spine, and sural nerve) of subjects who were accidentally exposed to sarin during a military operation (low-level sarin exposure) or during the Tokyo subway attack. Despite the small number of studies, any human data on this endpoint were considered highly informative and therefore have been included and assessed in this report.

The circumstances associated with exposure to sarin (i.e., often occurring during a traumatic event, such as a terrorist attack) contribute to a “co-exposure” from the nature of the exposure event itself whereby subjects exposed to sarin might also experience PTSD due to the traumatic event, which may confound results of nervous system morphological and histological changes associated with sarin exposure. In addition, subjects could experience PTSD due to the severity of complications that occur after sarin exposure. The use of a control population (i.e., no exposure to sarin) with PTSD could allow researchers to control for PTSD as a confounder, but such controls are unlikely to be available and may be complicated by other confounders. Despite these potential limitations, the data presented in this section are still considered useful for evaluating the effects of sarin exposure. Changes to muscle tissue are not considered in this section because the focus of the section is neurological effects; however, it should be noted that any muscle effects could also be related to some of the neuromuscular effects observed.

#### Human Morphological and Histological Data

##### Summary

There is moderate confidence in the body of evidence that acute sarin exposure is associated with morphological and histological changes in human neurological tissues in the extended period. The human body of evidence consists of two case reports (Himuro et al. 1998; Loh et al. 2010) and one cross-sectional study (Yamasue et al. 2007) (see Table 9 and Figure 10) that evaluate effects months to years after sarin exposure. None of the studies provide data on morphological and histological changes over a period of days or weeks after exposure. A single case report was available that evaluated morphological or histological changes in neurological tissue at 8 months following sarin exposure but found no abnormalities during an MRI examination of the brain and spine (Loh et al. 2010). The studies that provide data on morphological and histological changes in nervous tissue ≥1 year after exposure, including one cross-sectional (Yamasue et al. 2007) and one case report (Himuro et al. 1998), report evidence of morphological and histological changes to human nervous system components following acute sarin exposure. The moderate confidence in the body of evidence is based mainly on the cross-sectional study with an initial and final confidence of moderate and support from one case report. While the case report had an initial and final rating of low confidence due to general limitations based on the case report study design (e.g., mainly not having a control for comparison), the study assessed damage to the brain against a “normal” standard, which could potentially increase the confidence in the case reports. There are inadequate data to assess the relationship between sarin and morphological changes in the initial and intermediate time periods after exposure due to the lack of data available.

Table 9 Studies on Morphological and Histological Changes to Nervous System Tissues in Humans

Study | Study Design (Location/Study) [n] | Exposure Measure Timing | | | Assessment Timing | | Analysis | Morphological/Histological Outcome Summary
Initial Time Period after Exposure (>24 hours–7 days)
No studies available.
Intermediate Time Period after Exposure (8 days–1 year)
Loh et al. (2010) | Case report (U.S. Military) [1] | Disarming an IED containing colorless liquid determined to be sarin, subject had decreased RBC ChE and symptoms | | | 8 months | | MRI of the brain and spine | MRI examination of brain and spine was normal
Extended Time Period after Exposure (≥1 year)
Himuro et al. (1998) | Case report (Japan/Tokyo subway system attack victim) [1] | Terrorist attack, single exposure (not measured) | | | 15 months (man died 15 months after attack without regaining consciousness) | | Autopsy (pathologic examination) | In sural nerve, severe reduction in both large and small myelinated fibers with preferential loss of large myelinated fibers; in spinal cord, total loss of myelinated fibers in the white matter and severe neuronal loss in the central gray matter; no changes observed in dorsal root ganglia, dorsal roots, posterior column of the spinal cord; in brain, severe hypoxic-ischemic encephalopathy
Yamasue et al. (2007) | Cross-sectional (Japan/Tokyo subway system attack victims) [38 victims + 76 controls] | Terrorist attack, single exposure (not measured) | | | 5–6 years | | Diffusion tensor MRI; voxel-based morphometry | Reduced regional gray matter volume in the right insular and temporal cortices; significant regional gray matter volume reduction in left hippocampus; significant regional white matter volume reduction in left temporal stem close to the insular cortex; negative correlation between reduced regional white matter volume in the left temporal stem and severity of symptoms; reduced regional white matter volume correlated with decreased serum ChE and severity of chronic somatic complaints

RBC = red blood cells; ChE = cholinesterase; MRI = magnetic resonance imaging.

Figure 10

Morphological and Histological Changes to Nervous System Tissues Evidence Profile for Sarin

References: Human: Himuro et al. (1998),^c^ Loh et al. (2010),^a^ Yamasue et al. (2007).^b^ Animal: Chaubey et al. (2017),^e^ Grauer et al. (2008),^d^ Kadar et al. (1995),^d,e^ Kawabuchi et al. (1991),^d^ Lazar et al. (2016),^d^ Singer et al. (1987).^d,e^

The available epidemiological studies in the human body of evidence that evaluated the association between acute exposure to sarin and morphological and histological changes in the human nervous system tissues evaluated the outcomes months to years after the initial exposure (see Table 9). There are no studies that specifically evaluated morphological and histological changes in the human nervous system within days or weeks after exposure. Two studies (one cross-sectional and one case report) were conducted in adults who were exposed during the Tokyo subway sarin terrorist attack. The third study was a case report of a military man deployed in Iraq who was exposed while disarming an IED containing sarin.

##### Overall Risk-of-bias Discussion of Body of Evidence

Risk-of-bias ratings for individual studies for all questions are available in Figure A-31 and Figure A-32. Although there were a few risk-of-bias concerns in two of the three key risk-of bias questions (i.e., questions regarding confounding and outcome assessment), it is unlikely that the risk-of-bias concerns in the body of evidence seriously altered the results. The cross-sectional study (Yamasue et al. 2007) had a single risk-of-bias concern related to confounding, but the study adjusted for most potential confounders. The authors treated age, sex, socioeconomic status, and intracranial volume, as confounding factors. However, BMI, alcohol consumption, and smoking were not reported or addressed, which has potential to bias the results. One case report (Himuro et al. 1998) was also rated as probably high risk of bias for confounding. It was noted that before the attack the patient was a healthy 51-year-old man with no neuropathy; however, few details were provided on the subject to indicate that there were no potential confounders for the outcomes of interest. The Loh et al. (2010) case report was rated as probably high risk of bias for outcome assessment due to lack of blinding of outcome assessors, although concerning the MRI results reported in the case report, the lack of blinding would likely bias toward an effect but no effect was observed; therefore, it is not considered a serious risk of bias.

##### Effects in the Initial Period after Exposure

There is no human evidence to evaluate the potential association between acute sarin exposure and morphological and histological changes in human nervous system tissues at 1–7 days after exposure.

##### Effects in the Intermediate Period after Exposure

A single case report was available that evaluated morphological or histological changes in neurological tissue at 8 months following sarin exposure (Loh et al. 2010). A 34-year-old male senior Army sergeant who was exposed to sarin while disarming an IED was examined for brain and spine abnormalities. The MRI examination of the brain and spine was determined to be normal. Loh et al. (2010) was rated as probably high risk of bias for one key question—outcome assessment—due to lack of blinding of outcome assessors (see Figure A-31 and Figure A-32), although this may be less of a concern for the MRI assessment. However, the study used a standard MRI, which is not comparable to the diffusion tensor MRI and voxel-based morphometry used by Yamasue et al. (2007).

##### Effects in the Extended Period after Exposure

One cross-sectional and one case report were available that evaluated morphological and histological changes in nervous tissue of adults who were exposed during the terrorist attack on the Tokyo subway. Yamasue et al. (2007) evaluated nervous tissue changes of 38 victims of the Tokyo subway attack who had been treated in the emergency department compared with 76 healthy controls. The study was conducted 5–6 years after the exposure. Recruitment methods for the 38 subjects from the 149 who participated in the 2000 survey conducted by Kawana et al. (2001) was not specified, but the controls were matched by age and sex. There were no significant differences in total gray matter, total white matter, total cerebrospinal fluid volume, or intracranial volume measured by diffusion tensor MRI; however, the voxel-based morphometry demonstrated that exposed subjects had a significantly reduced regional gray matter volume in the right insular and temporal cortices. A significant regional gray matter volume reduction in the left hippocampus and a significant regional white matter volume reduction in the left temporal stem close to the insular cortex were also observed. The study also found a negative correlation between the reduced regional white matter volume in the left temporal stem and the severity of symptoms. The reduced regional white matter volume was noted to be correlated with decreased serum ChE and the severity of chronic somatic complaints. PTSD was not specifically addressed in this study, and the study used healthy controls. This study used 29 of the same subjects as in Tochigi et al. (2002), which reported that 8 of 34 subjects developed PTSD due to the attack with two subjects diagnosed with PTSD at the time of the study (5 years after exposure). Therefore, the current study included no more than eight subjects diagnosed with PTSD, indicating that this is unlikely to be a major contributing factor in the study.

Himuro et al. (1998) reported a case of a 51-year-old man who was exposed to sarin during the Tokyo subway attack and died 15 months later without regaining consciousness. During autopsy, a neuropathological examination showed a severe reduction in large and small myelinated fibers with preferential loss of large myelinated fibers of the sural nerve. The spinal cord examination revealed total loss of myelinated fibers in the white matter and severe neuronal loss in the central gray matter. No changes were observed in the dorsal root ganglia, dorsal roots, and posterior column of the spinal cord. Examination of the brain revealed severe hypoxic-ischemic encephalopathy. The authors concluded that the revealed pathology is consistent with dying-back neuropathy and could represent a late sequela of sarin intoxication.

Both studies were rated as probably high risk of bias for one key risk-of-bias question (confounding) (see Figure A-31 and Figure A-32). However, it is unlikely that this plausible bias seriously altered the results. In Himuro et al. (1998), the authors noted that before the attack the patient was a healthy man with no neuropathy, but the authors did not provide any details on the subject to indicate that there were no potential confounders for the outcomes of interest. However, given the damage observed and the subject’s symptoms after the exposure, it is likely that the effects are related to the sarin exposure. In Yamasue et al. (2007), statistical analyses treated intracranial volume, age, and sex as confounding covariates, but did not address BMI, alcohol consumption, and smoking status, leading to a probably high risk of bias. Although the confounders not evaluated could potentially bias results, it is highly unlikely that they would occur in one group at a rate that would significantly affect the brain morphology, which is assumed to likely be a result of the sarin exposure. In addition, Yamasue et al. (2007) selected subjects who had sufficient evidence of sarin exposure after the attack, and outcomes were assessed using reliable methods. As noted above, PTSD may be a potential confounder that was not addressed; however, because the PTSD may be related to severity of exposure and only a few (i.e., up to 8) subjects were diagnosed with PTSD, it is not expected to be a major contributing factor in the study.

Taken together, the epidemiological evidence suggests that acute exposure to high levels of sarin is associated with morphological and histological changes in human nervous system tissues in the years following sarin exposure. There is inadequate human evidence available to evaluate the potential association between sarin exposure and nervous tissue effects in the days to months following exposure.

#### Animal Morphological and Histological Data

##### Summary

There is moderate confidence in the body of evidence that acute sarin exposure is associated with morphological and histological changes in neurological tissues in animals over the initial period and intermediate period after exposure (see Figure 10). The results provide consistent evidence of sarin-related effects related to nervous tissue changes within the first 7 days and through 90 days following acute sarin exposure. However, there are limitations in the body of evidence, including serious risk-of-bias concerns. In addition, although the staining methods used (e.g., hematoxylin and eosin [H&E] staining or Nissl) allowed the authors to detect morphologic changes in nervous tissue, modern techniques that provide a more comprehensive assessment of underlying neuropathology not revealed by classical Nissl/H&E staining were not employed, and therefore the full extent of the morphological changes may not have been detected and reported, suggesting a bias toward the null. Downgrades of one or two levels were considered for the risk-of-bias concerns. Downgrade considerations were also made for the opposing issue of the impact of changes in histological techniques. The decision was reached to downgrade the bodies of evidence one level to reflect the overall concerns. The initial high confidence in the animal body of evidence was downgraded for risk-of-bias concerns related to randomization, exposure assessment, and outcome assessment to support a final rating of moderate confidence for a period of days to months following acute sarin exposure.

Six experimental studies in the animal body of evidence evaluated the association between acute exposure to sarin and morphological and histological changes in neurological tissues (Chaubey et al. 2017; Grauer et al. 2008; Kadar et al. 1995; Kawabuchi et al. 1991; Lazar et al. 2016; Singer et al. 1987). All studies used rats (five male Sprague Dawley rat studies; one Wistar female rat study). Sarin administration methods varied (i.e., subcutaneous injection, intramuscular injection, or inhalation); doses and timing of outcome measure also varied by study.

##### Overall Risk-of-bias Discussion of Body of Evidence

Confidence in the body of evidence for the animal studies was downgraded because of serious concerns for risk of bias (see Figure A-33 and Figure A-34). The main risk-of-bias concern with the animal studies was lack of reporting of important details for key risk-of-bias questions (i.e., questions regarding randomization, exposure assessment, and outcome assessment). Only two of the five studies indicated that the animals were randomized to treatment (Grauer et al. 2008; Singer et al. 1987). None of the others provided sufficient details on randomization or how animals were assigned to treatment. The main limitation of the exposure characterization in three of the five animal studies was lack of data on the source and/or purity of the sarin administered. Three studies administered sarin with ≥95% purity, but only one study (Kadar et al. 1995) indicated that the purity was verified and provided methods. Morphology- and histology-related endpoints were measured using acceptable methods in all studies; however, none of the studies reported that the outcome assessors were adequately blinded to the study group or reported methods to reduce potential bias.

##### Effects in the Initial Period after Exposure

Five experimental studies in rats examined sarin-related effects related to nervous tissue changes within the first 7 days after sarin exposure. Results from the five studies in rats for this time period suggest that there are nervous tissue effects associated with sarin that can occur within the first week after acute exposure. In Grauer et al. (2008), male rats were exposed to 34.2 μg/L of sarin via inhalation for 10 minutes, and brain morphology was examined at 1 week. Brain damage was found in six of the 10 exposed animals and included enlargement of ventricles and cell death in the piriform cortex, the hippocampus (including the CA1, CA3, and dentate gyrus), and the thalamus. No brain damage was observed in controls. Authors noted that the severity of brain damage was correlated with initial signs of toxicity (convulsions). Kawabuchi et al. (1991) exposed female Wistar rats to a single subcutaneous injection of sarin at 80 μg/kg and evaluated motor nerve fiber degeneration on days 1, 3, and 6. Neural degeneration was observed over that time period, but recovery was apparent by day 6, evidenced by restored neural sites, nerve sprouting, and endplate regeneration. In Lazar et al. (2016), male rats received an intramuscular injection of sarin at 80 μg/kg, and brains were removed and examined at 1, 2, 6, 24, and 48 hours after exposure. The authors observed a time-dependent increase in the severity of brain damage, most notably in the hippocampus and piriform cortex. Pyknotic and necrotic cells seen in the CA1 and CA3 subregions of the hippocampus increased over time. In the piriform cortex, neuronal cell death was almost complete at 48 hours following exposure to sarin and was due mostly to necrosis associated with severe astrocytosis. Singer et al. (1987) administered a single subcutaneous injection of sarin (111–197 μg/kg) to rats and evaluated brain damage on days 2, 6, and 7. Moderate or severe neuronal necrosis was observed in two of the three animals sacrificed at 2 days (moderate at 157 and 170 μg/kg), three of the six rats sacrificed at 6 days (moderate at 170 μg/kg and severe at 125 and 197 μg/kg), and one rat sacrificed at 7 days (severe at 170 μg/kg). Kadar et al. (1995) observed neuronal loss in the piriform cortex 1 week after a single intramuscular injection of sarin at 95 μg/kg in surviving rats. Other observations at 1 week included replacement of CA1 cells with large vacuoles in the hippocampus, expansion of lesions into the amygdaloidal nuclei, and extensive gliosis in the thalamus.

##### Effects in the Intermediate Period after Exposure

Three experimental studies in rats (Chaubey et al. 2017; Kadar et al. 1995; Singer et al. 1987) examined sarin-related effects related to nervous tissue changes in the intermediate period after sarin exposure. Results from all studies suggest that nervous tissue effects associated with sarin that can last for weeks or months after the acute exposure. Kadar et al. (1995) exposed rats to a single LD_50_ dose of sarin (95 μg/kg intramuscular) and examined the brains of surviving animals for histological and morphometric changes. Seventy percent of surviving rats developed brain lesions with varying degrees of severity primarily in the hippocampus, piriform cortex, and thalamus. The severity of the lesions was related to the presence or absence of convulsions, and the damage was exacerbated over time. At 3 months, damage had extended to areas of the brain that had not been affected initially. In addition, the authors observed almost complete degeneration of the CA1 cell layer and severe necrosis in the CA2 and CA3 regions. There was an initial decrease in single-cell surface area in the hippocampal CA1 and CA3 subfields of exposed animals with gradual increases back toward control; however, results were still significantly decreased 90 days after the exposure. Singer et al. (1987) administered a single subcutaneous injection of sarin (111–197 μg/kg) to rats and evaluated brain damage on days 9, 21, 28, and 35. Mild, moderate, or severe neuronal necrosis was observed in 2 of 5 rats sacrificed at 9 days (moderate at 125 and severe at 170 μg/kg), 0 of 5 rats sacrificed at 21 days, 1 of 5 rats sacrificed at 28 days (moderate at 140 μg/kg), and 1 of 6 rats sacrificed at 35 days (mild at 125 μg/kg). Chaubey et al. (2017) administered a single subcutaneous 0.5-LD_50_ dose (i.e., 80 μg/kg) to rats and evaluated brain histopathology at 3 months. The authors observed necrotic regions with degenerative neurons and neuroglia in the cortex, similar effects in the corpus striatum characterized by formation of perineuronal and perivascular spaces, and necrotic regions in the hippocampus with hypocellularity of neurons and neuroglia prominent.

##### Effects in the Extended Period after Exposure

There is no animal evidence to evaluate the potential association between sarin exposure and morphological and histological changes in nervous tissue in the extended period after exposure.

#### Integration of Evidence for Morphological and Histological Changes

There is evidence to suggest morphological and histological changes in human and animal nervous tissue following acute exposure to higher doses of sarin. There is moderate confidence in the human data for sarin-associated nervous tissue effects in the extended period based on one cross-sectional study with support from one case report with little potential for bias. The body of evidence prior to a year (i.e., in the initial and intermediate periods) is inadequate in humans. There is moderate confidence that acute sarin exposure is associated with nervous tissue effects in animals based on the consistency of the findings in rats through 90 days after exposure. These confidence ratings translate directly into level-of-evidence conclusions and support an initial hazard identification conclusion of suspected to be a neurological hazard to humans.

##### Effects in the Initial Period after Exposure

- Human body of evidence: No studies = Inadequate level of evidence
- Animal body of evidence: Moderate confidence = Moderate level of evidence
- Initial hazard conclusion (Inadequate Human × Moderate Animal) = Suspected to be a neurological hazard to humans
- Final hazard conclusion (after consideration of biological plausibility) = Suspected to be a neurological hazard to humans

##### Effects in the Intermediate Period after Exposure

- Human body of evidence: Low confidence with no effect = Inadequate level of evidence
- Animal body of evidence: Moderate confidence = Moderate level of evidence
- Initial hazard conclusion (Inadequate Human × Moderate Animal) = Suspected to be a neurological hazard to humans
- Final hazard conclusion (after consideration of biological plausibility) = Suspected to be a neurological hazard to humans

##### Effects in the Extended Period after Exposure

- Human body of evidence: Moderate confidence = Moderate level of evidence
- Animal body of evidence: No studies = Inadequate level of evidence
- Initial hazard conclusion (Moderate Human × Inadequate Animal) = Suspected to be a neurological hazard to humans
- Final hazard conclusion (after consideration of biological plausibility) = Suspected to be a neurological hazard to humans

Collectively, the human and animal bodies of evidence provide consistent patterns of findings that acute exposure to higher doses of sarin is associated with morphological and histological changes in nervous tissue. The human data are based on one cross-sectional study and one case report evaluating adults from the Tokyo subway attack. The animal data support that an acute sarin exposure can cause nervous tissue effects.

Mechanistic data support the evidence of morphological and histological changes in humans and animals associated with acute sarin exposure. OP nerve agents, including sarin, cause hyperactivity in the nervous system triggered by hyperstimulation of cholinergic receptors, which leads to respiratory failure via peripheral and central mechanisms and seizures via central mechanisms. The increased cholinergic drive in the central nervous system (CNS) results in an overactivation of glutamate receptors and a subsequent rise in intracellular calcium levels, which culminates in an excitotoxic response in the CNS (Chen 2012). Significant elevations in hippocampal calcium levels after OP-induced status epilepticus persist for weeks, and drugs inhibiting intracellular calcium-induced calcium release reduce neuronal cell damage and death (Deshpande et al. 2016). Secondary effects, such as extensive intracellular edema, increased blood-brain barrier permeability, cerebral hemorrhages, and increased neuroinflammatory and stress responses, likely also contribute to morphological changes caused by OP exposure (Chen 2012). Studies in animals and humans have linked oxidative stress with acute and chronic exposures to OP nerve agents and pesticides (Pearson and Patel 2016), and the highly potent OP nerve agent soman causes changes in brain region oxygenation after sublethal doses that cause seizures (Lee et al. 2018). Hypoxia and oxidative stress are important considerations because they may be effects unrelated to OP-induced seizures, and both hypoxia and oxidative stress have been linked to morphological and histological changes in central and peripheral nervous systems in other disease contexts (Pomara et al. 2015; Raz et al. 2016; Tonni et al. 2014). The few mechanistic animal studies conducted specifically with sarin are consistent with the above studies of other OP nerve agents and pesticides. For example, rats exposed to sublethal doses of sarin exhibited significant cell death and neurodegeneration in the CNS associated with changes in apoptotic proteins and an early bi-phasic activation of astrocytes (Lazar et al. 2016), and proteomic studies of sarin-exposed rats are beginning to unmask details of the excitotoxicity and other mechanisms described above (Chaubey et al. 2017).