# Methods

## Problem Formulation and Protocol Development

The research question and specific aims stated above were developed and refined through a series of problem formulation steps including: (1) consideration of reports in the literature as to whether long-term neurological effects of OP agents in humans are a common occurrence; (2) discussion of these reports and related questions on long-term neurological health effects of OP agents at the National Institutes of Health Countermeasures Against Chemical Threats (CounterACT) Workshop in February 2014; and (3) development of the Systematic Review Subcommittee (chaired by David A. Jett, Ph.D.; Pamela J. Lein, Ph.D.; and Mark Kirk, M.D.). The Systematic Review Subcommittee was convened in June 2015 and began to refine the research question and specific aims, and to develop a draft protocol for conducting the systematic review. The focus of the current project on sarin exclusively, rather than on all OP agents, was selected to aid in reaching conclusions (i.e., equivalent exposure to the same agent could be more directly compared than could exposure across multiple agents). Similarly, the focus on neurological health effects was selected as an aid in reaching conclusions and because the majority of data on potential health effects of sarin are for neurological effects. The protocol was peer reviewed and finalized in April 2017 and used to conduct this review ([underlined: Appendix I]). A brief summary of the methods is presented below.

## PECO Statements

PECO ([underlined: P]opulation, [underlined: E]xposure, [underlined: C]omparator, and [underlined: O]utcome) statements were developed as an aid to identify search terms and inclusion/exclusion criteria as appropriate for addressing the overall research question (long-term neurological effects of acute sarin exposure) for the systematic review (Higgins and Green 2011).The PECO statements are listed below for human (Table 1), animal (Table 2), and in vitro/mechanistic studies (Table 3).

Table 1 Human PECO Statement

PECO Element | Evidence
Population | Humans without restriction as to age or sex, geographic location, or life stage at exposure or outcome assessment; and no restriction as to whether military or civilian/noncombatant
Exposure | Single acute exposure to sarin based on: • known dose or concentration in an experimental protocol • diagnostic biomonitoring data (e.g., sarin or biomarkers in plasma or urine) • environmental detection (e.g., air, soil) • corroboration by assessment of direct (in hospital, in clinic) or indirect observation of symptoms of acute cholinergic signs (video or reported by patient’s family) • dose may be extrapolated from clinical signs and symptoms per Brown and Brix (1998) and as adapted from Namba et al. (1971) No restriction on whether exposure is accidental or intentional
Comparator | For controlled and uncontrolled studies, comparable populations not exposed to sarin; and for case series or case reports, no comparable populations
Outcome | Neurological outcomes including changes in nervous system function (e.g., cognitive, sensory, motor), and neuropathology (e.g., imaging and post-mortem)

Table 2 Animal PECO Statement

PECO Element | Evidence
Population | Without restriction as to species, age, or sex, or life stage at exposure or outcome assessment
Exposure | Single acute exposure to sarin based on administered dose or concentration or biomonitoring data (e.g., urine, blood, or other specimens)
Comparator | Comparable untreated animal subjects or animals exposed to vehicle-only treatment
Outcome | Neurological outcomes including changes in nervous system function (e.g., cognitive, sensory, motor), neuropathology (e.g., imaging and post-mortem), and neurophysiology (e.g., ion channel and receptor function)

Table 3 In Vitro/Mechanistic PECO Statement

PECO Element | Evidence
Population | Human or animal cells, tissues, or model systems with in vitro exposure regimens
Exposure | Exposure to sarin based on administered dose or concentration
Comparator | Comparable cells or tissues exposed to vehicle-only treatment or untreated controls
Outcome | Measurements of the survival and the morphology of neurons or glia, including histochemical and immunohistochemical techniques such as H&E, Nissl, Rapid Golgi, Fluoro-Jade, Silver Stain, HRP, GFAP, neurotransmitter stains, axon/dendrite-specific markers, and others

Using the PECO statements, the evaluation searched for evidence of long-term neurological effects associated with acute sarin exposure from human studies across a broad range of study design types along with controlled exposure animal studies and mechanistic/in vitro studies. Mechanistic data can come from a wide variety of studies that are not intended to identify a disease phenotype. This source of experimental data includes in vitro and in vivo laboratory studies directed at cellular, biochemical, and molecular mechanisms that explain how a chemical produces particular adverse health effects.

## Literature Search

Search terms were developed to identify all relevant published evidence that addresses the research question on long-term neurological health effects potentially associated with acute, sublethal exposure to sarin in humans and animals by (1) using the search term “sarin” and related synonyms “GB” or sarin’s IUPAC ID “(RS)-propan-2-yl methylphosphonofluoridate” and (2) without restriction by health outcome or key words to identify long-term neurological effects. A test set of relevant studies was used to ensure that the search terms retrieved 100% of the test set. The following eight electronic databases were searched using a search strategy tailored for each database by an informationist on the evaluation team (specific search terms used for the PubMed search are presented in Appendix B); the search strategy for other databases are available in the protocol ([underlined: Appendix I]). No language restrictions or publication year limits were imposed, and the databases were searched in April 2016, with several updated searches and a final search conducted on October 25, 2018.

### Databases Searched

- Cochrane Library
- DTIC
- EMBASE
- NIOSHTIC
- PubMed
- Scopus
- Toxline
- Web of Science

### Searching Other Resources

The reference lists of all included studies, relevant reviews or reports, commentaries or letters on specific studies, and other non-research articles were manually searched for additional relevant publications.

Given that incidents of human exposure to sarin include terrorist attacks and military personnel, the search was conducted to identify the anticipated range of evidence for human studies. Original papers may include non-peer-reviewed studies, for example, reports from U.S. military observational studies, as well as uncontrolled studies, case series, or case reports. In all instances, the paper must: (1) document exposure to sarin and confirm both (2) acute symptoms (i.e., cholinergic crisis) and (3) assess and report some long-term neurological health effects from the exposure.

### Unpublished Data

Unpublished data were eligible for inclusion provided the owner of the data was willing to have the data made public and peer reviewed (see protocol in Appendix I for more details).

## Study Selection

### Evidence Selection Criteria

To be eligible for inclusion, studies had to comply with the type of evidence specified by the PECO statements (Table 1, Table 2, and Table 3). The following additional exclusion criteria were applied:

1. Human or animal studies with an exposure duration ≥24 hours, except repeat dose studies in which the outcome is first measured at least 24 hours after the first dose but before any subsequent exposure after 24 hours;
2. Human controlled studies in which the purpose was only to apply treatment for acute sarin effects;
3. Human or animal studies with acute exposures to several different chemicals;
4. Animal treatment/recovery studies that administer sarin and a treatment, unless there is a sarin-only control group;
5. Human studies with no assessment of health effect outcomes after cholinergic crisis has subsided;
6. Animal studies with neurological effects only measured within 24 hours after exposure;
7. Articles without original data (e.g., editorials or reviews); and
8. Studies published in abstract form only (grant awards and conference abstracts).

### Screening Process

References retrieved from the literature search were screened for relevance and eligibility using DistillerSR^®^ (https://www.evidencepartners.com/products/distillersr-systematic-review-software/) by Evidence Partners, a web-based, systematic-review software program with structured forms and procedures to ensure standardization of the process. Search results were first consolidated in Endnote reference management software and duplicate articles were removed prior to uploading the references into DistillerSR. Screeners from the evaluation team were trained with an initial pilot phase to improve clarity of the evidence selection criteria and to improve accuracy and consistency among screeners. All references were independently screened by two trained screeners at the title and abstract level to determine whether a reference met the evidence selection criteria. Studies that were not excluded by reviewing the title and abstract were screened with a full-text review. Screening conflicts were resolved through discussion. Following full-text review, the remaining studies were “included” and used for the evaluation.

## Data Extraction

### Extraction Process

Data were collected (i.e., extracted) from included studies by one member of the evaluation team and checked by a second member for completeness and accuracy. Any discrepancies in data extraction were resolved by discussion or consultation with a third member of the evaluation team. Information that was inferred, converted, or estimated during data extraction is annotated using brackets [e.g., n = 10]. Data were extracted as presented in the publications, including reported levels of statistical significance. NTP did not conduct independent statistical analyses to confirm levels of statistical significance reported in the publications nor did they determine statistical significance when study authors did not conduct statistical analyses.

### Data Availability

Data extraction was completed using the Health Assessment Workspace Collaborative (HAWC (https://hawcproject.org/portal/)), an open-source and freely available web-based interface application, for visualization and warehousing.^4^ The data extraction results for included studies are publicly available (https://hawcproject.org/assessment/302/) and can be downloaded in Excel format through HAWC (NTP 2019b). Data extraction elements are listed separately for human, animal, and in vitro studies in the protocol ([underlined: Appendix I]) (NTP 2019c).

4 HAWC (Health Assessment Workspace Collaborative): A Modular Web-based Interface to Facilitate Development of Human Health Assessments of Chemicals (https://hawcproject.org/portal/).

## Quality Assessment of Individual Studies

Risk of bias was assessed for individual studies using a tool developed by OHAT that outlines a parallel approach to evaluating risk of bias from human, animal, and mechanistic studies to facilitate consideration of risk of bias across evidence streams with common terms and categories. The risk-of-bias tool comprises a common set of 11 questions that are answered based on the specific details of individual studies to develop risk-of-bias ratings for each question. Study design determines the subset of questions used to assess risk of bias for an individual study (Figure 1).

Figure 1

OHAT Risk-of-bias Questions and Applicability by Study Design

*Experimental animal studies are controlled exposure studies. Nonhuman animal observational studies can be evaluated using the design features of observational human studies such as cross-sectional study design.

**Human controlled trials are studies in humans with controlled exposure (e.g., randomized controlled trials or RCTs, nonrandomized experimental studies).

***Cross-sectional studies include population surveys with individual data (e.g., NHANES) and surveys with aggregate data (i.e., ecological studies).

Assessors were trained with an initial pilot phase undertaken to improve clarity of rating criteria and to improve consistency among assessors. Studies were independently evaluated by two trained assessors who answered all applicable risk-of-bias questions with one of four options shown in Figure 2 following pre-specified criteria detailed in the protocol ([underlined: Appendix I]). The criteria describe aspects of study design, conduct, and reporting required to reach risk-of-bias ratings for each question and specify factors that can distinguish among ratings (e.g., what separates “definitely low” from “probably low” risk of bias).

Figure 2

The Four Risk-of-bias Rating Options

Answers to the risk-of-bias questions result in one of the above four risk-of-bias ratings.

### Key Risk-of-bias Questions

In the OHAT approach, some risk-of-bias questions or elements are considered potentially more important when assessing studies because there is more empirical evidence that these areas of bias have a greater impact on estimates of the effect size or because these issues are generally considered to have a greater effect on the credibility of study results in environmental health studies (Rooney et al. 2016). There were three key questions for observational human studies: confounding, exposure characterization, and outcome assessment. There were also three key questions for experimental animal studies: randomization, exposure characterization, and outcome assessment. When there was insufficient information to assess the potential bias for a risk-of-bias question and authors did not respond to an inquiry for further information, a conservative approach was followed, and the studies were rated as “probably high” risk of bias for that question.

Any discrepancies in ratings between assessors were resolved through discussion to reach the final recorded risk-of-bias rating for each question along with a statement of the basis for that rating. Members of the evaluation team were consulted for assistance if additional expertise was necessary to reach final risk-of-bias ratings based on specific aspects of study design or performance reported for individual studies. Information or study procedures that were not reported is assumed not to have been conducted, resulting in an assessment of probably high risk of bias. Although the protocol defines a purity of 95% with independent confirmation to be necessary for a rating of probably low risk of bias, Munroe et al. (1999) indicates that sarin must be at least 93% pure; therefore, 93% without independent confirmation was considered probably low risk of bias unless there were other reasons (e.g., inhalation study without chamber concentrations) for the exposure characterization to be considered probably high risk of bias.

## Organizing and Rating Confidence in Bodies of Evidence

### Health Outcome and Endpoint Grouping by Four Main Categories of Neurological Effects

The main category for long-term neurological health outcomes includes all neurological effects. After data were extracted for all studies, the health effects results were grouped across studies to develop bodies of evidence or collections of studies with data on the same or related outcomes for the four main categories of neurological effects: (1) cholinesterase (ChE) levels; (2) visual and ocular effects; (3) effects on learning, memory, and intelligence; and (4) morphology and histopathology. Technical advisors and subject matter experts were consulted as needed to determine: (1) endpoints that can be grouped as similar or related endpoints, and (2) if downgrades are warranted based on the reliability or quality of specific endpoints or groups of endpoints for determining neurological effects. The remaining neurological endpoints are discussed briefly.

## Considerations for Pursuing a Narrative or Quantitative Evidence Synthesis

Heterogeneity within the available evidence was used to determine the type of evidence integration that was appropriate: either a quantitative synthesis (meta-analysis) or a narrative approach for evidence integration. Heterogeneity within the available human and animal evidence was so high that only a narrative approach (and not a meta-analysis) was appropriate for evidence integration. Meta-analysis approaches are considered most suitable if there are at least six to 10 studies for a continuous variable and at least four studies for a categorical variable (Fu et al. 2011). ChE effects had the most data available with two controlled trials, one cross-sectional study, and six case reports/series, as well as 14 experimental animal studies; however, the data are not amenable for a meta-analysis because they were not collected during the same time frame, or in the case of the animals from the same biological metric (i.e., blood and different areas of the brain). While studies on memory and visual and ocular effects were also available, the specific tests were diverse. Therefore, the data do not lend themselves to conducting a meta-analysis as there were generally only three to five studies available for any specific endpoint for these continuous variables.

### Confidence Rating: Assessment of Body of Evidence

The quality of evidence within groups of neurological effects was evaluated using the GRADE system for rating the confidence in the body of evidence (Guyatt et al. 2011; Rooney et al. 2014). More detailed guidance on reaching confidence ratings in the body of evidence as “high,” “moderate,” “low,” or “very low” is provided in the OHAT Handbook for Conducting a Literature-Based Health Assessment (https://ntp.niehs.nih.gov/go/38673, see STEP 5). In brief, available human and animal studies on a particular health outcome were initially grouped by key study design features, and each grouping of studies was given an initial confidence rating by those features. Starting at this initial rating (column 1 of Figure 3), potential downgrading of the confidence rating was considered for factors that decrease confidence in the results (column 2 of Figure 3 [risk of bias, unexplained inconsistency, indirectness or lack of applicability, imprecision, and publication bias]); and potential upgrading of the confidence rating was considered for factors that increase confidence in the results (column 3 of Figure 3 [large magnitude of effect, dose response, consistency across study designs/populations/animal models or species, consideration of residual confounding, and other factors that increase confidence in the association or effect]). Consideration of consistency across study designs, human populations, or animal species is not included in the GRADE guidance (Guyatt et al. 2011); however, it is considered in the modified version of GRADE used by OHAT (NTP 2015; NTP 2019a; Rooney et al. 2014).

Figure 3

Assessing Confidence in the Body of Evidence

Confidence ratings were independently assessed by the evaluation team, CounterACT personnel, and the analyst-contractors for accuracy and consistency, and discrepancies were resolved by consensus and consultation with technical advisors as needed. Confidence ratings for the primary outcomes are summarized in evidence profile tables for each outcome.

## Preparation of Level-of-evidence Conclusions

The confidence ratings were translated into level of evidence of health effects for each type of health outcome separately according to one of four statements: (1) High, (2) Moderate, (3) Low, or (4) Inadequate (Figure 4 and Table 4). The descriptor “evidence of no health effect” is used to indicate confidence that the substance is not associated with a health effect. Because of the inherent difficulty in proving a negative, the conclusion “evidence of no health effect” is only reached when there is high confidence in the body of evidence.

Figure 4

Translation of Confidence Ratings into Evidence of Health Effect Conclusions

Table 4 Definitions of Level-of-evidence Descriptors

Evidence Descriptors | Definition
High Level of Evidence | There is high confidence in the body of evidence for an association between exposure to sarin and the health outcome(s).
Moderate Level of Evidence | There is moderate confidence in the body of evidence for an association between exposure to sarin and the health outcome(s).
Low Level of Evidence | There is low confidence in the body of evidence for an association between exposure to sarin and the health outcome(s), or no data are available.
Inadequate Evidence | There is insufficient evidence available to assess if exposure to sarin is associated with the health outcome(s).
Evidence of No Health Effect | There is high confidence in the body of evidence that exposure to sarin is not associated with the health outcome(s).

## Integration of Evidence to Develop Hazard Identification Conclusions

Finally, the levels of evidence ratings for human and animal data were integrated with consideration of in vitro/mechanistic data to reach one of five possible categories of evidence of long-term neurological health effect: (1) Known, (2) Presumed, (3) Suspected, (4) Not Classifiable, or (5) Not Identified to Be a Long-term Neurological Effect in Humans (Figure 5).

Figure 5

Hazard Identification Scheme for Long-term Neurological Effects

### Consideration of Human and Animal Data

Initial hazard identification conclusions were attempted by integrating the highest level-of-evidence conclusion for long-term neurological health effect(s) on an outcome basis for the human and the animal evidence streams. The level of evidence conclusion for human data from Step 6 of the OHAT Handbook for that health outcome was considered together with the level of evidence for animal data to reach one of four initial hazard identification conclusions as to the evidence of long-term neurological effects in humans: Known, Presumed, Suspected, or Not Classifiable. When either the human or animal evidence stream was characterized as inadequate evidence for a particular health effect, then conclusions were based on the remaining evidence stream alone (which is equivalent to treating the missing evidence stream as “Low” in Figure 5).

A clarification and update to the OHAT approach for systematic review and evidence integration were posted (NTP 2019d) after the peer review draft of this systematic review was publicly available (posted December 2018). Therefore, NTP considered any potential effect of the update and determined that the 2019 update and clarification would have no effect on hazard conclusions reached in this evaluation. In brief, the update clarified how hazard conclusions are reached when there is a moderate level of evidence for human data with low or inadequate level of evidence for the animal evidence stream. In that case, a hazard identification conclusion of either “suspected to be a hazard to humans” or “presumed to be a hazard to humans” can be reached based on scientific judgement as to the robustness of the body of evidence that supports moderate confidence in the human data and consideration of the potential impact of additional studies. As presented in the Results and Evidence Synthesis section of this document, this situation applied to visual and ocular effects in the initial and intermediate time periods; learning, memory, and intelligence effects in the extended period; and morphological and histological changes in the extended period, and the 2019 clarification had no effect on hazard conclusions.

### Consideration of Mechanistic Data

There is no requirement to consider mechanistic or mode-of-action data to reach a hazard identification conclusion regarding long-term neurological health effects. However, when available, this and other relevant supporting types of evidence may be used to raise (or lower) the category of the hazard identification conclusion. Mechanistic data can come from a wide variety of studies that are not intended to identify a disease phenotype. This source of experimental data includes in vitro and in vivo laboratory studies directed at cellular, biochemical, genetic, and molecular mechanisms that explain how a chemical produces particular adverse effects.

For the evaluation of long-term neurological health effects associated with acute exposure to sarin, NTP was interested in mechanistic or in vitro measures that may support the biological plausibility of corresponding neurological outcomes reported from in vivo studies in animals or humans. The PECO statement in Table 3 provides the specific endpoints considered, mainly including survival and morphology of neurons or glia. For this assessment, no in vitro studies following these criteria were identified for any time period following exposure (including <24 hours).