# Introduction

Sarin is a nerve agent developed for chemical warfare during World War II. This highly toxic nerve agent (which can cause death, seizures, and immediate cholinergic symptoms) is liquid at ambient temperatures. It is also known as GB, which is a two-character identifier assigned by the North Atlantic Treaty Organization (NATO). Sarin belongs to a chemically diverse group of organophosphorus (OP) chemicals that have at least one carbon atom bound to a phosphorous atom. The group includes other chemical weapons and many agricultural and residential pesticides. Although prohibited by international treaties, it is likely that sarin continues to be used in conflict, as reported by the United Nations in Syria in 2013 (Sellström et al. 2013).

The National Toxicology Program (NTP), in partnership with the National Institutes of Health (NIH) Countermeasures Against Chemical Threats (CounterACT) program, conducted a systematic review to evaluate the evidence for long-term neurological effects^1^ in humans and nonhuman animals^2^ following acute exposure^3^ to the OP nerve agent sarin (CASRN: 107-44-8). This review was initiated because of suggestions in the literature of long-term neurological effects of sarin poisoning in humans [e.g., case reports of victims in the Matsumoto and Tokyo subway attacks suffering long-term behavioral abnormalities and alteration of brain morphology (Murata et al. 1997; Yamasue et al. 2007)] and reports in animal studies of long-term neurological effects of sarin [e.g., experimental animal studies of neurotoxicity (Burchfiel and Duffy 1982) and behavioral and neurophysiological functions (Kassa et al. 2001c)].

1 Throughout this document, a “long-term” neurological effect is defined as any neuropathological, pathophysiological, or behavioral effect observed that occurs at least 24 hours after the acute sarin exposure. Therefore, long-term neurological effects, as defined in this document, may occur immediately after the cholinergic signs and symptoms caused by an initial sublethal acute exposure have subsided, or they may overlap with the initial cholinergic crisis. Long-term neurological effects may also be observed over a range of time periods including days, weeks, months, or years after the cholinergic symptoms subside. Long-term neurological effects may resolve or persist.

2 Throughout this document, the terms “animal” and “animals” are used to refer to nonhuman animals.

3 Throughout this document, “acute exposure” is defined as exposure to sarin occurring in a period of 24 hours or less that causes cholinergic signs and symptoms.

## Acute versus Long-term Effects

The persistence, or time period of effects following acute exposure to sarin, is a key factor in this review. Acute effects of sarin immediately after exposure are well characterized and are not the focus of the review. The median lethal dose (LD_50_) of dermal exposure to sarin for a 70-kg person is only 1–10 mL (ATSDR 2011). Acute effects include a progression from miosis (constriction of the pupils), excessive secretions, and muscle fasciculation to seizures that may progress to status epilepticus, muscle paralysis, cardiorespiratory depression, and death due to respiratory failure. The signs and symptoms of acute exposure are generally referred to as cholinergic signs.

The focus of this review is on neurological effects that are considered “long term” or observed at any time after cholinergic signs have subsided. Such long-term neurological health effects may be observed several hours, days, weeks, or years after the cholinergic crisis subsides. Long-term effects may be pathophysiological and/or behavioral. Therefore, in this evaluation, “long term” is considered any effect occurring more than 24 hours after exposure. The 24-hour time point was selected to reflect the possible variation in time for cholinergic signs to subside due to differing exposure levels and individual responses. For the purpose of characterizing outcomes, the time after exposure was broken down into three time periods to better capture effects related to sarin exposure in the days (initial time period, potentially including cholinergic effects), weeks (intermediate time period, not anticipated to include cholinergic effects), and years (extended time period) after exposure. This approach was followed to help determine if the long-term effects resolve or persist.

## Purpose of the Review

This review critically evaluated the publicly available evidence of potential long-term neurological effects associated with acute sarin exposure to help inform the focus of treatment options for prolonged effects. Several literature reviews of the long-term neurological effects following exposure to sarin have been published (Augerson 2000; Binns et al. 2004; Brown 2009; Brown and Brix 1998; Defense Science Board 1994; IOM 2004; SIPRI 1975; White et al. 2016). Many of these reviews, however, have assessed health effects in military personnel during conflicts such as the Gulf War and are confounded by concurrent mixed exposures to other chemicals including other chemical warfare agents. Although other OP nerve agents may cause long-term neurological effects through similar mechanisms, there may be differences in health effects, potencies, and durations of effects associated with exposures to different OP agents and mixtures of OP agents. Therefore, those data are beyond the scope of this review, although it is recognized that in a wider context the results from studies on other OP agents may support the long-term neurological effects of sarin.

This systematic review was developed to focus on a specific data set for which sarin is the only exposure. To date, a systematic review of the evidence on sarin has not been performed in which selection criteria were clearly stated and consistently applied; where a broad hierarchy of evidence is considered including all evidence streams (human, animal and mechanistic); where a broad range of human study designs are considered including uncontrolled studies and case reports or case series; and in which individual studies were assessed for internal validity or risk of bias. Given that most of the evidence for potential long-term health effects of sarin addresses neurological endpoints, this review focused on neurological outcomes.

## Available Data

Due to the nature of exposure to sarin (i.e., rare events that, when they occur, are most often a result of occupational accidents or terror attacks), the available studies in humans are primarily case reports, case series, or cross-sectional studies; they also include two controlled trials. The majority of human data come from individuals studied following two terrorist attacks in Japan. One attack occurred in the Tokyo subway system in 1995 (Okumura et al. 1996) and the other attack occurred in Matsumoto in 1994 in a residential area near the center of the city (Morita et al. 1995). Although it is suspected that sarin was used in recent attacks in Syria, publicly available data on long-term neurological effects from these exposures have not been identified for this review.

During the 1995 Tokyo subway attack, sarin was released in five subway cars on three separate subway lines during the morning rush hour. Eleven of the commuters died and more than 5,000 subjects required emergency medical evaluation (Okumura et al. 1996). The agent used in the attack was quickly identified as a dilute form of sarin, and patients were treated within hours of exposure. Many of the publications on this attack were based on the initial 640 patients admitted to St. Luke’s International Hospital. This was the closest hospital to one of the subway stations hit and treated the largest patient population exposed to sarin (Ohbu et al. 1997). Of these 640 subjects, 111 were admitted to the hospital and 528 were considered to be mild cases and were discharged.

The 1994 Matsumoto attack occurred in a residential area near the center of the city (Morita et al. 1995). Sarin was not immediately identified as the source of illness in residents but was detected in a city pond approximately 1 week after symptoms of poisoning were first reported. It was estimated that about 600 residents were exposed based on a survey of residents conducted 3 weeks after exposure with an 84.9% response rate (Nakajima et al. 1999; Nakajima et al. 1998). Fifty-eight people were reportedly admitted to hospitals, and seven deaths occurred (Morita et al. 1995). Although many of the subjects required hospitalization or consulted a doctor due to symptoms, treatment would have occurred for many subjects more than a week after exposure if at all.

It is acknowledged that there are likely clinical observations on individuals following acute sarin exposure that are unpublished or not publicly available due to the military and terrorism significance of sarin; however, all of the evidence in a systematic review must be fully available to support the rigor and transparency of the conclusions. This evaluation does not aim to discount the value of these clinical experiences, but for the purpose of transparency, this review only considered publicly available data.

It is also recognized that due to the hazards of working with sarin, there are only a few laboratories that are permitted to work with the substance. This limits the number of publicly available nonhuman mammalian studies. As discussed above for the clinical observations, it is likely that there are many governments that have studied neurological effects of sarin in research animals but have not made the data publicly available. NTP did not contact laboratories that worked with sarin, nor did it contact other government agencies to determine the accessibility of sarin data that are not publicly available for review.

## Exposure Assessment

In experimental studies of humans and animals for which dose is known, cholinergic signs are generally characterized as mild, moderate, or severe. When dose is unknown, a reasonable approximation of dose may be estimated by observing clinical signs and symptoms. This is an established approach in which a threshold detection level may be translated into estimates of high-, intermediate-, and low-level exposures with an accepted degree of consistency (Brown and Brix 1998). The assessment of quantitative exposure levels of sarin at which long-term neurological effects occur is beyond the scope of this review. Most studies—with the exception of case reports on separate individuals—did not report the data in a manner that allowed for the assessment of exposure levels in relation to the results (e.g., a lack of reporting of clinical signs or severity of the cholinergic effects). It is possible that the likelihood of long-term effects may be tied to the severity of the cholinergic signs, which in turn may be related to exposure level; however, the available data do not allow for such an evaluation.

Responders to the attacks were also likely exposed to sarin to some degree depending on the timing of the response and proximity to the source of exposure. There are studies that evaluated long-term neurological effects in first responders of the Tokyo subway attack; however, none of these studies specifically addressed the exposure levels of these individuals.

Several factors may affect dose and possible long-term neurological effects. In controlled human and animal trials, 93% was the lowest percent purity that was considered sufficient to reduce potential bias of exposure. Although it is recognized that the purity of sarin may be an issue in accidental occupational exposures or during terrorist attacks, purity of the sarin used in the attack is not generally reported. Possible purity issues were only addressed when there was additional exposure that may affect treatment (e.g., sarin was not the only compound of concern).

Another factor that may affect results for long-term neurological effects of sarin is if or when a person or experimental animal receives treatment for the acute effects. After a known exposure to sarin, humans will receive treatment to alleviate the symptoms of exposure. Because the attack in Matsumoto did not immediately identify sarin as the cause of the symptoms, subjects were less likely to receive treatment or treatment was delayed compared with the Tokyo subway attack. This difference in treatment is likely to have contributed to differences in health effects reported after these two attacks. Experimental animal studies, in which the animals received treatment before or after receiving sarin, were not included in this review.

## Objective and Specific Aims

### Objective

The overall objective of this evaluation was to undertake a systematic review to understand the long-term neurological effects following acute, sublethal exposure to sarin based on integrating levels of evidence from human and animal studies and consideration of the degree of support from mechanistic data.

### Specific Aims

- Identify literature that assessed long-term neurological health effects following acute exposure to sarin in human, animal, and in vitro/mechanistic studies.
- Extract data on potential long-term (as described above) neurological health effects from relevant studies.
- Assess the internal validity (risk of bias) of individual studies using predefined criteria.
- Summarize the extent and types of health effects evidence available.
- Describe limitations of the systematic review and limitations of the evidence base; identify areas of uncertainty, as well as data gaps and research needs on long-term neurological health effects of sarin.

Dependent on the extent and nature of the available evidence:

- Synthesize the evidence using a narrative approach or meta-analysis (if appropriate) considering limitations on data integration such as study design heterogeneity.
- Rate confidence in the body of evidence for human and animal studies separately according to one of four statements: High, Moderate, Low, or Very Low/No Evidence Available.
- Translate confidence ratings into level of evidence of health effects for human and animal studies separately according to one of four statements: High, Moderate, Low, or Inadequate.
- Combine the level of evidence ratings for human and animal data to reach one of five possible hazard identification conclusions: Known, Presumed, Suspected, Not Classifiable, or Not Identified to Be a Hazard to Humans.