# Conflict of Interests

Individuals identified as collaborators in the About This Review section have certified that they have no known real or apparent conflict of interest related to sarin.