# Acknowledgments

This work was supported by the Intramural Research Program (ES103316, ES103317) at the National Institute of Environmental Health Sciences, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts HHSN316201200028W (Order No. HHSN27300006) and GS00Q14OADU417 (Order No. HHSN273201600015U). The evaluation reported in this monograph was supported in part by the NIH Countermeasures Against Chemical Threats program in the Office of Biodefense Research and Surety at the National Institute for Allergy and Infectious Disease.