# Appendix I Supplemental Files

The following supplemental file is available at https://doi.org/10.22427/NTP-DATA-MGRAPH-6.

## I.1 Protocol Information

Protocol