# Appendix H Protocol History

The protocol is available in Appendix I.

Table H-1 Protocol History and Revisions

Date | Activity or Revision
February 26–27, 2014 | Problem formulation: Outcome of CounterACT workshop. Posted online and circulated internally for comment/review – impetus for this systematic review.
January 5, 2016 | Draft evaluation protocol reviewed: Sent to technical advisors for peer reviewer by Drs. Madsen and Scherer.
April 15, 2017 | Evaluation protocol finalized: Review protocol finalized for use and posting.