# Appendix F Additional Data Tables

Table F-1 Neurological Symptom Summary for Victims of the Matsumoto and Tokyo Subway Sarin Attacks^a,b^

Symptom^c^ | Study Population | | | | | | | | | | | | | | Symptom References^f^ (Time Frames) | Reference Notes
Symptom^c^ | Matsumoto Sarin Attack (1994) Time after Exposure^d^ | | | | | | Tokyo Subway Sarin Attack (1995) Time after Exposure^e^ | | | | | | | | Symptom References^f^ (Time Frames) | Reference Notes
Symptom^c^ | 1 wk. | 3 wk. | 4 mo. | 1 yr. | 3 yr. | 5 yr. | 1 wk. | 1 mo. | 2 mo. | 3 mo. | 1 yr. | 2 yr. | 3 yr. | 5 yr. | Symptom References^f^ (Time Frames) | Reference Notes
Eye Problems
Visual
Asthenopia | – | √ | √ | √ | √ | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998); Nakajima et al. (1999); Okudera (2002)
Blurred vision | √ | √ | √ | √ | √ | – | √ | √ | √ | √ | – | – | – | √ | Nakajima et al. (1998); Nakajima et al. (1999); Ogawa et al. (1999); Ohtani et al. (2004); Ohtomi et al. (1996); Nohara and Segawa (1996); Okudera (2002)
Constricted visual field | – | – | – | – | – | – | – | – | √ | – | – | – | – | – | Ogawa et al. (1999)
Darkness of visual field | – | √ | √ | – | – | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998); Okudera (2002); Morita et al. (1995) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr.
Difficulty focusing (vision) | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Difficulty in seeing far | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Difficulty in seeing nearby objects | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Difficulty seeing close | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Difficulty seeing distance | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Dim vision | √ | – | – | – | – | √ | √ | √ | √/0 | √ | – | √ | √ | √ | Kawana et al. (2001); Ohtomi et al. (1996); Morita et al. (1995); Ogawa et al. (1999); Nohara and Segawa (1996) | For Ohtomi et al. (1996), symptom was reported by two victims at 1 mo. and one victim at 3 mo., but no victims reported it at 2 mo.; symptom was reported by Ogawa et al. (1999) at 2 mo.
Diplopia/double vision | – | √ | √ | – | – | – | – | – | √ | – | – | – | – | – | Nakajima et al. (1998); Ogawa et al. (1999) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr.
Flickering of vision | – | √ | √ | – | – | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr.
Narrowing of visual field | √ | √ | √ | √ | √ | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998); Nakajima et al. (1999); Nohara and Segawa (1996)
Visual field abnormalities | – | – | – | √ | – | – | √ | √ | √ | √ | – | – | – | – | Ohtomi et al. (1996); Sekijima et al. (1997)
Ocular
Ciliary and conjunctival congestion | – | – | – | – | – | – | √ | √ | √ | √ | – | – | – | – | Ohtomi et al. (1996)
Eye/ocular irritation | – | – | – | – | – | – | – | – | √ | – | – | – | – | – | Ogawa et al. (1999)
Eye mucus | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Eye/ocular pain | √ | √ | √ | – | – | – | – | – | √ | – | – | – | – | – | Ogawa et al. (1999); Nohara and Segawa (1996); Nakajima et al. (1998); Okudera (2002); Morita et al. (1995) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr.
Eyes tend to become easily tired | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Feeling of a foreign object in the eye | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Increase in lacrimation | – | √ | √ | – | – | – | – | – | √ | – | – | – | – | – | Nakajima et al. (1998); Ogawa et al. (1999) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr. (Nakajima et al. 1998).
Lower intraocular pressure | – | – | – | – | – | – | √ | √ | √ | √ | – | – | – | – | Ohtomi et al. (1996)
Miosis | – | – | – | – | – | – | √ | √ | 0 | 0 | – | – | – | – | Ohtomi et al. (1996) | Miosis appeared in 95% of 62 hospitalized patients but disappeared within 1 mo. except for two patients. Miosis disappeared in all patients by 2 mo. following exposure.
Ocular and periorbital pain | – | – | – | – | – | – | √ | √ | √ | √ | – | – | – | – | Ohtomi et al. (1996)
Eye symptoms (general) | – | √ | – | – | – | √ | – | – | – | – | √ | √ | √ | √ | Kawana et al. (2001); Ohtani et al. (2004); Okumura et al. (2005); Okudera (2002); Morita et al. (1995)
Behavioral Changes
Avoidance
Avoidance of places that trigger recollections of the trauma | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Avoidance of the subject of the incident | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Avoidance of thoughts and conversations associated with trauma | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Concentration Difficulty
Difficulty concentrating | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Difficulty in focusing | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Lack of concentration | – | – | – | – | – | – | – | – | – | – | √ | – | – | √ | Ohtani et al. (2004); Okumura et al. (2005)
Depression
Depressed mood/feelings | – | – | – | – | – | √ | – | √ | – | – | √ | √ | √ | √ | Kawana et al. (2001); Ohbu et al. (1997); Okumura et al. (2005) | Ohbu et al. (1997) reports that 74 of 475 hospital patients (16%) reported this symptom at 1 mo. following the exposure. The author does not report on this symptom specifically at 3 and 6 mo. following exposure but notes that “almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 mo. after the incident. This percentage remained almost the same even 3 and 6 mo. after the incident.”
Diminished interest, numbing | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Diminished interest and apathy | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Memory
Difficulty with memory | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Forgetfulness | √ | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004); Sekijima et al. (1995)
Recollections of an event | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Sleep Disruption
Bad dreams | – | – | – | √ | √ | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998); Nakajima et al. (1999); | This symptom was included in the questionnaire at 1 yr. but was excluded from the questionnaires at 3 wk. and 4 mo. (Nakajima et al. 1998).
Nightmares | – | – | – | – | – | – | – | √ | – | – | – | – | – | √ | Ohbu et al. (1997); Ohtani et al. (2004) | Ohbu et al. (1997) reports that 48 of 475 hospital patients (10%) reported this symptom at 1 mo. following the exposure. The author does not report on this symptom specifically at 3 and 6 mo. following exposure but notes that “almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 mo. after the incident. This percentage remained almost the same even 3 and 6 mo. after the incident.”
Difficulty falling or staying asleep | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Distressing dreams, nightmares | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Insomnia | – | √ | √ | √ | √ | – | – | – | √ | – | – | – | – | √ | Nakajima et al. (1998); Nakajima et al. (1999); Ogawa et al. (1999); Ohtani et al. (2004)
Sleep disturbance | – | – | – | – | – | – | – | √ | – | – | – | – | – | – | Ohbu et al. (1997) | Ohbu et al. (1997) reports that 137 of 475 hospital patients (29%) reported this symptom at 1 mo. following the exposure. The author does not report on this symptom specifically at 3 and 6 mo. following exposure but notes that “almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 mo. after the incident. This percentage remained almost the same even 3 and 6 mo. after the incident.”
Anxiety and Fear
Fear concerning escape from the attack | – | – | – | – | – | – | – | – | – | – | √ | – | – | – | Okumura et al. (2005)
Fear in the subway or at the incident | – | – | – | – | – | – | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Fear of subway | – | – | – | – | – | – | – | √ | – | – | √ | – | – | – | Okumura et al. (2005); Ohbu et al. (1997) | Ohbu et al. (1997) reports that 152 of 475 hospital patients (32%) reported this symptom at 1 mo. following the exposure. The author does not report on this symptom specifically at 3 and 6 mo. following exposure but notes that “almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 mo. after the incident. This percentage remained almost the same even 3 and 6 mo. after the incident.”
Shaking with fear | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Fatigue/Lethargy/Weakness
Asthenia | – | – | – | √ | √ | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998); Nakajima et al. (1999); Okudera (2002) | This symptom was included in the questionnaire at 1 yr. but was excluded from the questionnaires at 3 wk. and 4 mo. (Nakajima et al. 1998).
Easily fatigued | – | √ | √ | √ | √ | – | – | – | – | – | √ | – | – | √ | Nakajima et al. (1998); Nakajima et al. (1999); Ohtani et al. (2004); Okumura et al. (2005); Okudera (2002); Morita et al. (1995)
Tiredness | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Lethargy | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Weakness (general) | – | – | – | – | – | – | – | – | √ | – | – | – | – | – | Ogawa et al. (1999)
Other Behavior
Astonishment | – | – | – | – | – | – | – | √ | – | – | – | – | – | – | Ohbu et al. (1997) | Ohbu et al. (1997) reports that 52 of 475 hospital patients (11%) reported this symptom at 1 mo. following the exposure. The author does not report on this symptom specifically at 3 and 6 mo. following exposure but notes that “almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 mo. after the incident. This percentage remained almost the same even 3 and 6 mo. after the incident.”
Difficulty reading/writing | – | √ | √ | 0 | – | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998)
Flashbacks | – | – | – | – | – | √ | – | √ | – | – | √ | √ | √ | √ | Kawana et al. (2001); Ohbu et al. (1997); Okumura et al. (2005) | Ohbu et al. (1997) reports that 76 of 475 hospital patients (16%) reported this symptom at 1 mo. following the exposure. The author does not report on this symptom specifically at 3 and 6 mo. following exposure but notes that “almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 mo. after the incident. This percentage remained almost the same even 3 and 6 mo. after the incident.”
Hypervigilance | – | – | – | – | – | √ | – | – | – | – | – | √ | √ | √ | Kawana et al. (2001)
Effect of event scale-revised (IES-R) | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Irritability | – | – | – | – | – | √ | – | √ | – | – | – | √ | √ | √ | Kawana et al. (2001); Ohbu et al. (1997) | Ohbu et al. (1997) reports that 48 of 475 hospital patients (10%) reported this symptom at 1 mo. following the exposure. The author does not report on this symptom specifically at 3 and 6 mo. following exposure but notes that “almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 mo. after the incident. This percentage remained almost the same even 3 and 6 mo. after the incident.”
Restlessness and irritability | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Sense of suppression | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Tension | – | – | – | – | – | – | – | – | – | – | – | – | – | √ | Ohtani et al. (2004)
Neuromuscular Effects
Gait disturbance | – | 0 | 0 | – | – | – | – | – | √ | – | – | – | – | – | Nakajima et al. (1998); Ogawa et al. (1999) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr. Zero patients reported this symptom at 3 wk. and 4 mo. (Nakajima et al. 1998). For Ogawa 1999, gait disturbance persisted for 0.3% of subjects at 2 mo.
Numbness of extremities | – | – | – | – | – | – | – | – | √ | – | – | – | – | – | Ogawa et al. (1999)
Paresis of perioral muscle | – | √ | 0 | – | – | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr. Zero victims reported this symptom at 4 mo.
Other Neurological
Dysomia (change in sense of smell) | – | – | – | – | – | – | – | – | √ | – | – | – | – | – | Ogawa et al. (1999)
Dizziness | – | √ | √ | – | – | √ | – | – | √ | – | – | √ | √ | √ | Kawana et al. (2001); Nakajima et al. (1998); Ogawa et al. (1999); Ohtani et al. (2004) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr. (Nakajima et al. 1998).
Dysesthesia of extremities | – | √ | √ | – | – | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998) | This symptom was included in the questionnaires at 3 wk. and 4 mo. but was excluded from the questionnaire at 1 yr.
Headache | – | √ | √ | √/0 | √ | √ | √ | √ | √ | √ | √ | √ | √ | √ | Kawana et al. (2001); Nakajima et al. (1998); Nakajima et al. (1999); Ogawa et al. (1999); Ohtani et al. (2004); Ohtomi et al. (1996); Okumura et al. (2005); Okudera (2002); Morita et al. (1995) | Zero victims reported this symptom at 1 yr. (Nakajima et al. 1998).
Heaviness in head | – | √ | √ | 0 | – | – | – | – | – | – | – | – | – | – | Nakajima et al. (1998) | Zero victims reported this symptom at 1 yr.

^a^ This table provides a summary of neurological symptoms identified by study subjects at various time frames after exposure. The prevalence or severity of symptoms is not indicated here.

^b^ A “√” indicates the effect was reported at that time frame in at least one subject and in at least one of the studies listed. A dash indicates that no data are available for that time frame by any of the listed studies. A “0” indicates that at least one listed study reported that the symptom had fully subsided by the time frame.

^c^ Symptoms are self-reported (via questionnaire) or based on physician observation (not determined by a specific test).

^d^ Matsumoto study time frames: Nohara and Segawa (1996) (1 wk.); Morita et al. (1995) (1 wk.); Sekijima et al. (1995) (1 wk.); Nakajima et al. (1998) (3 wk., 4 mo., 1 yr.); Nakajima et al. (1999) (1 and 3 yr.); Kawana et al. (2001) (5 yr.).

^e^ Tokyo study time frames: Ogawa et al. (1999) (2 mo.); Ohtomi et al. (1996) (1 wk., 1 mo., 2 mo., and 3 mo.); Okumura et al. (2005) (1 yr.); Ohtani et al. (2004) (5 yr.); Ohbu et al. (1997) (1 mo.); Kawana et al. (2001) (2, 3, and 5 yr.).

^f^ All studies list this symptom for at least one of the time frames presented, but all studies do not necessarily report symptoms for all the time frames.

Table F-2 Summary of Neurobehavioral Endpoints in Animals – Learning and Memory

Endpoint | Genovese et al. (2008) | Genovese et al. (2009) | | Grauer et al. (2008) | | | Kassa et al. (2001b)
Endpoint | Monkey | Rat | Rat | | | | Rat
Endpoint | 30 d. | 48 hr. | 5 wk. | | 4 mo. | 6 mo. | 1 wk. | 2 wk. | 3 wk. | 4 wk. | 5 wk.
Endpoint | 0, 0.701 mg/m^3^ | 0–4 mg/m^3^ | 0, 34.2 μg/L | | | | 0–2.5 μg/L
Neurological: Behavior
Learning and Memory
Serial probe recognition | NS ↔ | – | – | | – | – | – | – | – | – | –
Radial-arm maze, completion time (first 5-block session) | – | NS ↑ (high dose) | – | | – | – | – | – | – | – | –
Radial-arm maze, total errors (first 5-block session) | – | SIG ↑ block 1 | – | | – | – | – | – | – | – | –
Radial-arm maze, reference errors (first 5-block session) | – | SIG ↑ block 1 | – | | – | – | – | – | – | – | –
Radial-arm maze, working errors (first 5-block session) | – | SIG ↑ block 1 | – | | – | – | – | – | – | – | –
Radial-arm maze, VI56 response rate (first session) | – | NS ↕ | – | | – | – | – | – | – | – | –
Radial-arm maze, VI56 response rate (first 5-block session) | – | NS ↓ | – | | – | – | – | – | – | – | –
T-maze, completion | – | – | – | | – | – | NS ↔ | NS ↔ | NS ↔ | NS ↔ | NS ↔
Water maze, latency to reach platform (trial 1, day 1) | – | – | NS ↔ | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 1, day 2) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 1, day 3) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 1, day 4) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 1, day 5) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 2, day 1) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 2, day 2) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 2, day 3) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 2, day 4) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –
Water maze, latency to reach platform (trial 2, day 5) | – | – | ↑ (SIG UNK) | | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | –

SIG ↑ or ↓ = statistically significant increase or decrease at the dose(s) specified; if no dose is specified, it was a single-dose study or significance occurred at all doses.

NS = not significant: ↔ (≤15% change; also considered NS at ≤15% change when statistical analyses were not conducted [see Grauer et al. (2008)]); ↑ increased; ↓ decreased;

↕ inconsistent change; if no dose is specified, it was a single-dose study or the change occurred at all doses.

SIG UNK = level of significance unknown/unclear.

Table F-3 Summary of Neurobehavioral Endpoints in Animals – Discrimination Learning

Endpoint | Kassa et al. (2002) | | | | | Kassa et al. (2004) | | | | | | Muggleton et al. (2003) | Pearce et al. (1999) | | | | | | Wolthuis et al. (1995)
Endpoint | Rat | | | | | Rat | | | | | | Marmoset | Marmoset | | | | | | Marmoset
Endpoint | 1 wk. | 2 wk. | 3 wk. | 4 wk. | 5 wk. | 1 wk. | 2 wk. | 3 wk. | 4 wk. | 5 wk. | 6 wk. | 0–12 d. | 1 wk. | 2 wk. | 3 wk. | 4 wk. | 5 wk. | 6 wk. | 2 d. | 3 d. | 4 d.
Endpoint | 0–2.5 μg/L | | | | | 0–2.5 μg/L | | | | | | 0, 11.15 μg/kg | 0, 3 μg/kg | | | | | | 0–12 μg/kg
Neurological: Behavior
Discrimination Learning
% Errors; lines | – | – | – | – | – | – | – | – | – | – | – | – | NS ↔ | NS ↔ | NS ↔ | NS ↔ | NS ↓ | NS ↔ | – | – | –
% Errors; shapes | – | – | – | – | – | – | – | – | – | – | – | – | NS ↑ | NS ↔ | NS ↓ | NS ↔ | NS ↓ | NS ↔ | – | – | –
Mean errors per reversal | – | – | – | – | – | – | – | – | – | – | – | SIG ↓ | – | – | – | – | – | – | – | – | –
Visual discrimination performance | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | NS ↓ (high dose) | NS ↓ (high dose) | NS ↓ (high dose)
Y-maze, spatial discrimination (time of reaction) | SIG ↑ (high dose) | SIG ↑ (high dose) | SIG ↑ (high dose) | NS ↑ (mid, high dose) | NS ↑ (mid, high dose) | SIG ↑ (high dose) | SIG ↑ (high dose) | SIG ↑ (high dose) | NS ↑ | NS ↑ | NS ↔ | – | – | – | – | – | – | – | – | – | –

SIG ↑ or ↓ = statistically significant increase or decrease at the dose(s) specified; if no dose is specified, it was a single-dose study or significance occurred at all doses.

NS = not significant: ↔ (≤15% change); ↑ increased; ↓ decreased; ↕ inconsistent change; if no dose is specified, it was a single-dose study or the change occurred at all doses.

Table F-4 Summary of Neurobehavioral Endpoints in Animals – Reflexes, Motor Strength, Coordination, and Motor Activity and Memory

Endpoint | Abou-Donia et al. (2002) | | Allon et al. (2011) | | Grauer et al. (2008) | | | | Kassa et al. (2001a) | | | Kassa et al. (2004) | Little et al. (1986) | Wolthuis et al. (1995)
Endpoint | Rat | | Rat | | Rat | | | | Rat | | | Rat | Mouse | Marmosets
Endpoint | 7 d. | 15 d. | 1 mo. | 6 mo. | 5 wk. | 6 wk. | 4 mo. | 6 mo. | 3 mo.^a^ | 6 mo. | 12 mo. | 3 mo. | 4 d | 4 d | 5 d | 6 d
Endpoint | 0–100 μg/kg | | 0, 27.2 μg/L | | 0, 34.2 μg/L | | | | 0–2.5 μg/L | | | 0–2.5 μg/L | 0, 80 μg/kg | 0–12 μg/kg
Neurological: Behavior
Reflexes, Motor Strength, Coordination
Beam walk score | SIG ↓ | SIG ↓ | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Beam walk time | SIG ↑ | SIG ↑ | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Grip (time to release grip) | SIG ↓ | SIG ↓ | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Hand-eye coordination performance | – | – | – | – | – | – | – | – | – | – | – | – | – | NS ↓ (high dose) | NS ↓ (high dose) | NS ↔
Incline plane (slip angle) | SIG ↓ | SIG ↓ | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Fall from vertical position, FOB score | – | – | – | – | – | – | – | – | NS ↔ | NS ↔ | NS ↔ | – | – | – | – | –
Fore and hindlimb grip strength, FOB score | – | – | – | – | – | – | – | – | NS ↔ | NS ↔ | NS ↔ | – | – | – | – | –
Forelimb grip strength, FOB score | – | – | – | – | – | – | – | – | NS ↔ | NS ↔ | NS altered (high dose) | – | – | – | – | –
Hindlimb grip strength, FOB score | – | – | – | – | – | – | – | – | NS ↔ | SIG altered (low, mid dose) | NS ↔ | – | – | – | – | –
Landing foot splay, FOB score | – | – | – | – | – | – | – | – | NS altered (low dose) | NS ↔ | NS ↔ | – | – | – | – | –
Righting reflex, FOB score | – | – | – | – | – | – | – | – | NS ↔ | NS ↔ | NS ↔ | – | – | – | – | –
Motor Activity
Spontaneous activity | – | – | – | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) | – | – | –
Open field activity (no. of crossings) | – | – | NS ↑ | SIG ↑ | – | – | – | – | – | – | – | – | – | – | – | –
Open field activity in center (day 1) | – | – | – | – | – | NS ↔ | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Open field activity in center (day 2) | – | – | – | – | – | ↑ (SIG UNK) | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Open field activity in periphery (day 1) | – | – | – | – | – | NS ↔ | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Open field activity in periphery (day 2) | – | – | – | – | – | ↑ (SIG UNK) | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Activity, FOB score | – | – | – | – | – | – | – | – | SIG altered (high dose) | NS ↔ | NS ↔ | SIG altered (high dose) | – | – | – | –
Activity horizontal, FOB score | – | – | – | – | – | – | – | – | NS ↔ | NS altered (low, mid dose) | NS altered (all doses) | – | – | – | – | –
Activity vertical, FOB score | – | – | – | – | – | – | – | – | NS altered (all doses) | NS altered (all doses) | NS altered (all doses) | – | – | – | – | –
Gait disorder, FOB score | – | – | – | – | – | – | – | – | SIG altered (high dose) | NS ↔ | NS ↔ | SIG altered (high dose) | – | – | – | –
Gait score, FOB score | – | – | – | – | – | – | – | – | SIG altered (high dose) | NS ↔ | NS ↔ | SIG altered (high dose) | – | – | – | –
Mobility, FOB score | – | – | – | – | – | – | – | – | SIG altered (high dose) | NS ↔ | NS ↔ | SIG altered (high dose) | – | – | – | –
Stereotypy, FOB score | – | – | – | – | – | – | – | – | SIG altered (mid, high dose) | NS ↔ | NS ↔ | SIG altered (mid, high dose) | – | – | – | –
Exploratory activity, FOB score | – | – | – | – | – | – | – | – | NS altered (mid, high dose) | SIG altered (low dose) | NS altered (all doses) | – | – | – | – | –
Motor Activity or Memory
Water maze speed of performance (trial 1, day 1) | – | – | – | – | ↑ (SIG UNK) | – | NS ↔ | NS ↔ | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 1, day 2) | – | – | – | – | ↑ (SIG UNK) | – | NS ↔ | ↓ (SIG UNK) | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 1, day 3) | – | – | – | – | ↑ (SIG UNK) | – | NS ↔ | NS ↔ | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 1, day 4) | – | – | – | – | ↑ (SIG UNK) | – | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 1, day 5) | – | – | – | – | ↑ (SIG UNK) | – | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 2, day 1) | – | – | – | – | NS ↔ | – | NS ↔ | NS ↔ | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 2, day 2) | – | – | – | – | ↑ (SIG UNK) | – | NS ↔ | NS ↔ | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 2, day 3) | – | – | – | – | – | – | NS ↔ | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 2, day 4) | – | – | – | – | NS ↔ | – | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –
Water maze speed of performance (trial 2, day 5) | – | – | – | – | ↑ (SIG UNK) | – | ↑ (SIG UNK) | ↑ (SIG UNK) | – | – | – | – | – | – | – | –

SIG ↑ or ↓ = significantly increased or decreased at the dose(s) specified; if no dose is specified, it was a single-dose study or significance occurred at all doses.

NS = not significant: ↔ (≤15% change; also considered NS at ≤15% change when statistical analyses were not conducted [see Grauer et al. (2008)]); ↑ increased; ↓ decreased;

↕ inconsistent change; if no dose is specified, it was a single-dose study or the change occurred at all doses.

SIG altered = significantly altered FOB score at the dose(s) specified.

NS altered = not significant but altered FOB score (≤15% change) at the dose(s) specified.

SIG UNK = level of significance unknown/unclear.

^a^ Except for righting reflex and exploratory activity, these 3-month data were also presented in Kassa et al. 2001c.

Table F-5 Summary of Neurobehavioral (Sensory, Anxiety, Other), Neuromuscular, and Ocular Endpoints in Animals

Endpoint | Kassa et al. (2001c) | Kassa et al. (2001a)
Endpoint | Rat | Rat
Endpoint | 3 mo. | 3 mo.^a^ | 6 mo. | 12 mo.
Endpoint | 0–2.5 μg/L | 0–2.5 μg/L
Neurological: Behavior
Sensory (FOB Score)
Approach response | – | NS altered (mid dose) | NS ↔ | NS altered (all doses)
Click response | – | NS altered (all doses) | NS altered (mid, high dose) | NS altered (low, high dose)
Tail-pinch response | – | NS altered (all doses) | NS ↔ | NS altered (low, mid dose)
Touch response | – | NS altered (all doses) | NS ↔ | NS altered (all doses)
Anxiety and Fear (FOB Score)
Bizarre behavior | – | NS ↔ | NS ↔ | NS ↔
Tension | NS ↔ | – | NS ↔ | NS ↔
Tremor | NS ↔ | – | NS ↔ | NS ↔
Urination | – | NS altered (all doses) | NS altered (all doses) | NS altered (low, high dose)
Defecation | – | NS altered (all doses) | NS altered (all doses) | NS altered (all doses)
Vocalizations | NS ↔ | – | NS ↔ | NS ↔
Other Neurotoxicity (FOB Score)
Catch difficulty | – | NS altered (low, high dose) | NS altered (mid, high dose) | NS ↔
Ease of handling | – | NS altered (low, mid dose) | NS altered (mid, high dose) | NS altered (mid, high dose)
Piloerection | – | NS ↔ | NS ↔ | NS ↔
Posture | – | NS altered (mid dose) | SIG altered (low, mid dose) | NS ↔
Salivation | – | NS ↔ | NS ↔ | NS ↔
Secretion | – | NS ↔ | NS ↔ | NS ↔
Neuromuscular (FOB Score)
Muscular tonus | – | NS ↔ | NS ↔ | NS ↔
Ocular (FOB Score)
Endo-exophthalmos | – | NS ↔ | NS ↔ | NS ↔
Lacrimation | – | NS ↔ | NS ↔ | NS ↔
Palpebral closure | – | NS ↔ | NS ↔ | NS ↔
Pupil size | – | NS ↔ | NS ↔ | NS ↔
Pupil response | – | NS ↔ | NS ↔ | NS ↔

NS = not significant: ↔ (≤15% change).

SIG altered = significantly altered FOB score at the dose(s) specified.

NS altered = not significant but altered FOB score (≥15% change) at the dose(s) specified.

^a^ The 3-month data reported for Kassa et al. 2001a were also reported in Kassa et al. 2001c.

## F.1 Additional Human Endpoints and Animal Biochemical Data

Additional endpoints from human studies not discussed in the main document or Appendix E are listed by category in Table F-6.

Seven animal studies included biochemical endpoint data after acute sarin exposure. Although most of the studies found some effect in the endpoints measured (see Table F-7 below), none of the studies evaluated the same endpoints. Therefore, no conclusion can be made on any potential mechanism from the available biochemical data in animals.

Table F-6 Additional Human Endpoints

Study Name | Endpoint
PTSD
Kawana et al. (2001) | PTSD (DSM-IV); PTSE-Nakano; partial PTSD
Ohtani et al. (2004) | Effect of event scale-revised (IES-R); lifetime PTSD; current PTSD
Tochigi et al. (2005) | Current PTSD; PTSD; lifetime PTSD
Nishiwaki et al. (2001) | IES score
Murata et al. (1997) | PTSD
Okumura et al. (1996) | PTSD
Tochigi et al. (2002) | IES-R score
Balance
Miyaki et al. (2005) | Stabilometry-x length (eyes open or closed); Stabilometry-total length (eyes open or closed); Stabilometry-y length (eyes open or closed); Stabilometry-sway area (eyes open or closed)
Yokoyama et al. (1998b) | Frequencies of sway (different measures, eyes open or closed); postural sway (eyes open or closed)
Nishiwaki et al. (2001) | Stabilometry-x length (eyes open or closed); Stabilometry-total length (eyes open or closed); Stabilometry-y length (eyes open or closed); Stabilometry-sway area (eyes open or closed)
Digit Tapping
Miyaki et al. (2005) | Psychomotor function-tapping (dominant); Psychomotor function-tapping (nondominant)
Loh et al. (2010) | Psychomotor finger tapping T-scores
Nishiwaki et al. (2001) | Psychomotor function-tapping (dominant); Psychomotor function-tapping (nondominant)
Neuromuscular
Ohtomi et al. (1996) | Accommodative spasm
Baker and Sedgwick (1996) | Reciprocal jitter after transformation; >55 µs jitter of muscle fiber pairs
Grob (1956) | Muscle cramp; generalized muscular fasciculations
Other
Grob (1956) | Speech difficulty
Miyaki et al. (2005) | Simple reaction time; Choice reaction time
Loh et al. (2010) | Grooved pegboard T-score; Visuoperceptual scores; seashore rhythm test; failure to maintain sets; trail making test T-scores; attention and executive function tests
Murata et al. (1997) | Event-related potential-P300 or N100 latency
Suzuki et al. (1997) | Stupor
Yokoyama et al. (1998c) | Continuous performance test; confusion; anger-hostility; vigor
Nishiwaki et al. (2001) | Simple reaction time
Okumura et al. (2005) | Subclinical neuropsychobehavioral effects
Sekijima et al. (1995) | Autonomic nervous system tests-CV(R-R)

Table F-7 Summary of Biochemical Endpoints in Animals

Brain Biochemical Endpoint | Abou-Donia et al. (2002) | Allon et al. (2011) | | Bhardwaj et al. (2012) | | Bielavska and Kassa (2000) | Bloch-Shilderman et al. (2005) | | Jones et al. (2000) | Lazar et al. (2016)
Brain Biochemical Endpoint | Rat, Sprague Dawley ♂ | Rat, Sprague Dawley ♂ | | Rat, Wistar ♀ | | Rat, Albino SPF ♂ | Rat, Sprague Dawley ♂ | | Rat, Sprague Dawley ♂ | Rat, Sprague Dawley ♂
Brain Biochemical Endpoint | 15 d. | 1 mo. | 6 mo. | 3 d. | 7 d. | 12 mo. | 120 hr. | 240 hr. | 90 d. | 48 hr.
Brain Biochemical Endpoint | 0, 50, 75, 90, 100 μg/kg | 0, 27.2 μg/L | | 0, 40, 80 μg/kg | | 0, 0.8, 1.25, 2.5 μg/L | 0, 90 mg/kg | | 0, 1, 10, 50, 100 μg/kg | 0, 80 μg/kg
Dopamine, Serotonin, and Their Metabolites
3,4-Dihydroxyphenylacetic acid (DOPAC) level | – | – | – | – | – | ↓ 0.8 μg/L | – | – | – | –
3-Methoxytyramine hydrochloride (3-MT) level | – | – | – | – | – | ↓ 0.8, 2.5 μg/L | – | – | – | –
5-Hydroxyindoleacetic acid (5-HIAA) level | – | – | – | – | – | ↑ ≥0.8 μg/L | – | – | – | –
Dopamine hydrochloride (DA) level | – | – | – | – | – | ↑ ≥1.25 μg/L | – | – | – | –
Homovanillic acid (HVA) level | – | – | – | – | – | ↓ 0.8 μg/L | – | – | – | –
Serotonin creatinine sulfate (5-HT) level | – | – | – | – | – | ↑ ≥0.8 μg/L | – | – | – | –
Binding Receptors
nAChR ligand binding (cortex) | – | – | – | – | – | – | – | – | ↓ ≥50 μg/kg | –
nAChR ligand binding (brainstem) | – | – | – | – | – | – | – | – | ↑ 100 μg/kg | –
M2 mAChR ligand binding (cortex) | NS | – | – | – | – | – | – | – | ↓ 100 μg/kg | –
M2 mAChR ligand binding (brainstem) | NS | – | – | – | – | – | – | – | ↑ 50 μg/kg | –
M2 receptor binding (Bmax) (striatum) | – | NS | ↑ 27.2 μg/L | – | – | – | – | – | – | –
M2 receptor binding (Bmax) (cortex) | – | NS | ↑ 27.2 μg/L | – | – | – | – | – | – | –
M2 receptor binding (kD) (striatum) | – | NS | ↑ 27.2 μg/L | – | – | – | – | – | – | –
M2 receptor binding (kD) (cortex) | – | ↑ 27.2 μg/L | ↑ 27.2 μg/L | – | – | – | – | – | – | –
Brain Function Markers
Apoptotic regulation (bax protein levels) (frontal cortex) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (bax protein levels) (parietal cortex) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (bax protein levels) (piriform cortex) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (bax protein levels) (hippocampus) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (bcl2 protein levels) (frontal cortex) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (bcl2 protein levels) (parietal cortex) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (bcl2 protein levels) (piriform cortex) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (bcl2 protein levels) (hippocampus) | – | – | – | – | – | – | – | – | – | ↓ (SIG UNK) 80 μg/kg
Apoptotic regulation (ERK1/2 enzymatic activity) (frontal cortex) | – | – | – | – | – | – | – | – | – | ↑ (SIG UNK) 80 μg/kg
Apoptotic regulation (ERK1/2 enzymatic activity) (parietal cortex) | – | – | – | – | – | – | – | – | – | ↑ (SIG UNK) 80 μg/kg
Apoptotic regulation (ERK1/2 enzymatic activity) (piriform cortex) | – | – | – | – | – | – | – | – | – | ↑ (SIG UNK) 80 μg/kg
Apoptotic regulation (ERK1/2 enzymatic activity) (hippocampus) | – | – | – | – | – | – | – | – | – | ↑ (SIG UNK) 80 μg/kg
Apoptotic regulation (JNK enzymatic activity) (frontal cortex) | – | – | – | – | – | – | – | – | – | ↑ (SIG UNK) 80 μg/kg
Apoptotic regulation (JNK enzymatic activity) (parietal cortex) | – | – | – | – | – | – | – | – | – | ↑ (SIG UNK) 80 μg/kg
Apoptotic regulation (JNK enzymatic activity) (piriform cortex) | – | – | – | – | – | – | – | – | – | no change
Apoptotic regulation (JNK enzymatic activity) (hippocampus) | – | – | – | – | – | – | – | – | – | no change
PGE2 levels | – | ↑ 27.2 μg/L | ↓ 27.2 μg/L | – | – | – | – | – | – | –
TSPO binding density | – | NS | NS | – | – | – | – | – | – | ↑ 80 μg/kg
Alterations of Protein Kinase C Isozymes
PKC beta II expression (cytosolic) (frontal cortex) | – | – | – | – | – | – | NS | NS | – | –
PKC beta II expression (cytosolic) (thalamus) | – | – | – | – | – | – | ↑ 90 mg/kg | ↑ 90 mg/kg | – | –
PKC beta II expression (cytosolic) (hippocampus) | – | – | – | – | – | – | ↑ 90 mg/kg | ↑ 90 mg/kg | – | –
PKC beta II expression (cytosolic) (striatum) | – | – | – | – | – | – | ↓ 90 mg/kg | NS | – | –
PKC beta II expression (membrane) (frontal cortex) | – | – | – | – | – | – | NS | NS | – | –
PKC beta II expression (membrane) (thalamus) | – | – | – | – | – | – | ↑ 90 mg/kg | ↑ 90 mg/kg | – | –
PKC beta II expression (membrane) (hippocampus) | – | – | – | – | – | – | ↑ 90 mg/kg | ↑ 90 mg/kg | – | –
PKC beta II expression (membrane) (striatum) | – | – | – | – | – | – | ↓ 90 mg/kg | NS | – | –
PKC zeta expression (cytosolic) (frontal cortex) | – | – | – | – | – | – | ↓ 90 mg/kg | ↓ 90 mg/kg | – | –
PKC zeta expression (cytosolic) (thalamus) | – | – | – | – | – | – | NS | ↑ 90 mg/kg | – | –
PKC zeta expression (cytosolic) (hippocampus) | – | – | – | – | – | – | ↑ 90 mg/kg | ↑ 90 mg/kg | – | –
PKC zeta expression (cytosolic) (striatum) | – | – | – | – | – | – | NS | NS | – | –
PKC zeta expression (membrane) (frontal cortex) | – | – | – | – | – | – | NS | NS | – | –
PKC zeta expression (membrane) (thalamus) | – | – | – | – | – | – | ↑ 90 mg/kg | ↑ 90 mg/kg | – | –
PKC zeta expression (membrane) (hippocampus) | – | – | – | – | – | – | ↑ 90 mg/kg | ↑ 90 mg/kg | – | –
PKC zeta expression (membrane) (striatum) | – | – | – | – | – | – | NS | NS | – | –
Cholinergic System
ChAT immunoreactivity (cortex) | – | – | – | ↓ ≥40 μg/kg | ↓ 80 μg/kg | – | – | – | – | –
ChAT immunoreactivity (cerebellum) | – | – | – | ↓ ≥40 μg/kg | NS | – | – | – | – | –
VAChT immunoreactivity (cortex) | – | – | – | NS | ↓ 80 μg/kg | – | – | – | – | –
VAChT immunoreactivity (cerebellum) | – | – | – | ↓ 40 μg/kg | ↓ 40 μg/kg | – | – | – | – | –
Other
Blood-brain barrier permeability (cortex) | – | – | – | – | – | – | – | – | NS | –
Blood-brain barrier permeability (midbrain) | – | – | – | – | – | – | – | – | NS | –
Blood-brain barrier permeability (brainstem) | – | – | – | – | – | – | – | – | ↓ 100 μg/kg | –
Blood-brain barrier permeability (cerebellum) | – | – | – | – | – | – | – | – | NS | –

↓↑ = statistically significant results.

↓↑ (SIG UNK) = a direction of effect, but significance is unknown/unclear.

NS = no statistically significant results.

Figure F-1

Number of Studies by Endpoint Category, Evidence Stream, and Time Period

Interactive figure and additional study details in Tableau (https://public.tableau.com/profile/ntp.visuals#!/vizhome/Sarin_StudyCounts/StudyCountSummary)^®^.