# Appendix E Inadequate Evidence: Evidence Synthesis and Risk-of-bias Assessment

## E.1 Sleep Disruption

Sleep disruption-related outcomes in humans included bad dreams, distressing dreams or nightmares, difficulty falling or staying asleep, insomnia, and sleep disturbance. Symptoms of sleep disruption were reported in the weeks to years following acute sarin exposure. In animals, no studies of sleep disruption-related effects were identified.

### E.1.1 Human Sleep Disruption Data

The available studies support a rating of very low confidence in the body of evidence that acute sarin exposure is associated with sleep disruption in humans over all time periods after the initial exposure. Six studies reporting on sleep disruption (including bad dreams, distressing dreams or nightmares, difficulty falling or staying asleep, insomnia, and sleep disturbance) after acute sarin exposure were identified, and all of the studies are from subjects following the Matsumoto terrorist attack or the Tokyo subway terrorist attack (Kawana et al. 2001; Nakajima et al. 1999; Nakajima et al. 1998; Ogawa et al. 1999; Ohbu et al. 1997; Ohtani et al. 2004). For the initial period covering 1–7 days following acute sarin exposure, no studies were available. Subjects from three case series studies report symptoms related to sleep disturbance 3 weeks to 4 months following acute sarin exposure (Nakajima et al. 1998; Ogawa et al. 1999; Ohbu et al. 1997). Subjects from three case series studies and one prospective cohort study report symptoms related to sleep disruption 1–5 years following acute sarin exposure (Kawana et al. 2001; Nakajima et al. 1999; Nakajima et al. 1998; Ohtani et al. 2004). There are serious limitations in the human body of evidence to evaluate the potential association between exposure to sarin and symptoms related to sleep disruption due to risk-of-bias concerns and uncertainties related to study design for case reports/series. The case reports/series that reported effects at the intermediate period of 8 days to 1 year had an initial confidence of low and were downgraded for serious risk-of-bias concerns to support a final rating of very low confidence in the body of evidence for the intermediate period. The initial confidence of moderate for the cohort study (Nakajima et al. 1999) was downgraded twice for serious risk-of-bias concerns (i.e., failure to control for PTSD as a confounder, potential biases in outcome assessment from self-reporting of symptoms via questionnaires, and loss of subjects over time) to support a final rating of very low confidence in the body of evidence for extended period following acute sarin exposure.

The available epidemiological studies in the human body of evidence that evaluated the association between acute exposure to sarin and long-term effects on sleep were based on two terror attacks—the 1994 Matsumoto sarin attack and 1995 Tokyo subway sarin attack—and a subset of these studies followed only some of the victims over time. There is no human evidence to evaluate the potential association between sarin exposure and effects on sleep days following exposure; therefore, there is inadequate evidence in the initial days after exposure.

Three studies are available that observed sleep disruption in subjects <1 year after sarin exposure (Nakajima et al. 1998; Ogawa et al. 1999; Ohbu et al. 1997). At 1 month following the Tokyo subway sarin attack, Ohbu et al. (1997) reported that 137 of 475 hospital patients (29%) described symptoms of sleep disturbance and 48 of 475 hospital patients (10%) reported nightmares. The authors did not report on these symptoms specifically at 3 and 6 months following exposure but noted that almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of post-traumatic stress disorders (PTSD), 1 month after the incident. This percentage remained almost the same even 3 and 6 months after the incident.” Insomnia was self-reported in 25 (3.7%) of 681 victims of the Tokyo subway attack surveyed 2 months after exposure (Ogawa et al. 1999). Nakajima et al. (1998) reported that 2 (<1%) of 1,743 subjects surveyed, who were inhabitants living in one of nine town districts closest to the Matsumoto attack, reported insomnia 3 weeks following the Matsumoto attack. Four of the 105 subjects surveyed at 4 months continued to report insomnia.

Four studies are available that observed sleep disruption in subjects 1–5 years after sarin exposure (Kawana et al. 2001; Nakajima et al. 1999; Nakajima et al. 1998; Ohtani et al. 2004). At 1 year following sarin exposure, Nakajima et al. (1998) reported that 3 of 45 surveyed subjects continued to experience insomnia and two of 45 subjects were experiencing bad dreams. Although bad dreams were included in the questionnaire at 1 year, they were excluded from the questionnaires at 3 weeks and 4 months. Nakajima et al. (1999) reported that 8 (<1%) of 1237 surveyed participants experienced insomnia and 6 (<1%) of 1237 surveyed participants experienced bad dreams at 1 year following the Matsumoto attack. Nakajima et al. (1999) compared victims of the attack who were admitted to the hospital to victims who were outpatients or nonpatients and did not observe any significant difference in the risk for both insomnia and bad dreams in the victims initially admitted to the hospital versus outpatients at 1 year after the exposure. At 3 years post-exposure, Nakajima et al. (1999) reported that no differences were found in the symptoms of those with bad dreams or insomnia between nonvictims and victims. Kawana et al. (2001) followed victims of the Tokyo sarin attack and reported on psychological effects, including distressing dreams or nightmares and difficulty falling or staying asleep, at 2 years (1997), 3 years (1998), and 5 years (2000) after sarin exposure. The authors then compared these symptoms of the Tokyo sarin attack victims to victims of the Matsumoto sarin attack. Distressing dreams or nightmares were reported by 26 (9.2%) of 283 victims in 1997, 19 (9.2%) of 206 victims in 1998, and 11 (5.8%) of 191 victims in 2000. In 2000, Matsumoto victims and Matsumoto controls experienced distressing dreams or nightmares at 10.3% and 2.3%, respectively. Difficulty falling or staying asleep were reported by 21 (7.4%) of 283 victims in 1997, 18 (8.7%) of 206 victims in 1998, and 15 (7.9%) of 191 victims in 2000. In 2000, Matsumoto victims and Matsumoto controls experienced difficulty falling or staying asleep at 11.4% and 6.8%, respectively. Ohtani et al. (2004) examined post-traumatic stress disorder symptoms 5 years after the Tokyo attack and reported that nine of 34 victims surveyed reported nightmares (eight mild and one severe) and 10 of 34 victims reported insomnia (seven mild and three severe).

Confidence in the body of evidence for the human studies was downgraded because of serious concern for risk of bias. Risk-of-bias ratings for individual studies for all questions are available in Figure E-1 and Figure E-2. There are a number of risk-of-bias issues in the evidence relating to design and conduct of individual studies, as well as general limitations (i.e., not risk-of-bias issues) based on the case report/series study design. Almost all studies were rated as probably high or definitely high risk of bias for two of the three key questions (i.e., confounding and outcome assessment). Two of the six studies addressed potential confounders that may have been associated with the symptoms reported. Nakajima et al. (1999) was the only study that calculated odds ratios. All outcomes were self-reported, and all the subjects were aware of their exposure making the outcomes likely to be biased. The Nakajima et al. (1999) study included a question regarding exposure on its survey making it even more likely that the subjects were aware of the connection between exposure and symptoms. All but one study experienced attrition with only a small subset of the subjects followed through the different time points; some studies included as few as 34 of hundreds of potential subjects. This might bias the results because it is likely that only those who were concerned about exposure continued to participate in the studies.

### E.1.2 Animal Sleep Disruption Data

No animal studies were identified on the potential association between acute sarin exposure and sleep disruption.

### E.1.3 Integration of Evidence for Sleep Disruption-related Outcomes

There is some evidence to suggest that acute sarin exposure is associated with sleep disruption-related effects that can last for a long time after exposure; however, there is also some evidence that symptoms of sleep disruption may be an indication of psychological aftereffects of a terrorist attack or post-traumatic stress disorder. There is very low confidence in the human body of evidence that acute sarin exposure will cause long-term effects on sleep based mainly on concerns about risk of bias. The very low confidence in the human body of evidence translates into an inadequate level of evidence. There is no animal evidence to evaluate the potential association between acute exposure to sarin and sleep disruption. An evidence profile or detailed discussions of the evidence synthesis were not developed because of the limitations of the bodies of evidence for acute sarin and sleep disruption-related outcomes, and this health effect was not considered for hazard identification conclusions.

Figure E-1

Risk-of-bias Heat Map for Case Reports/Series and Standard Observational Studies Assessing Sleep Disruption in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in Health Assessment Workspace Collaborative (HAWC) (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-2

Risk-of-bias Bar Graph for Case Reports/Series and Standard Observational Studies Assessing Sleep Disruption in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## E.2 Anxiety and Fear

Endpoints related to anxiety and fear were grouped together because anxiety and fear can be related. Anxiety was measured in humans using anxiety tests scores, and fear was assessed through self-reported symptoms by study subjects who experienced a terrorist attack. In animals, anxiety and fear were measured using FOB scores for bizarre behavior, tension, tremors, urination, defecation, and vocalizations. Many studies specifically evaluated PTSD. This document does not specifically evaluate PTSD, even in terms of anxiety and fear, because of the inability to separate the effects of the traumatic event (i.e., terrorist attack) from the effects related to exposure to sarin during the attack.

### E.2.1 Human Anxiety and Fear Data

The available studies support a rating of very low confidence in the body of evidence that acute sarin exposure affects anxiety and fear in humans over all time periods after the initial exposure. All of the data on fear are based on symptoms reported by study subjects following the Tokyo subway terrorist attack (Kawana et al. 2001; Ohbu et al. 1997; Ohtani et al. 2004; Okumura et al. 2005), including fear in the subway or at the incident, fear concerning escape from the attack, or shaking with fear. For the initial period covering 1–7 days following acute sarin exposure, no studies were available. Subjects from one case series study report symptoms related to anxiety and fear 1 month following acute sarin exposure (Ohbu et al. 1997), and subjects from three case series studies report symptoms related to anxiety and fear 1–5 years following acute sarin exposure (Kawana et al. 2001; Ohtani et al. 2004; Okumura et al. 2005). Three studies evaluated anxiety (Tochigi et al. 2005; Tochigi et al. 2002; Yokoyama et al. 1998c). There are serious limitations in the human body of evidence to evaluate the potential association between exposure to sarin and symptoms related to anxiety and fear. Initial confidence in the evidence is moderate for cross-sectional studies and low for the case series based on study design and was downgraded twice for serious risk-of-bias concerns and uncertainties related to study design and exposure. Subjects in the case series studies also self-reported their symptoms and were aware of their exposure. Moreover, these studies do not attempt to differentiate the association between symptoms related to anxiety and fear and acute sarin exposure and symptoms related to anxiety and fear and the experience of a traumatic event (i.e., a terrorist attack) with questions based more on fear of the subway or escape. The data available support a rating of very low confidence in the body of evidence for all time periods after the initial exposure.

The available epidemiological studies in the human body of evidence that evaluated the association between acute exposure to sarin and long-term effects on anxiety and fear were all based on two terror attacks and followed some of the victims over time. No studies were identified that specifically evaluated symptoms related to anxiety and fear in the days following exposure. Ohbu et al. (1997) reported that 152 (32%) of 475 hospital patients experienced fear of using the subway, some of whom could still not use the subway, 1 month following the exposure. One year after the Tokyo attack, 39 (12.9%) of 303 subjects surveyed reported fear of the subway, and 35 (11.6%) of 303 subjects surveyed reported fear concerning escape from the attack (Okumura et al. 2005). Kawana et al. (2001) reported that 25 (8.8%) of 283 hospital patients, 18 (8.7%) of 206 hospital patients, and 21 (11.0%) of 191 hospital patients experienced fear in the subway or at the incident 2, 3, and 5 years following the exposure, respectively. Kawana et al. (2001) also reported that 151 (23.1%) of 655 victims of the Tokyo subway attack studied by an NGO, 7 (7.9%) of 88 victims of the 1994 Matsumoto sarin attack, and 2 (2.3%) of 87 members of a control group from Matsumoto self-reported fear in the subway or at the incident 5 years after the exposure. Ohtani et al. (2004) reported that 5 years after the Tokyo attack, 5 (14.7%) of 34 subjects surveyed reported mild shaking with fear. These symptoms related to anxiety and fear were not assessed at any other time points, and no other health endpoints related to anxiety and fear were included in study questionnaires following the terrorist attacks. Yokoyama et al. (1998c) did not find any significant difference in the tension-anxiety profile of mode states scores in 18 subjects 6–8 months after the Tokyo subway attack compared to 15 controls. Tochigi et al. (2005) evaluated state and trait anxiety, but did not really make comparisons between the Tokyo subway victims and the controls and appears to be a follow-up of the Tochigi et al. (2002) study. Tochigi et al. (2002) compared the state anxiety scores in 34 Tokyo subway victims compared to 34 controls 5 years after exposure. There was no significant difference between the groups unless the subjects identified to have PTSD were separated out and in those subjects the state anxiety score was increased.

Confidence in the body of evidence for the human studies was downgraded because of serious concern for risk of bias. Risk-of-bias ratings for individual studies for all questions are available in Figure E-3 through Figure E-6. There are a number of risk-of-bias issues in the evidence relating to design and conduct of individual studies, as well as general limitations (i.e., not risk-of-bias issues) based on the case report/series study design. Nearly all studies were rated as probably high risk of bias for two of the three key questions (i.e., confounding and outcome assessment). All outcomes were self-reported, and all the subjects were aware of their exposure making the outcomes likely to be biased. The case series studies also had probably high risk of bias due to challenges with confounding and/or attrition. None of the studies addressed potential confounders that may have been associated with the symptoms reported. For Kawana et al. (2001), of the 582 St. Luke patients contacted, 283 (48.6%) responded in 1997, 206 (35.3%) responded in 1998, and 191 (32.8%) responded in 2000. While the mean age and sex of the subjects over the different times were reported and were similar, there was no comparison made between those lost to follow-up and those remaining in the study. This might bias the results because it is likely that only those who were concerned about exposure continued to participate in the study. For Ohtani et al. (2004),Tochigi et al. (2002), and Yokoyama et al. (1998c), only 18–34 of the hundreds of potential victims participated in the study. No information was provided on the subjects who participated compared with those who did not. Moreover, none of the studies included in the body of evidence were designed to assess symptoms related to anxiety and fear associated with acute sarin exposure separately from anxiety and fear associated with the experience of a traumatic event. Most of the questions included in questionnaires regarding anxiety and fear were tailored toward assessing fear related with the experience of the terrorist attack (e.g., fear of subway), which increases the likelihood that the reported incidence of anxiety and fear in the body of evidence is more if not mostly related to the experience of a traumatic event and not the sarin exposure alone. Studies that did conduct anxiety tests, only found significant anxiety in subjects who had PTSD.

### E.2.2 Animal Anxiety and Fear Data

There is low confidence in the body of evidence that acute sarin exposure affects long-term anxiety and fear in animals because of heterogeneity across endpoints studied and very serious risk-of-bias concerns. Although initial confidence in the animal data is high, confidence in the body of evidence was downgraded twice for very serious concerns for risk of bias. Health endpoints related to anxiety and fear in animal studies included FOB scores for bizarre behavior, tension, tremors, urination, defecation, and vocalizations. No studies were identified that specifically evaluated these outcomes in the days to weeks following exposure. Kassa et al. (2001c) observed no effect in FOB scores for tension, tremors, and vocalizations in male albino Wistar rats 3 months after inhalation exposure to sarin (0.8–2.5 μg/L). Kassa et al. (2001a) also observed no effects in FOB scores for bizarre behavior, tension, tremors, or vocalizations in male albino SPF rats 6 months and 12 months after inhalation exposure to sarin (0.8–2.5 μg/L). Although Kassa et al. (2001a) observed no statistically significant effects in FOB scores for urination and defecation at 3 months, 6 months, and 12 months, FOB scores for urination and defecation had large variations with more than 15% score difference (in both directions) at all doses at 3 months, 6 months, and 12 months following sarin exposure.

There were multiple risk-of-bias concerns to support a very serious risk-of-bias rating for the animal body of evidence related to anxiety and fear. The studies in general were rated as probably high risk of bias for the three key questions (randomization, exposure characterization, and outcome assessment) (see Figure E-7 and Figure E-8). Kassa et al. did respond to correspondence requesting information on randomization and noted that animals in their studies were not randomized to treatment. Both Kassa et al. studies (2001a; 2001c) administered sarin via inhalation, but none reported measuring exposure concentrations in the chambers. Correspondence with the study authors indicated that sarin concentrations in the chambers were measured, but no results were available and were only reported based on ChE depression and/or clinical symptoms. In the assessment of outcomes, none of the outcomes were measured blind and all of these studies used FOB scores to describe anxiety and fear, which increases the risk of bias due to the subjective nature of the outcome.

### E.2.3 Integration of Evidence for Anxiety and Fear-related Outcomes

There is some human evidence to evaluate the potential association between acute exposure to sarin and increased anxiety and fear months to years after exposure; however, no epidemiological studies were identified that assessed anxiety and fear associated with acute sarin exposure separately from anxiety and fear associated with the experience of a traumatic event (i.e., a terrorist attack). There is no evidence of an association between acute sarin exposure and anxiety and fear in animals 3 months to 12 months following exposure. There is very low confidence in the human body of evidence and low confidence in the animal body of evidence that acute sarin exposure will cause long-term effects on anxiety and fear based mainly on concerns about risk of bias. The very low confidence in the human body of evidence translates into an inadequate level of evidence, and the low confidence in the animal data translates into a low level of evidence. Therefore, an evidence profile or detailed discussions of the evidence synthesis were not developed for acute sarin exposure and anxiety and fear-related outcomes, and this health effect was not considered for hazard identification conclusions.

Figure E-3

Risk-of-bias Heat Map for Standard Observational Studies Assessing Anxiety in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-4

Risk-of-bias Bar Graph for Standard Observational Studies Assessing Anxiety in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-5

Risk-of-bias Heat Map for Case Series Assessing Fear in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-6

Risk-of-bias Bar Graph for Case Series Assessing Fear in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-7

Risk-of-bias Heat Map for Individual Studies Assessing Anxiety and Fear in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-8

Risk-of-bias Bar Graph for Individual Studies Assessing Anxiety and Fear in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## E.3 Avoidance and Depression

Avoidance is described as behavior intended to avoid thoughts, discussion, or physical locations that trigger recollections of the trauma. Depression included depressed mood/feelings, diminished interest with numbing or apathy. Symptoms of avoidance and depression were self-reported via questionnaire or recorded by a clinician as part of an evaluation of PTSD.

### E.3.1 Human Avoidance and Depression Data

The available studies support a rating of very low confidence in the body of evidence that acute sarin exposure is associated with avoidance and depression in humans over all time periods after the initial exposure. The human body of evidence consists of four case series, all of which evaluated victims of the Tokyo subway system sarin attack that occurred in 1995 (Kawana et al. 2001; Ohbu et al. 1997; Ohtani et al. 2004; Okumura et al. 2005) and one cross-sectional study on the Tokyo subway attack (Yokoyama et al. 1998c). For the initial period covering 1–7 days following acute sarin exposure, no studies were available. One case series reported symptoms of depression (depressive mood) 1 month after acute sarin exposure (Ohbu et al. 1997). One cross-sectional study evaluated depression in profile of mood states 6–8 months after exposure (Yokoyama et al. 1998c) and subjects from three case series studies report symptoms related to avoidance and depression 1–5 years following acute sarin exposure (Kawana et al. 2001; Ohtani et al. 2004; Okumura et al. 2005). There are serious limitations in the human body of evidence that evaluates the potential association between exposure to sarin and symptoms related to avoidance and depression. Initial confidence in the evidence is low for the case series based on study design and was downgraded once for serious risk-of-bias concerns. Symptoms were either self-reported and subjects were aware of their exposure or recorded by a clinician as part of criteria used to evaluate PTSD. None of these studies attempted to differentiate the cause of the reported symptoms of avoidance and depression (i.e., as due to acute sarin exposure or trauma resulting from a terrorist attack). Consequently, there is very low confidence in the body of evidence for all time periods.

The available epidemiological studies in the human body of evidence that evaluated the association between acute exposure to sarin and long-term effects on avoidance and depression were based on the Tokyo attack and followed some of the victims over time. None of the studies evaluated symptoms of avoidance and depression in the days following exposure. One case series reported symptoms of depression (depressive mood) in 74 (16%) of 475 hospital patients, 1 month after exposure (Ohbu et al. 1997). The authors noted effects at 3 and 6 months by stating that almost 60% of respondents still suffered from some post-incident symptoms, which can be indication of PTSD, 1 month after the incident. This percentage remained almost the same even 3 and 6 months after the incident. Profiles of mood states scores for depression were not significantly different (p = 0.07) in 18 subjects from the Tokyo subway attack compared to 15 control subjects 6–8 months after exposure (Yokoyama et al. 1998c). At 1 year following exposure depressive feelings were reported by 24 of 303 (7.9%) exposed subjects (Okumura et al. 2005). Two years after the attack depressed mood was reported in 42 of 283 (14.8%) patients; this decreased significantly 1 year later to 9.7% (Kawana et al. 2001). Subjects reporting diminished interest, numbing (a symptom of depression) also decreased after 2 years from 18/283 (6.4%) to 9/206 (4.4%) and 11/191 (5.8%), 3 and 5 years following exposure, respectively (Kawana et al. 2001). Avoidance of places that trigger recollections of the trauma was reported slightly less frequently at 3 years (29/206; 14.1%) after exposure compared with 2 years (42/283; 14.8%); after 5 years the frequency (30/191; 15.7%) was comparable to that at 3 years (Kawana et al. 2001). At 5 years following exposure 16 of 34 (47.1%) subjects self-reported avoidance behavior of places that trigger recollections of the trauma, whereas 11/34 reported avoidance of thoughts and conversations associated with trauma (Ohtani et al. 2004). Signs of depression (diminished interest and apathy) were reported by 9/34 subjects (Ohtani et al. 2004). All four studies sampled from the same cohort (i.e., a total of 641 patients that were treated at St. Luke’s International Hospital following the Tokyo subway attack).

Confidence in the body of evidence for the human studies was downgraded because of serious concern for risk of bias. Risk-of-bias ratings for individual studies for all questions are available in Figure E-9 and Figure E-10. There are a number of risk-of-bias issues in the evidence that relate to design and conduct of individual studies, as well as general limitations (i.e., not risk-of-bias issues), based on the case report/series study design. Nearly all studies were rated as probably high or risk of bias for two of the three key questions (i.e., confounding and outcome assessment). Outcomes were predominantly self-reported, and all the subjects were aware of their exposure, which increases the likelihood of bias in the results. The case series studies probably also had a high risk of bias due to challenges with confounding and/or attrition. None of the studies addressed potential confounders that may have been associated with the symptoms that were reported. For Kawana et al. (2001), of the 582 St. Luke patients contacted, 283 (48.6%), 206 (35.3%) and 191 (32.8%) responded in 1997, 1998, and 2000, respectively. While the reported mean age and sex of the subjects over the different times were similar, there was no comparison made between those lost to follow-up and those remaining in the study. This might bias the results because it is likely that only those who were concerned about exposure continued to participate in the study. For Ohtani et al. (2004), only 34 of the same cohort of potential victims participated in the study. No information was provided on the subjects who participated compared to those who did not. Moreover, none of the studies included in the body of evidence were designed to differentiate between symptoms of avoidance and depression as a result of the long-term biological effect of acute exposure to sarin rather than as a result of the experience of a traumatic event, which could be related to PTSD. In fact, two of the studies [Kawana et al. (2001) and Ohtani et al. (2004)]considered symptoms of avoidance and depression as signs of PTSD. Ohtani et al. (2004) found that 32.4% of the subjects examined in their study developed PTSD over the 5 years following the attack; the authors noted that this high prevalence was likely caused by bias in the subject selection. In summary, reported symptoms of avoidance and depression in the human body of evidence could be equally related to the experience of a traumatic event or to the sarin exposure.

### E.3.2 Animal Avoidance and Depression Data

No animal studies were identified on the potential association between acute sarin exposure and avoidance and depression.

### E.3.3 Integration of Evidence for Avoidance and Depression-related Outcomes

There is limited human evidence available to evaluate the potential association between acute exposure to sarin and increased avoidance behavior and depression months to years after exposure. Furthermore, two of the four epidemiological studies assessed these symptoms within the wider context of evaluating prevalence of PTSD. No studies were identified that evaluated avoidance behavior and depression in animals acutely exposed to sarin. There is very low confidence in the human body of evidence that acute sarin exposure causes long-term effects on avoidance behavior and depression based mainly on concerns about risk of bias. The very low confidence in the human body of evidence translates into an inadequate level of evidence and as such, an evidence profile or detailed discussion of the evidence synthesis was not developed for acute sarin exposure and avoidance and depression-related outcomes. This health effect was not considered for hazard identification conclusions.

Figure E-9

Risk-of-bias Heat Map for Case Series and Standard Observational Studies Assessing Avoidance and Depression in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-10

Risk-of-bias Bar Chart for Case Series and Standard Observational Studies Assessing Avoidance and Depression in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## E.4 Activity and Strength

Similar endpoints on activity and strength were grouped together due to their close relationship, such that reduced strength can result in reduced activity and reduced activity can result in reduced strength (Germain et al. 2016; Leblanc et al. 2015). Activity was not specifically measured in humans, but endpoints considered included asthenia, fatigue or tiredness, lethargy, and general weakness. In animals, activity and strength were measured using several different endpoints, including beam walking, grip strength, hand-eye coordination, incline plane slip angle, spontaneous activity, field activity, and FOB activity scores.

### E.4.1 Human Activity and Strength Data

The available studies support a rating of very low confidence in the body of evidence that acute sarin exposure affects activity and strength in humans over all time periods after the initial exposure. Most of the data on health endpoints related to activity and strength (including asthenia, fatigue or tiredness, lethargy, and general weakness) are based on symptoms reported by study subjects following the Matsumoto terrorist attack or the Tokyo subway terrorist attack (Nakajima et al. 1999; Nakajima et al. 1998; Ogawa et al. 1999; Ohtani et al. 2004; Okudera 2002; Okumura et al. 2005). For the initial period covering 1–7 days following acute sarin exposure, no studies were available. Subjects from four case series studies report symptoms related to activity and strength 3 weeks to 4 months following acute sarin exposure (Morita et al. 1995; Nakajima et al. 1998; Ogawa et al. 1999; Okudera 2002). One cross-sectional study reported on profile of state mood scores related to fatigue 6–8 months following acute sarin exposure in 18 subjects from the Tokyo subway compared to 15 controls (Yokoyama et al. 1998a; Yokoyama et al. 1998c). Subjects from four case series studies and one prospective cohort study report symptoms related to activity and strength 1–5 years following acute sarin exposure (Nakajima et al. 1999; Nakajima et al. 1998; Ohtani et al. 2004; Okudera 2002; Okumura et al. 2005). There are serious limitations in the human body of evidence to evaluate the potential association between exposure to sarin and symptoms related to activity and strength. In the intermediate period of 8 days to 1 year following acute exposure, the cross-sectional study (Yokoyama et al. 1998a; Yokoyama et al. 1998c) had an initial and final confidence rating of moderate; however, no statistically significant effects were observed, and therefore the body of evidence is considered inadequate to evaluate whether sarin exposure affects long-term activity and strength in humans. The body of evidence in the intermediate period also consists of four case series with an initial confidence of low, which was downgraded once for risk-of-bias concerns. In the extended period of 1–5 years following exposure, the initial confidence of moderate for the cohort study (Nakajima et al. 1999) was downgraded twice for serious risk-of-bias concerns (i.e., failure to control for PTSD or PTSD-related effects [e.g., sleep disruption] as confounders, potential biases in outcome assessment from self-reporting of symptoms via questionnaires, and loss of subjects over time). The remaining case reports/series that reported effects in the extended period had an initial confidence of low, which was downgraded once for risk-of-bias concerns due to the self-reporting of symptoms and participants’ awareness of their exposure. The available data support a rating of very low confidence in the body of evidence for all time periods after the initial exposure.

The available epidemiological studies in the human body of evidence that evaluated the association between acute exposure to sarin and long-term effects on activity and strength were all based on two terror attacks and followed some of the victims over time. Nakajima et al. (1998) reported that 39 (2.2%) of the 1,743 subjects surveyed, who were inhabitants living in one of nine town districts closest to the Matsumoto attack, reported fatigue within the first 24 hours following the attack, of which 17 subjects (<1%) continued to report fatigue 3 weeks following the Matsumoto attack. Two of the 105 subjects surveyed at 4 months continued to report fatigue (Nakajima et al. 1998). Easy fatigue was also reported during an examination 3 weeks following the Matsumoto attack in 12 (7.7%) of the 155 subjects examined (Morita et al. 1995; Okudera 2002). Generalized weakness was self-reported in 36 (5.3%) of the 681 victims of the Tokyo subway attack surveyed 2 months after exposure (Ogawa et al. 1999). Profiles of mood state scores for fatigue was not significantly different between 18 Tokyo subway victims 6–8 months after exposure compared with controls (Yokoyama et al. 1998a; Yokoyama et al. 1998c). Asthenia and fatigue were reported 1–3 years following the Matsumoto attack (Nakajima et al. 1999; Nakajima et al. 1998; Okudera 2002). Nakajima et al. (1999) compared victims of the attack who were admitted to the hospital to victims who were outpatients or nonpatients and observed a significant increase in the risk for both asthenia and fatigue symptoms in the victims initially admitted to the hospital versus outpatients at 1 year after the exposure. Three years post-exposure, Nakajima et al. (1999) reported that fatigue was significantly greater in victims of the attack compared with nonvictims. One year after the Tokyo attack, 36 (11.9%) of 303 subjects surveyed reported being easily fatigued (Okumura et al. 2005). Five years after the Tokyo attack, 12 of 34 subjects surveyed reported mild tiredness and lethargy and 14 of 34 subjects reported being easily fatigued (eight mild and six severe) (Ohtani et al. 2004). These activity and strength-related health endpoints were not assessed at any other time points, and no other health endpoints related to activity and strength were included in study questionnaires following the terrorist attacks.

Confidence in the body of evidence for the human studies was downgraded because of serious concern for risk of bias. Risk-of-bias ratings for individual studies for all questions are available in Figure E-11 and Figure E-12. There are a number of risk-of-bias issues in the evidence relating to design and conduct of individual studies, as well as general limitations (i.e., not risk-of-bias issues) based on the case report/series study design. Almost all studies were rated as probably high or definitely high risk of bias for two of the three key questions (i.e., confounding and outcome assessment). Only one of the studies addressed potential confounders that may have been associated with the symptoms reported. Nakajima et al. (1999) was the only study that calculated odds ratios. All outcomes were self-reported, and all the subjects were aware of their exposure making the outcomes likely to be biased. The Nakajima et al. (1999) study included a question regarding exposure on its questionnaire making it even more likely that the subjects were aware of the connection between exposure and symptoms. Although exposure assessment was rated probably low risk of bias because subjects were recognized to be exposed, few studies evaluated exposure in terms of proximity to the release or admittance to the hospital following exposure, and most of studies did not consider these factors when evaluating symptoms reported years later. All studies experienced attrition with only a small subset of the subjects followed through the different time points; some studies included as few as 34 of hundreds of potential subjects. This might bias the results because it is likely that only those who were concerned about exposure continued to participate in the studies.

### E.4.2 Animal Activity and Strength Data

There is low confidence in the body of evidence that acute sarin exposure affects long-term activity and strength in animals because of heterogeneity across endpoints studied and very serious risk-of-bias concerns. Although initial confidence in the animal data is high, confidence in the body of evidence was downgraded twice for very serious concerns for risk of bias. Health endpoints related to activity and strength in animal studies included beam walking, grip strength, hand-eye coordination, incline plane slip angle, spontaneous activity, field activity, and FOB activity scores. The studies used different doses, species, and routes of exposure and effects were measured at various times points after exposure, leading to inconsistencies in the data. Wolthuis et al. (1995) observed a decrease in hand-eye coordination in a single marmoset monkey (only one was tested) 2–4 days after an intramuscular sarin injection (12 μg/kg). Abou-Donia et al. (2002) observed a decrease in grip strength and beam walk score and an increase in beam walk time in male Sprague Dawley rats at 7 and 15 days after intramuscular injection of sarin (100 μg/kg). A decrease in spontaneous activity was observed in mice 4 days after an intravenous exposure to sarin [80 μg/kg; (Little et al. 1986)], but open field activity was increased in male Sprague Dawley rats through 6 months after inhalation exposure to sarin [27.2–34.2 μg/L; (Allon et al. 2011; Grauer et al. 2008)]. Grauer et al. (2008) also noted some changes in speed performance for sarin-exposed rats in a water maze test that were stated to correspond with the increased activity observed. Kassa et al. studies (2001a; 2004; 2001c) observed alterations in gait, mobility, and other activity FOB scores at 3 months following sarin exposure, but not at 6 or 12 months or in FOB strength scores at 3, 6, or 12 months [outcomes assessed in all three studies at 3 months but only in Kassa et al. (2001a) at 6 and 12 months]. There were no other studies with activity FOB scores for comparison.

There were multiple risk-of-bias concerns to support a very serious risk-of-bias rating for the animal body of evidence related to activity and strength. The studies in general were rated as probably high risk of bias for the three key questions (randomization, exposure characterization, and blinding at outcome assessment) (see Figure E-13 and Figure E-14). The Grauer et al. (2008) study was the only study in which animals were known to be randomized to treatment. None of the other studies reported randomization nor did most authors respond to correspondence requesting information on randomization. Kassa et al. did respond and noted that animals in their studies were not randomized to treatment. Only one study was known to use sarin of sufficient purity (99%) (Wolthuis et al. 1995); however, this study had other risk-of-bias concerns because the five animals used in the visual discrimination test had been trained on hand-eye coordination and had been injected once at least 2 months prior with another ChE inhibitor (stated to be highly reversible). The authors did not state into which treatment groups these animals were placed, but this indicates that the experimental conditions were not the same for all animals. All the Kassa et al. studies (2001a; 2004; 2001c) administered sarin via inhalation, but none reported measuring exposure concentrations in the chambers. Correspondence with the study authors indicated that sarin concentrations in the chambers were measured, but no results were available and were only reported as based on ChE depression and/or clinical symptoms. In the assessment of outcomes, Abou-Donia et al. (2002) specified that outcomes were conducted blind, and Little et al. (1986) measured activity using an instrument that measured beam interruption, lowering the risk-of-bias potential. For the Kassa et al. studies (2001a; 2004; 2001c), none of the outcomes were measured blind and all of these studies used subjective FOB scores to describe activity and strength, which increases the potential for risk of bias. The remaining studies did not provide information on blinding, but appear to have used either automated tests or a video tracking system (Allon et al. 2011; Grauer et al. 2008; Wolthuis et al. 1995). Allon et al. (2011) and Grauer et al. (2008) did not use standard methods in the maze test, and the methods used had potential for bias. Abou-Donia et al. (2002) had definitely high risk of bias due to attrition and lack of reporting results for tests stated to have been measured (i.e., reflexes).

### E.4.3 Integration of Evidence for Activity and Strength-related Outcomes

There is some evidence that activity and strength are decreased after acute sarin exposure and can last for a long time after exposure; however, there is very low confidence in the human body of evidence and low confidence in the animal body of evidence that acute sarin exposure will cause long-term effects on activity and strength based mainly on concerns about risk of bias. The very low confidence in the human body of evidence translates into an inadequate level of evidence, and the low confidence in the animal data translates into a low level of evidence. Therefore, an evidence profile or detailed discussions of the evidence synthesis were not developed for acute sarin and activity and strength-related outcomes, and this health effect was not considered for hazard identification conclusions.

Figure E-11

Risk-of-bias Heat Map for Case Reports/Series and Standard Observational Studies Assessing Activity and Strength in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-12

Risk-of-bias Bar Chart for Case Reports/Series and Standard Observational Studies Assessing Activity and Strength in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-13

Risk-of-bias Heat Map for Individual Studies Assessing Activity and Strength in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-14

Risk-of-bias Bar Chart for Individual Studies Assessing Activity and Strength in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## E.5 Other Neurological Symptoms

During the two terrorist attacks in Matsumoto and the Tokyo subway, hundreds of individuals were exposed to sarin. Several studies evaluated symptoms in subjects involved in these incidents for up to 5 years after the events, mostly via questionnaire. In some of these studies that evaluated symptoms over time, a symptom was added to a follow-up questionnaire because it was reported previously by some subjects. In these instances, some symptoms may not have been captured early on but only at a later time point, thus influencing the results. Many of the reported symptoms have been discussed in the main document—such as visual and ocular effects—or in other sections of this appendix. The current section focuses on reported symptoms that cannot be grouped into larger categories (see Table F-1). Although some of the symptoms were reported by subjects up to 5 years after the exposure, there are serious limitations in the body of evidence. The same limitations apply to other neurological symptoms discussed in this appendix. Neurological symptoms were generally evaluated as part of a case series or case report without any comparison group, with the exception of Nakajima et al. (1999), who conducted a prospective cohort study 1 and 3 years after the Matsumoto attack. At 1 year, Nakajima et al. (1999) compared nonpatients, outpatients, and admitted patients, but the exposure status was based on self-reported muscarinic and/or nicotinic symptoms that occurred within a day of the attack and self-reported hospitalization, which were reported as part of the questionnaire during the 1-year survey. The exposure status (i.e., victims and nonvictims) of the subjects during the survey at 3 years following the exposure was based also on self-reported muscarinic and/or nicotinic symptoms that occurred within a day of the attack, but there is no indication that the exposure status was the same in the subjects during both surveys. Additional concerns were that the questionnaires changed over time; attrition because of losses to follow-up and in some cases due to subjects being excluded from follow-up surveys once they no longer experienced symptoms; and self-reporting of symptoms by subjects who were aware of their exposure (although only a few studies noted that they asked about the exposure and health effects in the same questionnaire). There were no tests to correlate sarin exposure to symptoms and no controls were included for comparison.

The numbers of symptoms included in the questionnaires are too numerous to list or discuss separately. Many of the symptoms occurred in the initial few days but subsided within the first few weeks of exposure. Only potential neurological symptoms are discussed in this document, but many reported symptoms were related to other systems (e.g., digestive and cardiovascular effects). Headache was a symptom included in many of the studies (Kawana et al. 2001; Loh et al. 2010; Morita et al. 1995; Nakajima et al. 1999; Nakajima et al. 1998; Ogawa et al. 1999; Ohtani et al. 2004; Ohtomi et al. 1996; Okudera 2002; Okumura et al. 2005). Although headache is a common occurrence and may be hard to relate to a specific exposure, Ohtomi et al. (1996) observed a decrease in the number of subjects who reported headache over time; 40 of the 62 subjects evaluated in the study reported headache on the day of the Tokyo subway attack, whereas only four reported headache 3 months later. Okumura et al. (2005) found a similar effect in a larger group (316 of 627 reported headache at admission and 26 of 303 reported headache after 1 year). In a small subset of subjects (n = 34) from the Tokyo subway attack, 16 reported headache after 5 years (Ohtani et al. 2004). Fewer subjects reported headache in the weeks following the Matsumoto attack (i.e., 2–4 subjects at 3 weeks) (Morita et al. 1995; Nakajima et al. 1998; Okudera 2002). Other symptoms were also reported to last longer than a few weeks after exposure including concentration difficulty (Kawana et al. 2001; Ohtani et al. 2004; Okumura et al. 2005), dizziness (Ogawa et al. 1999; Ohtani et al. 2004) (most studies found this symptom to disappear in the first few weeks), numbness or dysesthesia of extremities (Nakajima et al. 1998; Ogawa et al. 1999), and difficulty reading and writing (Nakajima et al. 1998).

Findings in animal studies cannot directly be compared to these symptoms in humans. Many of the categories for which results of animal tests could be related to a specific symptom in humans have been discussed in previous sections (e.g., anxiety and fear). No animal studies could be specifically related to headache, concentration, dizziness, numbness or dysesthesia of extremities, or difficulty reading or writing. There were additional FOB scores, such as ease in handling, piloerection, salivation, or muscular tonus. These either cannot be related to human effects or were not significantly changed and are not discussed.

After review of other neurological symptoms, it has been determined that the data are inadequate to reach any hazard conclusion due to the heterogeneity of the data and limitations in the human studies. The limitations include differences in the questionnaires used within and between studies (i.e., the list of symptoms potentially changing at the different time points), loss of subjects over time or sampling only a small number of the overall cohort of exposed subjects, and self-reporting of symptoms when the subjects were aware of their exposure (see Figure E-15 and Figure E-16). In addition, these symptoms in humans cannot be replicated with animal studies.

Figure E-15

Risk-of-bias Heat Map for Case Reports/Series and Standard Observational Studies Assessing Other Neurological Symptoms in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-16

Risk-of-bias Bar Chart for Case Reports/Series and Standard Observational Studies Assessing Other Neurological Symptoms in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## E.6 Electroencephalogram

An electroencephalogram (EEG) is a noninvasive way to record electrical activity in the brain by placing electrodes along the scalp. EEGs can detect abnormalities in brain waves or electrical activity of the brain that result from underlying disease or injury. Data that support persistent changes in EEGs in animals and humans exposed to sarin are limited. Human data include three case reports. Although five publications report on EEG, three of the publications appear to report on the same case from the Matsumoto terrorist attack. Animal data include two studies in monkeys with inconsistent results. Because the data are limited and inconsistent, the data are inadequate for drawing any hazard conclusions. A brief discussion of the studies is provided below. Risk-of-bias results for human and animal studies are provided in Figure E-17 through Figure E-20.

### E.6.1 Human EEG Data

An EEG of a 19-year-old male exposed to sarin during the Matsumoto attack (subject lived next to the site believed to be the target of the attack) demonstrated a frequent occurrence of high-amplitude waves in the sinciput portion of the brain and polyspike and wave complexes in the left side of the sinciput portion of the brain 30 hours after exposure (Sekijima et al. 1995). The EEG normalized by day 7 of hospitalization. However, an EEG conducted on day 10 of hospitalization demonstrated sporadic sharp waves and sigma waves when the subject was sleeping. An EEG conducted 1 year after exposure demonstrated sporadic sharp waves complexes in the left side of the sinciput portion of the brain when the subject was asleep even though he was experiencing no outward symptoms. Sekijima et al. (1997) included this subject as one of seven discussed. Morita et al. (1995) also appears to have included this subject in their publication, however, some details are different. As noted by Morita et al. (1995), EEGs conducted on day 2 demonstrated high-amplitude fast activity with frontal dominance and a 3Hz spike and wave complex in the right frontal area. The authors reported a decline in these effects over the following month. Grob (1956) provided information on three case reports, however, only one of them was given an EEG. This subject became unresponsive after oral exposure to an aqueous solution containing sarin. An EEG, obtained while the subject was unresponsive, revealed bursts of high-voltage waves in the temporofrontal leads that persisted for 6 days (no further information provided). EEG and positron emission topography (PET) were normal 8 months after exposure in a 34-year-old Army sergeant exposed to sarin when disarming an IED (Loh et al. 2010).

### E.6.2 Animal EEG Data

Adult rhesus monkeys exposed to a single “large” dose of sarin (5 μg/kg intramuscular) exhibited a persistent increase in beta activity in the temporal lobe EEG that was still present 1 year after exposure (Burchfiel and Duffy 1982). Slight changes in EEG were observed in marmoset monkeys administered 2.5 or 3.0 μg/kg sarin for several months (Pearce et al. 1999). EEG measurements were collected weekly through 15 months and it was reported that no significant changes in pattern over time were observed. An increase in amplitude in the beta 2 frequency band that approached significance was attributed to a 40% increase in a single animal.

Figure E-17

Risk-of-bias Heat Map for Case Reports/Series Assessing Electroencephalogram Data in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-18

Risk-of-bias Bar Chart for Case Reports/Series Assessing Electroencephalogram Data in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-19

Risk-of-bias Heat Map for Individual Studies Assessing Electroencephalogram Data in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-20

Risk-of-bias Bar Chart for Individual Studies Assessing Electroencephalogram Data in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## E.7 Other Sensory Effects

Sensory effects that are not visual or ocular effects include any of the other four senses: sound, touch, taste, or smell. Visual and ocular effects are discussed separately because there were sufficient data to support a separate category. The other senses are discussed together due to the limited amount of information.

### E.7.1 Human Other Sensory Data

The available studies support a rating of low confidence in the body of evidence that acute sarin exposure causes other sensory effects in humans over all time periods after the initial exposure, which is mainly due to the limited number of studies in any specific sensory effect. Four human studies were identified that evaluated effects in at least one of the four senses more than 24 hours after exposure (Murata et al. 1997; Nishiwaki et al. 2001; Ogawa et al. 1999; Sekijima et al. 1997). A survey from seven hospitals after the Tokyo subway attack included dysosmia (i.e., changes in sense of smell) in the questionnaire. ChE levels were available in the hospital records of 454 of the 681 subjects who responded to the questionnaire (1,089 were mailed questionnaires). Dysosmia was reported to still occur in 3 (0.4%) of the 681 subjects 2 months after the exposure (Ogawa et al. 1999). Six months after the Tokyo subway attack, Murata et al. (1997) did not find any significant differences in brainstem auditory evoked potential (BAEP, sense of sound) between 18 exposed subjects (exposure was related to initial serum ChE and other symptoms) and 18 controls (noted not exposed to any anticholinesterase exposure). One subject with initial severe symptoms from the Matsumoto attack was noted to develop sensory polyneuropathy (which potentially effects sense of touch) 7 months after the exposure (Sekijima et al. 1997). Nishiwaki et al. (2001) measured vibration perception thresholds (which is considered a measure of touch sensation) 3 years after exposure in 56 male rescue team staff members and police officers working at the Tokyo subway attack compared with 52 age and occupation-matched controls. The exposed group was separated by level of exposure based on self-reported hospitalization after the exposure (the high exposure group was hospitalized, and low exposure group was outpatients). None of the results were found to be related to exposure. Risk-of-bias results for human studies are provided in Figure E-21 and Figure E-22.

### E.7.2 Animal Other Sensory Data

A single animal study evaluated endpoints that could be considered other sensory effects (Kassa et al. 2001a). This study is inadequate to evaluate this effect because all of the outcomes were FOB scores, and correspondence with the study authors indicated that the outcome assessors were not blind to the treatment. Although there were some alterations in the FOB scores for approach response, click response, tail-pinch response, and touch response, none of the results were statistically significant, and the changes were inconsistent across dose and time (see Table F-5). In addition to the lack of blinding of outcome assessors, animals were not randomized to treatment.

### E.7.3 Integration of Evidence for Other Sensory Effects for Sarin

The human body of evidence is limited to a few studies that evaluated different outcomes related to different senses. Although there may have been low to moderate confidence in any specific study, the body of evidence is considered low due to the limited information available. The animal body of evidence was restricted to a single study examining the potential association between acute sarin exposure and a few FOB results at 3, 6, or 12 months after exposure. Both the human and animal evidence translate to an inadequate level of evidence. Therefore, an evidence profile table and detailed discussion of the evidence synthesis were not developed for sarin and other sensory effects, and this health effect was not considered for hazard identification conclusions.

Figure E-21

Risk-of-bias Heat Map for Case Reports/Series and Standard Observational Studies Assessing Other Sensory Effects in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure E-22

Risk-of-bias Bar Chart for Case Reports/Series and Standard Observational Studies Assessing Other Sensory Effects in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.