# Appendix D Risk-of-bias Assessment for All Included Studies

## D.1 Studies in Humans

Figure D-1

Risk-of-bias Heatmap for All Included Case Reports/Series and Standard Observational Studies in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in Health Assessment Workspace Collaborative (HAWC) (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure D-2

Risk-of-bias Heatmap for All Included Controlled Trials in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human controlled exposure studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## D.2 Studies in Nonhuman Animals

Figure D-3

Risk-of-bias Heatmap for All Included Studies in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.