# Appendix C List of Included Studies

## C.1 Studies in Humans

Baker DJ, Sedgwick EM. 1996. Single fibre electromyographic changes in man after organophosphate exposure. Hum Exp Toxicol. 15(5):369-375. https://dx.doi.org/10.1177/096032719601500501

Grob D. 1956. The manifestations and treatment of poisoning due to nerve gas and other organic phosphate anticholinesterase compounds. AMA Arch Intern Med. 98(2):221-239. https://dx.doi.org/10.1001/archinte.1956.00250260095010

Grob D, Harvey JC. 1958. Effects in man of the anticholinesterase compound sarin (isopropyl methyl phosphonofluoridate). J Clin Invest. 37(3):350-368. https://dx.doi.org/10.1172/JCI103615

Himuro K, Murayama S, Nishiyama K, Shinoe T, Iwase H, Nagao M, Takatori T, Kanazawa I. 1998. Distal sensory axonopathy after sarin intoxication. Neurology. 51(4):1195-1197. https://dx.doi.org/10.1212/WNL.51.4.1195

Kawana N, Ishimatsu S, Kanda K. 2001. Psycho-physiological effects of the terrorist sarin attack on the Tokyo subway system. Mil Med. 166(12 Suppl):23-26. https://dx.doi.org/10.1093/milmed/166.suppl_2.23

Kawana N, Ishimatsu SI, Matsui Y, Tamaki S, Kanda K. 2005. Chronic posttraumatic stress symptoms in victims of Tokyo subway sarin gas attack. Traumatology. 11(2):87-102. https://dx.doi.org/10.1177/153476560501100204

Loh Y, Swanberg MM, Ingram MV, Newmark J. 2010. Case report: Long-term cognitive sequelae of sarin exposure. Neurotoxicology. 31(2):244-246. https://dx.doi.org/10.1016/j.neuro.2009.12.004

Miyaki K, Nishiwaki Y, Maekawa K, Ogawa Y, Asukai N, Yoshimura K, Etoh N, Matsumoto Y, Kikuchi Y, Kumagai N et al. 2005. Effects of sarin on the nervous system of subway workers seven years after the Tokyo subway sarin attack. J Occup Health. 47(4):299-304. https://dx.doi.org/10.1539/joh.47.299

Morita H, Yanagisawa N, Nakajima T, Shimizu M, Hirabayashi H, Okudera H, Nohara M, Midorikawa Y, Mimura S. 1995. Sarin poisoning in Matsumoto, Japan. Lancet. 346(8970):290-293. https://dx.doi.org/10.1016/S0140-6736(95)92170-2

Murata K, Araki S, Yokoyama K, Okumura T, Ishimatsu S, Takasu N, White RF. 1997. Asymptomatic sequelae to acute sarin poisoning in the central and autonomic nervous system 6 months after the Tokyo subway attack. J Neurol. 244(10):601-606. https://dx.doi.org/10.1007/s004150050153

Nakajima T, Ohta S, Fukushima Y, Yanagisawa N. 1999. Sequelae of sarin toxicity at one and three years after exposure in Matsumoto, Japan. J Epidemiol. 9(5):337-343. https://dx.doi.org/10.2188/jea.9.337

Nakajima T, Ohta S, Morita H, Midorikawa Y, Mimura S, Yanagisawa N. 1998. Epidemiological study of sarin poisoning in Matsumoto City, Japan. J Epidemiol. 8(1):33-41. https://dx.doi.org/10.2188/jea.8.33

Nishiwaki Y, Maekawa K, Ogawa Y, Asukai N, Minami M, Omae K. 2001. Effects of sarin on the nervous system in rescue team staff members and police officers 3 years after the Tokyo subway sarin attack. Environ Health Perspect. 109(11):1169-1173. https://dx.doi.org/10.1289/ehp.011091169

Nohara M, Segawa K. 1996. Ocular symptoms due to organophosphorus gas (Sarin) poisoning in Matsumoto. Br J Ophthalmol. 80(11):1023. https://dx.doi.org/10.1136/bjo.80.11.1023

Ogawa Y, Yamamura Y, Ando H, Kadokura M, Agata T, Fukumoto M, Satake T, Machida K, Sakai O, Miyata Y et al. 1999. An attack with sarin nerve gas on the Tokyo subway system and its effects on victims. ACS Symp Ser. 745:333-355. https://dx.doi.org/10.1021/bk-2000-0745.ch022

Ohbu S, Yamashina A, Takasu N, Yamaguchi T, Murai T, Nakano K, Matsui Y, Mikami R, Sakurai K, Hinohara S. 1997. Sarin poisoning on Tokyo subway. South Med J. 90(6):587-593. https://dx.doi.org/10.1097/00007611-199706000-00002

Ohtani T, Iwanami A, Kasai K, Yamasue H, Kato T, Sasaki T, Kato N. 2004. Post-traumatic stress disorder symptoms in victims of Tokyo subway attack: A 5-year follow-up study. Psychiatry Clin Neurosci. 58(6):624-629. https://dx.doi.org/10.1111/j.1440-1819.2004.01313.x

Ohtomi S, Takase M, Kumagai F. 1996. Sarin poisoning in Japan. A clinical experience in Japan Self Defense Force (JSDF) Central Hospital. Rev Int Serv Sante Forces Armees. 69(4-6):97-102.

Okudera H. 2002. Clinical features on nerve gas terrorism in Matsumoto. J Clin Neurosci. 9(1):17-21. https://dx.doi.org/10.1054/jocn.2001.1020

Okumura T, Hisaoka T, Naito T, Isonuma H, Okumura S, Miura K, Maekawa H, Ishimatsu S, Takasu N, Suzuki K. 2005. Acute and chronic effects of sarin exposure from the Tokyo subway incident. Environ Toxicol Pharmacol. 19(3):447-450. https://dx.doi.org/10.1016/j.etap.2004.12.005

Okumura T, Takasu N, Ishimatsu S, Miyanoki S, Mitsuhashi A, Kumada K, Tanaka K, Hinohara S. 1996. Report on 640 victims of the Tokyo subway sarin attack. Ann Emerg Med. 28(2):129-135. https://dx.doi.org/10.1016/S0196-0644(96)70052-5

Rengstorff RH. 1985. Accidental exposure to sarin: Vision effects. Arch Toxicol. 56(3):201-203. https://dx.doi.org/10.1007/BF00333427

Rengstorff RH. 1994. Vision and ocular changes following accidental exposure to organophosphates. J Appl Toxicol. 14(2):115-118. https://dx.doi.org/10.1002/jat.2550140213

Sekijima Y, Morita H, Shindo M, Okudera H, Shibata T. 1995. [A case of severe sarin poisoning in the sarin attack in Matsumoto--one-year follow-up of clinical findings, and laboratory data]. Rinsho Shinkeigaku. 35(11):1241-1245.

Sekijima Y, Morita H, Yanagisawa N. 1997. Follow-up of sarin poisoning in Matsumoto. Ann Intern Med. 127(11):1042. https://dx.doi.org/10.7326/0003-4819-127-11-199712010-00028

Sidell FR. 1974. Soman and sarin: Clinical manifestations and treatment of accidental poisoning by organophosphates. Clin Toxicol. 7(1):1-17. https://dx.doi.org/10.3109/15563657408987971

Suzuki J, Kohno T, Tsukagosi M, Furuhata T, Yamazaki K. 1997. Eighteen cases exposed to sarin in Matsumoto, Japan. Intern Med. 36(7):466-470. https://dx.doi.org/10.2169/internalmedicine.36.466

Tochigi M, Otani T, Yamasue H, Kasai K, Kato T, Iwanami A, Kato N, Sasaki T. 2005. Support for relationship between serum cholinesterase and post-traumatic stress disorder; 5-year follow-ups of victims of the Tokyo subway sarin poisoning. Neurosci Res. 52(2):129-131. https://dx.doi.org/10.1016/j.neures.2005.03.012

Tochigi M, Umekage T, Otani T, Kato T, Iwanami A, Asukai N, Sasaki T, Kato N. 2002. Serum cholesterol, uric acid and cholinesterase in victims of the Tokyo subway sarin poisoning: A relation with post-traumatic stress disorder. Neurosci Res. 44(3):267-272. https://dx.doi.org/10.1016/S0168-0102(02)00146-3

Yamasue H, Abe O, Kasai K, Suga M, Iwanami A, Yamada H, Tochigi M, Ohtani T, Rogers MA, Sasaki T et al. 2007. Human brain structural change related to acute single exposure to sarin. Ann Neurol. 61(1):37-46. https://dx.doi.org/10.1002/ana.21024

Yokoyama K, Araki S, Murata K, Nishikitani M, Okumura T, Ishimatsu S, Takasu N. 1998. Chronic neurobehavioral and central and autonomic nervous system effects of Tokyo subway sarin poisoning. J Physiol Paris. 92(3-4):317-323. https://dx.doi.org/10.1016/S0928-4257(98)80040-5

Yokoyama K, Araki S, Murata K, Nishikitani M, Okumura T, Ishimatsu S, Takasu N. 1998. A preliminary study on delayed vestibulo-cerebellar effects of Tokyo Subway Sarin Poisoning in relation to gender difference: Frequency analysis of postural sway. J Occup Environ Med. 40(1):17-21. https://dx.doi.org/10.1097/00043764-199801000-00006

Yokoyama K, Araki S, Murata K, Nishikitani M, Okumura T, Ishimatsu S, Takasu N, White RF. 1998. Chronic neurobehavioral effects of Tokyo subway sarin poisoning in relation to posttraumatic stress disorder. Arch Environ Health. 53(4):249-256. https://dx.doi.org/10.1080/00039899809605705

Yokoyama K, Araki S, Nishikitani M, Sato H. 2002. Computerized posturography with sway frequency analysis: Application in occupational and environmental health. Ind Health. 40(1):14-22. https://dx.doi.org/10.2486/indhealth.40.14

## C.2 Studies in Nonhuman Animals

Abou-Donia MB, Dechkovskaia AM, Goldstein LB, Bullman SL, Khan WA. 2002. Sensorimotor deficit and cholinergic changes following coexposure with pyridostigmine bromide and sarin in rats. Toxicol Sci. 66(1):148-158. https://dx.doi.org/10.1093/toxsci/66.1.148

Allon N, Chapman S, Egoz I, Rabinovitz I, Kapon J, Weissman BA, Yacov G, Bloch-Shilderman E, Grauer E. 2011. Deterioration in brain and heart functions following a single sub-lethal (0.8 LCt50) inhalation exposure of rats to sarin vapor: A putative mechanism of the long-term toxicity. Toxicol Appl Pharmacol. 253(1):31-37. https://dx.doi.org/10.1016/j.taap.2011.03.007

Bansal I, Waghmare CK, Anand T, Gupta AK, Bhattacharya BK. 2009. Differential mRNA expression of acetylcholinesterase in the central nervous system of rats with acute and chronic exposure of sarin & physostigmine. J Appl Toxicol. 29(5):386-394. https://dx.doi.org/10.1002/jat.1424

Bhardwaj S, Musalgaonkar N, Waghmare C, Bhattacharya BK. 2012. Single dose exposure of sarin and physostigmine differentially regulates expression of choline acetyltransferase and vesicular acetylcholine transporter in rat brain. Chem Biol Interact. 198(1-3):57-64. https://dx.doi.org/10.1016/j.cbi.2012.05.002

Bielavska M, Kassa J. 2000. Simultaneous determination of dopamine, serotonin and their metabolites in the rat brain by HPLC method with coulometric detection. Collect Czechoslov Chem Commun. 65(10):1677-1682. https://dx.doi.org/10.1135/cccc20001677

Bizot JC. 1998. Effects of various drugs including organophosphorus compounds (OPC) and therapeutic compounds against OPC on DRL responding. Pharmacol Biochem Behav. 59(4):1069-1080. https://dx.doi.org/10.1016/S0091-3057(97)00519-4

Bloch-Shilderman E, Kadar T, Levy A, Sahar R, Rabinovitz I, Gilat E. 2005. Subcellular alterations of protein kinase C isozymes in the rat brain after organophosphate poisoning. J Pharmacol Exp Ther. 313(3):1082-1089. https://dx.doi.org/10.1124/jpet.105.083469

Burchfiel JL, Duffy FH. 1982. Organophosphate neurotoxicity: Chronic effects of sarin on the electroencephalogram of monkey and man. Neurobehav Toxicol Teratol. 4(6):767-778.

Burchfiel JL, Duffy FH, Sim VM. 1976. Persistent effects of sarin and dieldrin upon the primate electroencephalogram. Toxicol Appl Pharmacol. 35:365-379. https://dx.doi.org/10.1016/0041-008X(76)90296-9

Chaubey K, Alam SI, Nagar DP, Waghmare CK, Pant SC, Singh L, Srivastava N, Bhattacharya BK. 2017. From the cover: Proteome profile of different rat brain regions after sarin intoxication. Toxicol Sci. 160(1):136-149. https://dx.doi.org/10.1093/toxsci/kfx162

Chaubey K, Rao MK, Alam SI, Waghmare C, Bhattacharya BK. 2016. Increased expression of immune modulator proteins and decreased expression of apolipoprotein A-1 and haptoglobin in blood plasma of sarin exposed rats. Chem Biol Interact. 246:36-44. https://dx.doi.org/10.1016/j.cbi.2016.01.008

Damodaran TV, Bilska MA, Rahman AA, Abou-Donia MB. 2002. Sarin causes early differential alteration and persistent overexpression in mRNAs coding for glial fibrillary acidic protein (GFAP) and vimentin genes in the central nervous system of rats. Neurochem Res. 27(5):407-415. https://dx.doi.org/10.1023/A:1015508132137

Damodaran TV, Jones KH, Patel AG, Abou-Donia MB. 2003. Sarin (nerve agent GB)-induced differential expression of mRNA coding for the acetylcholinesterase gene in the rat central nervous system. Biochem Pharmacol. 65(12):2041-2047. https://dx.doi.org/10.1016/S0006-2952(03)00160-6

Damodaran TV, Mecklai AA, Abou-Donia MB. 2002. Sarin causes altered time course of mRNA expression of alpha tubulin in the central nervous system of rats. Neurochem Res. 27(3):177-181. https://dx.doi.org/10.1023/A:1014883402153

Damodaran TV, Patel AG, Greenfield ST, Dressman HK, Lin SM, Abou-Donia MB. 2006. Gene expression profiles of the rat brain both immediately and 3 months following acute sarin exposure. Biochem Pharmacol. 71(4):497-520. https://dx.doi.org/10.1016/j.bcp.2005.10.051

Duffy FH, Burchfield JL, Sim VM. 1976. Persistent effects of organophosphate exposure as evidenced by electroencephalographic measurements. Environ Health Effects Res Ser. 600:102-151.

Egoz I, Nili U, Grauer E, Gore A. 2017. Optimization of the ocular treatment following organophosphate nerve agent insult. Toxicol Sci. 159(1):50-63. https://dx.doi.org/10.1093/toxsci/kfx119

Genovese RF, Benton BJ, Oubre JL, Fleming PJ, Jakubowski EM, Mioduszewski RJ. 2008. Determination of miosis threshold from whole-body vapor exposure to sarin in African green monkeys. Toxicology. 244(2-3):123-132. https://dx.doi.org/10.1016/j.tox.2007.11.004

Genovese RF, Mioduszewski RJ, Benton BJ, Pare MA, Cooksey JA. 2009. Behavioral evaluation of rats following low-level inhalation exposure to sarin. Pharmacol Biochem Behav. 91(4):517-525. https://dx.doi.org/10.1016/j.pbb.2008.09.006

Genovese RF, Oubre JL, Jakubowski EM, Fleming PJ, Saxena A, Rockwood GA, Tipparaju P, Willmore CB. 2007. Evaluation of cognitive and biochemical effects of low-level exposure to sarin in rhesus and African green monkeys. Toxicology. 231(1):11-20. https://dx.doi.org/10.1016/j.tox.2006.10.018

Gore A, Brandeis R, Egoz I, Peri D, Turetz J, Bloch-Shilderman E. 2012. Efficacy assessment of various anticholinergic agents against topical sarin-induced miosis and visual impairment in rats. Toxicol Sci. 126(2):515-524. https://dx.doi.org/10.1093/toxsci/kfs009

Grauer E, Chapman S, Rabinovitz I, Raveh L, Weissman BA, Kadar T, Allon N. 2008. Single whole-body exposure to sarin vapor in rats: Long-term neuronal and behavioral deficits. Toxicol Appl Pharmacol. 227(2):265-274. https://dx.doi.org/10.1016/j.taap.2007.11.006

Grauer E, Levy A. 2007. Oxotremorine-induced hypothermia as a method for evaluating long-term neuronal changes following poisoning by cholinesterase inhibitors in rats. Toxicology. 242(1-3):1-6. https://dx.doi.org/10.1016/j.tox.2007.08.097

Gupta RC, Patterson GT, Dettbarn WD. 1991. Comparison of cholinergic and neuromuscular toxicity following acute exposure to sarin and VX in rat. Fundam Appl Toxicol. 16(3):449-458. https://dx.doi.org/10.1016/0272-0590(91)90085-I

Jones KH, Dechkovskaia AM, Herrick EA, Abdel RAA, Khan WA, Abou-Donia MB. 2000. Subchronic effects following a single sarin exposure on blood-brain and blood-testes barrier permeability, acetylcholinesterase, and acetylcholine receptors in the central nervous system of rat: A dose-response study. J Toxicol Environ Health A. 61(8):695-707. https://dx.doi.org/10.1080/00984100050195161

Kadar T, Shapira S, Cohen G, Sahar R, Alkalay D, Raveh L. 1995. Sarin-induced neuropathology in rats. Hum Exp Toxicol. 14(3):252-259. https://dx.doi.org/10.1177/096032719501400304

Kassa J, Koupilova M, Herink J, Vachek J. 2000. Long-term neurotoxicity in rats exposed to low-level sarin. Homeost Health Dis. 40(1-2):53-54.

Kassa J, Koupilova M, Herink J, Vachek J. 2001. The long-term influence of low-level sarin exposure on behavioral and neurophysiological functions in rats. Acta Medica (Hradec Kralove). 44(1):21-27.

Kassa J, Koupilova M, Vachek J. 2001. The influence of low-level sarin inhalation exposure on the spatial memory of rats. Pharmacol Biochem Behav. 70(1):175-179. https://dx.doi.org/10.1016/S0091-3057(01)00592-5

Kassa J, Koupilova M, Vachek J. 2001. The influence of low-level sarin inhalation exposure on the spatial memory of rats. Homeost Health Dis. 41(3-4):157-159.

Kassa J, Koupilova M, Vachek J. 2001. Long-term effects of low-level sarin inhalation exposure on the spatial memory of rats in a T-maze. Acta Medica (Hradec Kralove). 44(3):93-96. https://dx.doi.org/10.14712/18059694.2019.91

Kassa J, Krejcova G, Skopec F, Herink J, Bajgar J, Sevelova L, Tichy M, Pecka M. 2004. The influence of sarin on various physiological functions in rats following single or repeated low-level inhalation exposure. Inhal Toxicol. 16(8):517-530. https://dx.doi.org/10.1080/08958370490442494

Kassa J, Krejcova G, Vachek J. 2002. The impairment of spatial memory following low-level sarin inhalation exposure and antidotal treatment in rats. Acta Medica (Hradec Kralove). 45(4):149-153. https://dx.doi.org/10.14712/18059694.2019.72

Kassa J, Pecka M, Tichy M, Bajgar J, Koupilova M, Herink J, Krocova Z. 2001. Toxic effects of sarin in rats at three months following single or repeated low-level inhalation exposure. Pharmacol Toxicol. 88(4):209-212. https://dx.doi.org/10.1034/j.1600-0773.2001.d01-106.x

Kawabuchi M, Cintra WM, Deshpande SS, Albuquerque EX. 1991. Morphological and electrophysiological study of distal motor nerve fiber degeneration and sprouting after irreversible cholinesterase inhibition. Synapse. 8(3):218-228. https://dx.doi.org/10.1002/syn.890080308

Koelle GB, Koelle WA, Smyrl EG. 1977. Effects of inactivation of butyrylcholinesterase on steady state and regenerating levels of ganglionic acetylcholinesterase. J Neurochem. 28(2):313-319. https://dx.doi.org/10.1111/j.1471-4159.1977.tb07750.x

Landauer MR, Romano JA. 1984. Acute behavioral toxicity of the organophosphate sarin in rats. Neurobehav Toxicol Teratol. 6(3):239-243.

Lazar S, Egoz I, Brandeis R, Chapman S, Bloch-Shilderman E, Grauer E. 2016. Propagation of damage in the rat brain following sarin exposure: Differential progression of early processes. Toxicol Appl Pharmacol. 310:87-97. https://dx.doi.org/10.1016/j.taap.2016.09.008

Little PJ, Reynolds ML, Bowman ER, Martin BR. 1986. Tissue disposition of [3H]sarin and its metabolites in mice. Toxicol Appl Pharmacol. 83(3):412-419. https://dx.doi.org/10.1016/0041-008X(86)90223-1

Meshul CK, Boyne AF, Deshpande SS, Albuquerque EX. 1985. Comparison of the ultrastructural myopathy induced by anticholinesterase agents at the end plates of rat soleus and extensor muscles. Exp Neurol. 89(1):96-114. https://dx.doi.org/10.1016/0014-4886(85)90268-7

Mioduszewski R, Manthei J, Way R, Burnett D, Gaviola B, Muse W, Thomson S, Sommerville D, Crosier R. 2002. Interaction of exposure concentration and duration in determining acute toxic effects of sarin vapor in rats. Toxicol Sci. 66(2):176-184. https://dx.doi.org/10.1093/toxsci/66.2.176

Muggleton NG, Bowditch AP, Crofts HS, Scott EA, Pearce PC. 2003. Assessment of a combination of physostigmine and scopolamine as pretreatment against the behavioural effects of organophosphates in the common marmoset (Callithrix jacchus). Psychopharmacology. 166(3):212-220. https://dx.doi.org/10.1007/s00213-002-1324-7

Nieminen SA, Lecklin A, Heikkinen O, Ylitalo P. 1990. Acute behavioural effects of the organophosphates sarin and soman in rats. Pharmacol Toxicol. 67(1):36-40. https://dx.doi.org/10.1111/j.1600-0773.1990.tb00778.x

Pearce PC, Crofts HS, Muggleton NG, Ridout D, Scott EA. 1999. The effects of acutely administered low dose sarin on cognitive behaviour and the electroencephalogram in the common marmoset. J Psychopharmacol. 13(2):128-135. https://dx.doi.org/10.1177/026988119901300203

Pittel Z, Grauer E, Gez R, Shlomovich Y, Baranes S, Chapman S. 2018. Sex modulated effects of sarin exposure in rats: Toxicity, hypothermia and inflammatory markers. Neurotoxicology. 66:121-127. https://dx.doi.org/10.1016/j.neuro.2018.04.002

RamaRao G, Acharya JN, Bhattacharya BK. 2011. Changes of protein oxidation, calpain and cytoskeletal proteins (alpha tubulin and pNF-H) levels in rat brain after nerve agent poisoning. Toxicol Lett. 203(3):227-236. https://dx.doi.org/10.1016/j.toxlet.2011.03.020

Scaife JF, Shuster J. 1960. Tissue cholinesterase levels in sarin poisoning. Can J Biochem Physiol. 38:1087-1093. https://dx.doi.org/10.1139/o60-135

Singer AW, Jaax NK, Graham JS, McLeod CG, Jr. 1987. Cardiomyopathy in soman and sarin intoxicated rats. Toxicol Lett. 36(3):243-249. https://dx.doi.org/10.1016/0378-4274(87)90192-5

Tripathi HL, Dewey WL. 1989. Comparison of the effects of diisopropylfluorophosphate, sarin, soman, and tabun on toxicity and brain acetylcholinesterase activity in mice. J Toxicol Environ Health. 26(4):437-446. https://dx.doi.org/10.1080/15287398909531267

Whalley CE, Shih TM. 1989. Effects of soman and sarin on high affinity choline uptake by rat brain synaptosomes. Brain Res Bull. 22(5):853-858. https://dx.doi.org/10.1016/0361-9230(89)90030-0

Wolthuis OL, Groen B, Busker RW, van Helden H. 1995. Effects of low doses of cholinesterase inhibitors on behavioral performance of robot-tested marmosets. Pharmacol Biochem Behav. 51(2-3):443-456. https://dx.doi.org/10.1016/0091-3057(95)00006-I