# Appendix B Literature Search Strategy

The search terms and databases searched are provided below.

Table B-1. Sarin Search Terms

Database | Search Terms
Cochrane Library | (sarin or zarin or “o Isopropylmethyl Phosphonofluoridate” or “ortho Isopropylmethyl Phosphonofluoridate” or “ortho-Isopropylmethyl Phosphonofluoridate” or “Isopropyl methylphosphonofluoridate” or “Isopropyl Methylfluorophosphonate” or “(RS)-propan-2-yl methylphosphonofluoridate” or (GB and organophos*) or (GB and nerve)):ti,ab,kw
Embase | 'sarin':ab,ti OR 'sarin'/exp OR 'o isopropylmethyl phosphonofluoridate':ab,ti OR 'ortho isopropylmethyl phosphonofluoridate':ab,ti OR 'ortho-isopropylmethyl phosphonofluoridate':ab,ti OR 'isopropyl methylphosphonofluoridate'/exp OR 'isopropyl methylphosphonofluoridate':ab,ti OR 'isopropyl methylfluorophosphonate':ab,ti OR '(rs)-propan-2-yl methylphosphonofluoridate':ab,ti OR (gb:ab,ti AND organophos*:ab,ti) OR (gb:ab,ti AND nerve:ab,ti)
NIOSHTIC-2 Publications | Sarin[title] OR sarin[abstract] OR zarin[title] OR zarin[abstract]
NIOSHTIC-2 Publications | GB[abstract] AND nerve[abstract]
NIOSHTIC-2 Publications | GB[title] AND nerve[title]
NIOSHTIC-2 Publications | GB[abstract] AND organophos*[abstract]
NIOSHTIC-2 Publications | GB[title] AND organophos*[title]
PubMed/MEDLINE | (sarin[tiab] OR sarin[mesh] OR zarin[tiab] OR “o Isopropylmethyl Phosphonofluoridate”[tiab] OR “ortho Isopropylmethyl Phosphonofluoridate”[tiab] OR “ortho-Isopropylmethyl Phosphonofluoridate”[tiab] OR “Isopropyl methylphosphonofluoridate”[tiab] OR “Isopropyl Methylfluorophosphonate”[tiab] OR “(RS)-propan-2-yl methylphosphonofluoridate”[tiab] OR (GB[tiab] AND organophos*[tiab]) OR (GB[tiab] AND nerve[tiab]))
Scopus | Title-Abs-Key((sarin OR zarin OR {o Isopropylmethyl Phosphonofluoridate} OR {ortho Isopropylmethyl Phosphonofluoridate} OR {ortho-Isopropylmethyl Phosphonofluoridate} OR {Isopropyl methylphosphonofluoridate} OR {Isopropyl Methylfluorophosphonate} OR {(RS)-propan-2-yl methylphosphonofluoridate} OR (GB AND organophos*) OR (GB AND nerve)))
TOXLINE | Title: sarin[ti] OR sarin[mh] OR zarin[ti] OR “o Isopropylmethyl Phosphonofluoridate”[ti] OR “ortho Isopropylmethyl Phosphonofluoridate”[ti] OR “ortho-Isopropylmethyl Phosphonofluoridate”[ti] OR “Isopropyl methylphosphonofluoridate”[ti] OR “Isopropyl Methylfluorophosphonate”[ti] OR “(RS)-propan-2-yl methylphosphonofluoridate”[ti] OR (GB[ti] AND organophos*[ti]) OR (GB[ti] AND nerve[ti])
Toxline | Abstract: sarin[ab] OR sarin[mh] OR zarin[ab] OR “o Isopropylmethyl Phosphonofluoridate”[ab] OR “ortho Isopropylmethyl Phosphonofluoridate”[ab] OR “ortho-Isopropylmethyl Phosphonofluoridate”[ab] OR “Isopropyl methylphosphonofluoridate”[ab] OR “Isopropyl Methylfluorophosphonate”[ab] OR “(RS)-propan-2-yl methylphosphonofluoridate”[ab] OR (GB[ab] AND organophos*[ab]) OR (GB[ab] AND nerve[ab])
Web of Science | TS=(sarin OR zarin OR “o Isopropylmethyl Phosphonofluoridate” OR “ortho Isopropylmethyl Phosphonofluoridate” OR “ortho-Isopropylmethyl Phosphonofluoridate” OR “Isopropyl methylphosphonofluoridate” OR “Isopropyl Methylfluorophosphonate” OR “(RS)-propan-2-yl methylphosphonofluoridate” OR (GB AND organophos*) OR (GB AND nerve))