# Appendix A Data Figures

## A.1 Cholinesterase-related Effects and Outcomes

Figure A-1

ChE Levels in Blood in Humans Following Acute Sarin Exposure (Initial Period)

Interactive figure and additional study details in Health Assessment Workspace Collaborative (HAWC) (https://hawcproject.org/assessment/302/) (NTP, 2019b). For the studies presented, statistical analyses were not conducted. Results are based on a change from normal or subjects’ baseline. Subjects in the case reports/series were exposed to an unknown amount of sarin and were evaluated in terms of time after exposure. Baker and Sedgwick (1996) administered sarin vapor with an ambient concentration of 0.5 mg/m^3^ for 30 minutes. Grob and Harvey (1958) administered a solution containing sarin at varying concentrations (initial dose ranged from 0.0005–0.022 mg/kg with an average value of 0.012 mg/kg). Figures for the intermediate period (one for serum/plasma and one for red blood cells) are provided below.

Figure A-2

ChE Levels in Blood in Humans Following Acute Sarin Exposure (Intermediate Period – Serum or Plasma)

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b). For the studies presented, statistical analyses were not conducted. Results are based on a change from normal or subjects’ baseline. Subjects in the case reports/series were exposed to an unknown amount of sarin and were evaluated in terms of time after exposure. Rengstorff (1985) results are not shown in the visualization because of differing units.

Figure A-3

ChE Levels in Blood in Humans Following Acute Sarin Exposure (Intermediate Period – Red Blood Cells)

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/) (NTP, 2019b). For the studies presented, statistical analyses were not conducted. Results are based on a change from normal or subjects’ baseline. Subjects in the case reports/series were exposed to an unknown amount of sarin and were evaluated in terms of time after exposure. Rengstorff (1985) results are not shown in the visualization because of differing units.

Figure A-4

AChE Levels in Blood in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b). Some animal studies also specifically evaluated BChE, but these results are not included in the figure because its physiological function related to neurological effects is unclear. Studies with ChE activity or AChE mRNA results only (Chaubey et al. 2017; Chaubey et al. 2016; Damodaran et al. 2003; Whalley and Shih 1989) are not included in the figure. See the text for relevant information about these studies.

Figure A-5

AChE Levels in the Brain of Animals Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b). This figure includes brain regions with results from more than two studies. Some animal studies also specifically evaluated BChE, but these results are not included in the figure because its physiological function related to neurological effects is unclear. Studies with ChE activity or AChE mRNA results only (Chaubey et al. 2016; Damodaran et al. 2003; Whalley and Shih 1989) are not included in the figure. See the text for relevant information about these studies.

Figure A-6

Risk-of-bias Heat Map for Controlled Trials Assessing ChE Levels in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human controlled exposure studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-7

Risk-of-bias Bar Chart for Controlled Trials Assessing ChE Levels in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human controlled exposure studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-8

Risk-of-bias Heat Map for Case Reports/Series and Cross-Sectional Studies Assessing ChE Levels in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and cross-sectional studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-9

Risk-of-bias Bar Chart for Case Reports/Series and Cross-Sectional Studies Assessing ChE Levels in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and cross-sectional studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-10

Risk-of-bias Heat Map for Individual Studies Assessing AChE Levels in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-11

Risk-of-bias Bar Chart for Individual Studies Assessing AChE Levels in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## A.2 Visual and Ocular Effects

Figure A-12

Pupil Diameter in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

For the studies presented, statistical analyses were not conducted. Subjects in the case reports/series were exposed to an unknown amount of sarin and were evaluated in terms of time after exposure.

Normal pupil size varies from 2 to 4 mm (bright light) to 4 to 8 mm (dark) (see https://www.ncbi.nlm.nih.gov/books/NBK381/).

Figure A-13

Pupil/Iris Ratio in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b). For the study presented, statistical analyses were not conducted. Results are based on a change from normal or subjects’ baseline. Subjects in the case series were exposed to an unknown amount of sarin and were evaluated in terms of time after exposure.

Figure A-14

Pupil Diameter in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

Figure A-15

Risk-of-bias Heat Map for Case Reports/Series Assessing Visual and Ocular Effects in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-16

Risk-of-bias Bar Chart for Case Reports/Series Assessing Visual and Ocular Effects in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-17

Risk-of-bias Heat Map for Standard Observational Studies Assessing Visual and Ocular Effects in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-18

Risk-of-bias Bar Chart for Standard Observational Studies Assessing Visual and Ocular Effects in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-19

Risk-of-bias Heat Map for Individual Studies Assessing Visual and Ocular Effects in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-20

Risk-of-bias Bar Chart for Individual Studies Assessing Visual and Ocular Effects in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/302/)(NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## A.3 Effects on Learning, Memory, and Intelligence

Figure A-21

T-Maze Results in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

Figure A-22

Y-Maze Results in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

Figure A-23

Water Maze Latency to Reach Platform Results in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

Figure A-24

Water Maze Speed of Performance Results in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

Figure A-25

Risk-of-bias Heat Map for Case Reports/Series Assessing Learning, Memory, and Intelligence in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-26

Risk-of-bias Bar Chart for Case Reports/Series Assessing Learning, Memory, and Intelligence in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-27

Risk-of-bias Heat Map for Cross-Sectional Studies Assessing Learning, Memory, and Intelligence in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human cross-sectional studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-28

Risk-of-bias Bar Chart for Cross-Sectional Studies Assessing Learning, Memory, and Intelligence in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human cross-sectional studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-29

Risk-of-bias Heat Map for Individual Studies Assessing Learning, Memory, and Intelligence in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-30

Risk-of-bias Bar Chart for Individual Studies Assessing Learning, Memory, and Intelligence in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

## A.4 Morphological and Histological Changes

Figure A-31

Risk-of-bias Heat Map for Case Reports/Series and Standard Observational Studies Assessing Nervous System Morphology in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-32

Risk-of-bias Bar Chart for Case Reports/Series and Standard Observational Studies Assessing Nervous System Morphology in Humans Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for human case reports/series and standard human observational studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-33

Risk-of-bias Heat Map for Individual Studies Assessing Nervous System Histological Changes in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.

Figure A-34

Risk-of-bias Bar Chart for Individual Studies Assessing Nervous System Histological Changes in Animals Following Acute Sarin Exposure

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/302/) (NTP, 2019b).

*Questions in bold are the key risk-of-bias questions for experimental animal studies. These key questions relate to areas of bias that may have a greater impact on estimates of the overall effect size and are generally considered to have a greater effect on the credibility of study results in environmental health studies.