# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Systematic Review of Occupational Exposure to Cancer Chemotherapy Agents and Adverse Health Outcomes by letter in March 2018 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Determine whether the scientific information cited in the draft monograph is technically correct and clearly stated, and whether NTP has objectively presented and assessed the scientific evidence.
2. Determine whether the scientific evidence presented in the draft monograph supports NTP’s conclusions regarding the level of evidence from human studies for adverse health effects associated with occupational exposure to cancer chemotherapy agents.
3. Review and comment on NTP’s presentation of workplace monitoring and biomonitoring data as well as proposed research needs based on the assessment of the available scientific data on health effects and exposure monitoring.

NTP carefully considered reviewer comments in finalizing this monograph.

## Peer Reviewers

- David A. Eastmond, Ph.D.
  Environmental Toxicology Graduate Program
  Department of Molecular, Cell and Systems Biology
  University of California–Riverside
  Riverside, California, USA
- S. Katharine Hammond, Ph.D., CIH
  School of Public Health, Environmental Health Sciences Division
  University of California–Berkeley
  Berkeley, California, USA
- Steven Markowitz, M.D., Dr.P.H.
  Barry Commoner Center for Health and the Environment
  Queens College
  Flushing, New York, USA
- Carol Rice, Ph.D.
  Department of Environmental Health
  University of Cincinnati College of Medicine
  Cincinnati, Ohio, USA
- Mark B. Russi, M.D., FACOEM
  Wellness and Employee Population Health
  Yale School of Medicine and Yale-New Haven Health System
  New Haven, Connecticut, USA