# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Contributed to conception or design and contributed to drafting of protocol
  Kembra L. Howdeshell, Ph.D., Project Lead
  Andrew A. Rooney, Ph.D.
  Michael D. Shelby, Ph.D.
- Contributed to drafting of report
  Kembra L. Howdeshell, Ph.D.
  Andrew A. Rooney, Ph.D.
  Michael D. Shelby, Ph.D.
  Kyla W. Taylor, Ph.D.
- Critically reviewed draft report and figures
  Ruth M. Lunn, Ph.D.
- Critically reviewed protocol, draft report, and figures
  Kristine L. Witt, M.S.
- Retrieved and managed references
  Kembra L. Howdeshell, Ph.D.
- Screened studies
  Kembra L. Howdeshell, Ph.D.
  Michael D. Shelby, Ph.D.
- Developed visualizations
  Kembra L. Howdeshell, Ph.D.
- Assessed risk of bias
  Kyla W. Taylor, Ph.D.
- ICF, Durham, North Carolina, USA
  Critically reviewed draft report and figures
  Robyn B. Blain, Ph.D.
  Pam Ross, M.S., Lead Work Assignment Manager
- Extracted data and assessed risk of bias
  Robyn B. Blain, Ph.D.
  Pam Ross, M.S.
- National Center for Environmental Assessment, U.S. Environmental Protection Agency (formerly of Division of the National Toxicology Program, National Institute of Environmental Health Sciences), Research Triangle Park, North Carolina, USA
  Contributed to conception or design, contributed to drafting of protocol, and contributed to drafting of report
  Kristina A. Thayer, Ph.D.