# References

Acampora A, Castiglia L, Miraglia N, Pieri M, Soave C, Liotti F, Sannolo N. 2005. A case study: Surface contamination of cyclophosphamide due to working practices and cleaning procedures in two Italian hospitals. Ann Occup Hyg. 49(7):611–618. 10.1093/annhyg/mei029 15964876
Alam SS, Hafiz NA, Abd El-Rahim AH. 2011. Protective role of taurine against genotoxic damage in mice treated with methotrexate and tamoxfine. Environ Toxicol Pharmacol. 31(1):143–152. 10.1016/j.etap.2010.10.001 21787679
Albertini RJ, Anderson D, Douglas GR, Hagmar L, Hemminki K, Merlo F, Natarajan AT, Norppa H, Shuker DE, Tice R, 2000. IPCS guidelines for the monitoring of genotoxic effects of carcinogens in humans. International Programme on Chemical Safety. Mutat Res. 463(2):111–172. 10.1016/S1383-5742(00)00049-1 10913908
Andrews N, Miller E, Taylor B, Lingam R, Simmons A, Stowe J, Waight P. 2002. Recall bias, MMR, and autism. Arch Dis Child. 87(6):493–494. 10.1136/adc.87.6.493 12456546
Anwar WA, Salama SI, el Serafy MM, Hemida SA, Hafez AS. 1994. Chromosomal aberrations and micronucleus frequency in nurses occupationally exposed to cytotoxic drugs. Mutagenesis. 9(4):315–317. 10.1093/mutage/9.4.315 7968572
Axelsson G. 1990. Use of questionnaires in a study of spontaneous-abortion in a general-population. J Epidemiol Commun H. 44(3):202–204. 10.1136/jech.44.3.202 2273356
Benhamou S, Pot-Deprun J, Sancho-Garnier H, Chouroulinkov I. 1988. Sister chromatid exchanges and chromosomal aberrations in lymphocytes of nurses handling cytostatic agents. Int J Cancer. 41(3):350–353. 10.1002/ijc.2910410305 3346098
Bernabeu-Martinez MA, Ramos Merino M, Santos Gago JM, Alvarez Sabucedo LM, Wanden-Berghe C, Sanz-Valero J. 2018. Guidelines for safe handling of hazardous drugs: A systematic review. PLoS One. 13(5):e0197172. 10.1371/journal.pone.0197172 29750798
Berruyer M, Tanguay C, Caron NJ, Lefebvre M, Bussières JF. 2015. Multicenter study of environmental contamination with antineoplastic drugs in 36 Canadian Hospitals: A 2013 follow-up study. J Occup Environ Hyg. 12(2):87–94. 10.1080/15459624.2014.949725 25105559
Bigelow S, Schulz H, Dobish R, Chambers CR. 2009. Antineoplastic agent workplace contamination study: The Alberta Cancer Board Pharmacy perspective Phase III. J Oncol Pharm Pract. 15(3):157–160. 10.1177/1078155208101097 19171554
Biró A, Fodor Z, Major J, Tompa A. 2011. Immunotoxicity monitoring of hospital staff occupationally exposed to cytostatic drugs. Pathol Oncol Res. 17(2):301–308. 10.1007/s12253-010-9317-z 21113743
Bolognesi C, Nucci MC, Colacci AM, Grilli S, Ippoliti F, Mucci N, Romano Spica V, Barbieri A, Canitano N, Chiozzotto D et al. 2005. [Biomonitoring of nurses occupationally exposed to antineoplastic drugs: The IMEPA Project]. Epidemiol Prev. 29(5-6 Suppl):91-95.
Bonassi S, Znaor A, Ceppi M, Lando C, Chang WP, Holland N, Kirsch-Volders M, Zeiger E, Ban S, Barale R, 2007. An increased micronucleus frequency in peripheral blood lymphocytes predicts the risk of cancer in humans. Carcinogenesis. 28(3):625–631. 10.1093/carcin/bgl177 16973674
Bonassi S, Znaor A, Norppa H, Hagmar L. 2004. Chromosomal aberrations and risk of cancer in humans: An epidemiologic perspective. Cytogenet Genome Res. 104(1-4):376–382. 10.1159/000077519 15162068
Boughattas AB, Bouraoui S, Debbabi F, El Ghazel H, Saad A, Mrizak N. 2010. [Genotoxic risk assessment of nurses handling antineoplastic drugs]. Ann Biol Clin (Paris). 68(5):545–553. 10.1684/abc.2010.0464 20870576
Bouraoui S, Brahem A, Tabka F, Mrizek N, Saad A, Elghezal H. 2011. Assessment of chromosomal aberrations, micronuclei and proliferation rate index in peripheral lymphocytes from Tunisian nurses handling cytotoxic drugs. Environ Toxicol Pharmacol. 31(1):250–257. 10.1016/j.etap.2010.11.004 21787692
Bouyer J, Saurel-Cubizolles MJ, Grenier C, Aussel L, Job-Spira N. 1998. Ectopic pregnancy and occupational exposure of hospital personnel. Scand J Work Environ Health. 24(2):98–103. 10.5271/sjweh.285 9630056
Buono-Michel M, Orsière T, Sari-Minodier I, Botta A. 2000. Cytogenetic biomonitoring of nurses handling cytostatics. Arch Mal Prof. 61(3):148–155.
Burgaz S, Karahalil B, Bayrak P, Taskin L, Yavuzaslan F, Bokesoy I, Anzion RB, Bos RP, Platin N. 1999. Urinary cyclophosphamide excretion and micronuclei frequencies in peripheral lymphocytes and in exfoliated buccal epithelial cells of nurses handling antineoplastics. Mutat Res. 439(1):97–104. 10.1016/S1383-5718(98)00180-6 10029685
Burgaz S, Karahalil B, Canhi Z, Terzioglu F, Ancel G, Anzion RB, Bos RP, Huttner E. 2002. Assessment of genotoxic damage in nurses occupationally exposed to antineoplastics by the analysis of chromosomal aberrations. Hum Exp Toxicol. 21(3):129–135. 10.1191/0960327102ht230oa 12102538
Buschini A, Villarini M, Feretti D, Mussi F, Dominici L, Zerbini I, Moretti M, Ceretti E, Bonfiglioli R, Carrieri M, 2013. Multicentre study for the evaluation of mutagenic/carcinogenic risk in nurses exposed to antineoplastic drugs: Assessment of DNA damage. Occup Environ Med. 70(11):789–794. 10.1136/oemed-2013-101475 24143019
Bussières JF, Tanguay C, Touzin K, Langlois E, Lefebvre M. 2012. Environmental contamination with hazardous drugs in Quebec hospitals. Can J Hosp Pharm. 65(6):428–435. 10.4212/cjhp.v65i6.1190 23288952
Caciari T, Casale T, Tomei F, Samperi I, Tomei G, Capozzella A, Ripamonti K, Scala B, Andreozzi G, Nardone N, 2012. Exposure to antineoplastic drugs in health care and blood chemistry parameters. Clin Ter. 163(6):e387–e392. 23306750
Canal-Raffin M, Khennoufa K, Martinez B, Goujon Y, Folch C, Ducint D, Titier K, Brochard P, Verdun-Esquer C, Molimard M. 2016. Highly sensitive LC-MS/MS methods for urinary biological monitoring of occupational exposure to cyclophosphamide, ifosfamide, and methotrexate antineoplastic drugs and routine application. J Chromatogr B Analyt Technol Biomed Life Sci. 1038:109–117. 10.1016/j.jchromb.2016.10.021 28029545
Cardonick E, Usmani A, Ghaffar S. 2010. Perinatal outcomes of a pregnancy complicated by cancer, including neonatal follow-up after in utero exposure to chemotherapy: Results of an international registry. Am J Clin Oncol. 33(3):221–228. 10.1097/COC.0b013e3181a44ca9 19745695
Cavallo D, Ursini CL, Omodeo-Sale E, Iavicoli S. 2007. Micronucleus induction and FISH analysis in buccal cells and lymphocytes of nurses administering antineoplastic drugs. Mutat Res. 628(1):11–18. 10.1016/j.mrgentox.2006.10.014 17223378
Cavallo D, Ursini CL, Perniconi B, Francesco AD, Giglio M, Rubino FM, Marinaccio A, Iavicoli S. 2005. Evaluation of genotoxic effects induced by exposure to antineoplastic drugs in lymphocytes and exfoliated buccal cells of oncology nurses and pharmacy employees. Mutat Res. 587(1-2):45–51. 10.1016/j.mrgentox.2005.07.008 16202645
Cavallo D, Ursini CL, Rondinone B, Iavicoli S. 2009. Evaluation of a suitable DNA damage biomarker for human biomonitoring of exposed workers. Environ Mol Mutagen. 50(9):781–790. 10.1002/em.20501 19449396
Chu WC, Hon CY, Danyluk Q, Chua PP, Astrakianakis G. 2012. Pilot assessment of the antineoplastic drug contamination levels in British Columbian hospitals pre- and post-cleaning. J Oncol Pharm Pract. 18(1):46–51. 10.1177/1078155211402106 21737485
Cogliano VJ, Baan R, Straif K, Grosse Y, Lauby-Secretan B, El Ghissassi F, Bouvard V, Benbrahim-Tallaa L, Guha N, Freeman C, 2011. Preventable exposures associated with human cancers. J Natl Cancer Inst. 103(24):1827–1839. 10.1093/jnci/djr483 22158127
Colditz GA, Martin P, Stampfer MJ, Willett WC, Sampson L, Rosner B, Hennekens CH, Speizer FE. 1986. Validation of questionnaire information on risk-factors and disease outcomes in a prospective cohort study of women. Am J Epidemiol. 123(5):894–900. 10.1093/oxfordjournals.aje.a114319 3962971
Colditz GA, Stampfer MJ, Willett WC, Stason WB, Rosner B, Hennekens CH, Speizer FE. 1987. Reproducibility and validity of self-reported menopausal status in a prospective cohort study. Am J Epidemiol. 126(2):319–325. 10.1093/aje/126.2.319 3605058
Collins A, Koppen G, Valdiglesias V, Dusinska M, Kruszewski M, Moller P, Rojas E, Dhawan A, Benzie I, Coskun E, 2014. The comet assay as a tool for human biomonitoring studies: The ComNet project. Mutat Res Rev Mutat Res. 759:27–39. 10.1016/j.mrrev.2013.10.001 24184488
Connor TH, Anderson RW, Sessink PJ, Broadfield L, Power LA. 1999. Surface contamination with antineoplastic agents in six cancer treatment centers in Canada and the United States. Am J Health Syst Pharm. 56(14):1427–1432. 10.1093/ajhp/56.14.1427 10428450
Connor TH, DeBord DG, Pretty JR, Oliver MS, Roth TS, Lees PS, Krieg EF Jr, Rogers B, Escalante CP, Toennis CA, 2010. Evaluation of antineoplastic drug exposure of health care workers at three university-based US cancer centers. J Occup Environ Med. 52(10):1019–1027. 10.1097/JOM.0b013e3181f72b63 20881620
Connor TH, Lawson CC, Polovich M, McDiarmid MA. 2014. Reproductive health risks associated with occupational exposures to antineoplastic drugs in health care settings: A review of the evidence. J Occup Environ Med. 56(9):901–910. 10.1097/jom.0000000000000249 25153300
Connor TH, McDiarmid MA. 2006. Preventing occupational exposures to antineoplastic drugs in health care settings. CA Cancer J Clin. 56(6):354–365. 10.3322/canjclin.56.6.354 17135692
Cooke J, Williams J, Morgan RJ, Cooke P, Calvert RT. 1991. Use of cytogenetic methods to determine mutagenic changes in the blood of pharmacy personnel and nurses who handle cytotoxic agents. Am J Hosp Pharm. 48(6):1199–1205. 10.1093/ajhp/48.6.1199 1858797
Cooney MA, Buck Louis GM, Sundaram R, McGuiness BM, Lynch CD. 2009. Validity of self-reported time to pregnancy. Epidemiology. 20(1):56–59. 10.1097/EDE.0b013e31818ef47e 19057382
Cornetta T, Pádua L, Testa A, Ievoli E, Festa F, Tranfo G, Baccelliere L, Cozzi R. 2008. Molecular biomonitoring of a population of nurses handling antineoplastic drugs. Mutat Res. 638(1-2):75–82. 10.1016/j.mrfmmm.2007.08.017 17928012
Correa A, Cragan JD, Kucik JE, Alverson CJ, Gilboa SM, Balakrishnan R, Strickland MJ, Duke CW, O’Leary LA, Riehle-Colarusso T, 2007. Reporting birth defects surveillance data 1968-2003. Birth Defects Res A Clin Mol Teratol. 79(2):65–186. 10.1002/bdra.20350 17278144
Couch J, dePerio MA.2011. Health Hazard Evaluation Report: HETA-2010-0118-3142, September 2011. Chemotherapy drug evaluation at a medical laboratory - Pennsylvania. Govt Reports Announcements & Index. (04):24.
Couch J, Gibbins J, Connor T.2012. Health Hazard Evaluation Report: HETA-2010-0068-3156, April 2012. Chemotherapy drug evaluation at a veterinary teaching hospital - Michigan. Govt Reports Announcements & Index. (15):32.
Couch J, Gibbins J, Connor TH. 2013. Evaluation of chemotherapy drug exposure at a veterinary teaching hospital in Michigan. J Occup Environ Hyg. 10(4):D45–D51. 10.1080/15459624.2013.766561 23441586
Couch J, West C.2012. Health Hazard Evaluation Report: HETA-2009-0148-3158, June 2012. Chemotherapy drug exposure at an oncology clinic - Florida. Govt Reports Announcements & Index. (20):36.
Crauste-Manciet S, Sessink PJ, Ferrari S, Jomier JY, Brossard D. 2005. Environmental contamination with cytotoxic drugs in healthcare using positive air pressure isolators. Ann Occup Hyg. 49(7):619–628. 10.1093/annhyg/mei045 16126757
Deng HP, Lou JL, Zhang MB, Wu W, Jin LF, Chen SJ, Zheng W, Wang BH, He JL. 2006. Detecting the cytogenetic effects in workers occupationally exposed to vincristine with four genetic tests. Mutat Res. 599(1-2):152–159. 10.1016/j.mrfmmm.2006.02.003 16580025
Deng HP, Zhang MB, He JL, Wu W, Jin LF, Zheng W, Lou JL, Wang BH. 2005. Investigating genetic damage in workers occupationally exposed to methotrexate using three genetic end-points. Mutagenesis. 20(5):351–357. 10.1093/mutage/gei048 16037120
Dranitsaris G, Johnston M, Poirier S, Schueller T, Milliken D, Green E, Zanke B. 2005. Are health care providers who work with cancer drugs at an increased risk for toxic events? A systematic review and meta-analysis of the literature. J Oncol Pharm Pract. 11(2):69–78. 10.1191/1078155205jp155oa 16465719
El-Ebiary AA, Abuelfadl AA, Sarhan NI. 2013. Evaluation of genotoxicity induced by exposure to antineoplastic drugs in lymphocytes of oncology nurses and pharmacists. J Appl Toxicol. 33(3):196–201. 10.1002/jat.1735 21935972
Elshamy K, El-Hadidi M, El-Roby M, Fouda M. 2010. Health hazards among oncology nurses exposed to chemotherapy drugs. Afr J Haematol Oncol. 1(3):70–78.
Ensslin AS, Huber R, Pethran A, Rommelt H, Schierl R, Kulka U, Fruhmann G. 1997. Biological monitoring of hospital pharmacy personnel occupationally exposed to cytostatic drugs: Urinary excretion and cytogenetics studies. Int Arch Occup Environ Health. 70(3):205–208. 10.1007/s004200050208 9298404
Ensslin AS, Pethran A, Schierl R, Fruhmann G. 1994 a. Urinary platinum in hospital personnel occupationally exposed to platinum-containing antineoplastic drugs. Int Arch Occup Environ Health. 65(5):339–342. 10.1007/BF00405699 8175190
Ensslin AS, Stoll Y, Pethran A, Pfaller A, Rommelt H, Fruhmann G. 1994 b. Biological monitoring of cyclophosphamide and ifosfamide in urine of hospital personnel occupationally exposed to cytostatic drugs. Occup Environ Med. 51(4):229–233. 10.1136/oem.51.4.229 8199663
Evelo CT, Bos RP, Peters JG, Henderson PT. 1986. Urinary cyclophosphamide assay as a method for biological monitoring of occupational exposure to cyclophosphamide. Int Arch Occup Environ Health. 58(2):151–155. 10.1007/BF00380766 3744569
Ferguson LR, Everts R, Robbie MA, Harvey V, Tempel D, Mak D, Gerred AJ. 1988. The use within New Zealand of cytogenetic approaches to monitoring of hospital pharmacists for exposure to cytotoxic drugs: Report of a pilot study in Aukland. Aust J Hosp Pharm. 18(3):228–233.
Fransman W, Huizer D, Tuerk J, Kromhout H. 2007 a. Inhalation and dermal exposure to eight antineoplastic drugs in an industrial laundry facility. Int Arch Occup Environ Health. 80(5):396–403. 10.1007/s00420-006-0148-x 17021843
Fransman W, Kager H, Meijster T, Heederik D, Kromhout H, Portengen L, Blaauboer BJ. 2014. Leukemia from dermal exposure to cyclophosphamide among nurses in The Netherlands: Quantitative assessment of the risk. Ann Occup Hyg. 58(3):271–282. 10.1093/annhyg/met077 24412718
Fransman W, Peelen S, Hilhorst S, Roeleveld N, Heederik D, Kromhout H. 2007 b. A pooled analysis to study trends in exposure to antineoplastic drugs among nurses. Ann Occup Hyg. 51(3):231–239. 10.1093/annhyg/mel081 17337460
Fransman W, Roeleveld N, Peelen S, de Kort W, Kromhout H, Heederik D. 2007 c. Nurses with dermal exposure to antineoplastic drugs: Reproductive outcomes. Epidemiology. 18(1):112–119. 10.1097/01.ede.0000246827.44093.c1 17099323
Fucic A, Jazbec A, Mijic A, Seso-Simic D, Tomek R. 1998. Cytogenetic consequences after occupational exposure to antineoplastic drugs. Mutat Res. 416(1-2):59–66. 10.1016/S1383-5718(98)00084-9 9725992
Garaj-Vrhovac V, Kopjar N. 1998. Micronuclei in cytokinesis-blocked lymphocytes as an index of occupational exposure to antineoplastic drugs. Radiol Oncol. 32(4):385–392.
Goloni-Bertollo EM, Tajara EH, Manzato AJ, Varella-Garcia M. 1992. Sister chromatid exchanges and chromosome aberrations in lymphocytes of nurses handling antineoplastic drugs. Int J Cancer. 50(3):341–344. 10.1002/ijc.2910500302 1735601
Grummt T, Grummt HJ, Schott G. 1993. Chromosomal aberrations in peripheral lymphocytes of nurses and physicians handling antineoplastic drugs. Mutat Res. 302(1):19–24. 10.1016/0165-7992(93)90085-A 7683102
Gudkov SV, Shilyagina NY, Vodeneev VA, Zvyagin AV. 2015. Targeted radionuclide therapy of human tumors. Int J Mol Sci. 17(1). 10.3390/ijms17010033 26729091
Gunnarsdóttir H, Rafnsson V. 1995. Cancer incidence among Icelandic nurses. J Occup Environ Med. 37(3):307–312. 10.1097/00043764-199503000-00007 7796198
Gunnarsdóttir HK, Aspelund T, Karlsson T, Rafnsson VV. 1997. Occupational risk factors for breast cancer among nurses. Int J Occup Environ Health. 3(4):254–258. 10.1179/oeh.1997.3.4.254 9891125
Guyatt G, Oxman AD, Akl EA, Kunz R, Vist G, Brozek J, Norris S, Falck-Ytter Y, Glasziou P, DeBeer H, 2011. GRADE guidelines: 1. Introduction-GRADE evidence profiles and summary of findings tables. J Clin Epidemiol. 64(4):383–394. 10.1016/j.jclinepi.2010.04.026 21195583
Hall AL, Davies HW, Demers PA, Nicol AM, Peters CE. 2013. Occupational exposures to antineoplastic drugs and ionizing radiation in Canadian veterinary settings: Findings from a national surveillance project. Can J Public Health. 104(7):e460–e465. 10.17269/cjph.104.4167 24495821
Halsen G, Kramer I. 2011. Assessing the risk to health care staff from long-term exposure to anticancer drugs—the case of monoclonal antibodies. J Oncol Pharm Pract. 17(1):68–80. 10.1177/1078155210376847 20667850
Hama K, Fukushima K, Hirabatake M, Hashida T, Kataoka K. 2012. Verification of surface contamination of Japanese cyclophosphamide vials and an example of exposure by handling. J Oncol Pharm Pract. 18(2):201–206. 10.1177/1078155211419543 21947739
Hama T, Aoyama T, Shirai T, Higuchi S, Yokokawa T, Sugimoto Y. 2009. Environmental contamination due to preparation of cyclophosphamide and exposure of pharmacists to it. Jpn J Pharm Health Care Sci. 35(10):693–700.10.5649/jjphcs.35.693
Harris PE, Connor TH, Stevens KR, Theiss JC. 1992. Cytogenetic assessment of occupational exposure of nurses to antineoplastic agents. J Occup Med Toxicol. 1(3):243–254.
Hedmer M, Tinnerberg H, Axmon A, Jonsson BA. 2008. Environmental and biological monitoring of antineoplastic drugs in four workplaces in a Swedish hospital. Int Arch Occup Environ Health. 81(7):899–911. 10.1007/s00420-007-0284-y 18066576
Hemminki K, Kyyronen P, Lindbohm ML. 1985. Spontaneous abortions and malformations in the offspring of nurses exposed to anaesthetic gases, cytostatic drugs, and other potential hazards in hospitals, based on registered information of outcome. J Epidemiol Commun H. 39(2):141–147. 10.1136/jech.39.2.141 3925060
Hessel H, Radon K, Pethran A, Maisch B, Grobmair S, Sautter I, Fruhmann G. 2001. The genotoxic risk of hospital, pharmacy and medical personnel occupationally exposed to cytostatic drugs—evaluation by the micronucleus assay. Mutat Res. 497(1-2):101–109. 10.1016/S1383-5718(01)00236-4 11525912
Hirst M, Tse S, Mills DG, Levin L, White DF. 1984. Occupational exposure to cyclophosphamide. Lancet. 323(8370):186–188. 10.1016/S0140-6736(84)92111-1 6141334
Hola N, Sram RJ, Roznickova I. 1988. Evaluation of genotoxic risk in occupational exposure to cytostatics. Prac Lek. 40(4):154–157.
Hon CY, Teschke K, Chua P, Venners S, Nakashima L. 2011. Occupational exposure to antineoplastic drugs: Identification of job categories potentially exposed throughout the hospital medication system. Saf Health Work. 2(3):273–281. 10.5491/SHAW.2011.2.3.273 22953211
Hon CY, Teschke K, Demers PA, Venners S. 2014. Antineoplastic drug contamination on the hands of employees working troughout the hospital medication system. Ann Occup Hyg. 58(6):761–770. 10.1093/annhyg/meu019 24644303
Hon CY, Teschke K, Shen H, Demers PA, Venners S. 2015. Antineoplastic drug contamination in the urine of Canadian healthcare workers. Int Arch Occup Environ Health. 88(7):933–941. 10.1007/s00420-015-1026-1 25626912
International Agency for Research on Cancer (IARC). 1966. IARC Monograph on the Evaluation of the Carcinogenic Risk of Chemicals to Humans: Some Pharmaceutical Drugs. International Agency for Research on Cancer. Lyon, France: World Health Organization; p. 1–514.
International Agency for Research on Cancer (IARC). 1980. IARC Monograph on the Evaluation of the Carcinogenic Risk of Chemical to Human: Some Antineoplastic and Immunosuppressive Agents. International Agency for Research on Cancer. Lyon, France: World Health Organization; p. 396.
International Agency for Research on Cancer (IARC). 1981. IARC Monograph on the Evaluation of the Carcinogenic Risk of Chemicals to Humans: Some Antineoplastics & Immunosuppressive Agents. International Agency for Research on Cancer. Lyon, France: World Health Organization; p. 1–411.
International Agency for Research on Cancer (IARC). 1990. IARC Monograph on the Evaluation of the Carcinogenic Risk of Chemicals to Humans: Pharmaceutical Drugs. International Agency for Research on Cancer. Lyon, France: World Health Organization; p. 1–415.
International Agency for Research on Cancer (IARC). 2000. IARC Monograph on the Evaluation of the Carcinogenic Risk of Chemicals to Humans: Some Antineoplastics, Antivirals, and Other Pharmaceutical Drugs. International Agency for Research on Cancer. Lyon, France: World Health Organization; p. 1–531.
International Agency for Research on Cancer (IARC).2012. A review of human carcinogens. Part A: Pharmaceuticals. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans Meeting on 14-21 October 2008. Lyon, France: International Agency for Research on Cancer.https://monographs.iarc.fr/ENG/Monographs/vol100A/mono100A.pdf. [7 August 2017]
International Agency for Research on Cancer (IARC).2016. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: World Health Organization (WHO).https://monographs.iarc.fr/ENG/Classification/index.php. [Accessed: 10 July 2016]
Izdes S, Sardas S, Kadioglu E, Kaymak C, Ozcagli E. 2009. Assessment of genotoxic damage in nurses occupationally exposed to anaesthetic gases or antineoplastic drugs by the comet assay. J Occup Health. 51(3):283–286. 10.1080/152873901300018011 19305118
Jakab MG, Major J, Tompa A. 2001. Follow-up genotoxicological monitoring of nurses handling antineoplastic drugs. J Toxicol Environ Health A. 62(5):307–318. 10.1080/152873901300018011 11261894
Janes A, Tanguay C, Caron NJ, Bussieres JF. 2015. Environmental contamination with cyclophosphamide, ifosfamide, and methotrexate: A study of 51 Canadian centres. Can J Hosp Pharm. 68(4):279–289. 10.4212/cjhp.v68i4.1467 26327701
Janssens T, Brouwers EE, de Vos JP, de Vries N, Schellens JH, Beijnen JH. 2015 a. Determination of platinum surface contamination in veterinary and human oncology centres using inductively coupled plasma mass spectrometry. Vet Comp Oncol. 13(3):305–313. 10.1111/vco.12049 24034226
Janssens T, Brouwers EE, de Vos JP, de Vries N, Schellens JH, Beijnen JH. 2015 b. Inductively coupled plasma mass-spectrometric determination of platinum in excretion products of client-owned pet dogs. Vet Comp Oncol. 13(2):124–132. 10.1111/vco.12025 23714139
Jeebhay M, Mbuli S, Uebel R. 1993. Assessment of exposure to chloramphenicol and azathioprine among workers in a South African pharmaceutical plant. Int Arch Occup Environ Health. 65 S1:S119–S122. 10.1007/BF00381321 8406906
Jochimsen PR, Corder MP, Lachenbruch PA, Spaight ME. 1988. Preparation and administration of chemotherapy. Haematological consequences for hospital-based nurses. Med Toxicol. 3(1):59–63. 10.1007/BF03259931 3367786
Joffe M, Villard L, Li ZM, Plowman R, Vessey M. 1993. Long-term recall of time-to-pregnancy. Fertil Steril. 60(1):99–104. 10.1016/S0015-0282(16)56044-0 8513966
Karahalil B, Ilter Akkoyunlu K. 2004. Determination of urinary cyclophosphamide in oncology nurses handling antineoplastic drugs by gas chromatography-mass spectrometry. FABAD J Pharm Sci. 28(3):125–130.
Kašuba V, Rozgaj R, Garaj-Vrhovac V.1999. Analysis of sister chromatid exchange and micronuclei in peripheral blood lymphocytes of nurses handling cytostatic drugs. J Appl Toxicol. 19(6):401-404. 10.1002/(SICI)1099-1263(199911/12)19:6<401:AID-JAT592>3.0.CO;2-H
Kevekordes S, Gebel TW, Hellwig M, Dames W, Dunkelberg H. 1998. Human effect monitoring in cases of occupational exposure to antineoplastic drugs: A method comparison. Occup Environ Med. 55(3):145–149. 10.1136/oem.55.3.145 9624264
Kibby T. 2017. A review of surface wipe sampling compared to biologic monitoring for occupational exposure to antineoplastic drugs. J Occup Environ Hyg. 14(3):159–174. 10.1080/15459624.2016.1237026 27676216
Kiffmeyer TK, Kube C, Opiolka S, Schmidt KG, Schöppe G, Sessink PJM. 2002. Vapour pressures, evaporation behaviour and airborne concentrations of hazardous drugs: Implications for occupational safety. Pharm J. 268(7188):331–337.
Kiffmeyer TK, Tuerk J, Hahn M, Stuetzer H, Hadtstein C, Heinemann A, Eickmann U. 2013. Application and assessment of a regular environmental monitoring of the antineoplastic drug contamination level in pharmacies - the MEWIP project. Ann Occup Hyg. 57(4):444–455. 10.1093/annhyg/mes081 23125441
Kirsch-Volders M, Plas G, Elhajouji A, Lukamowicz M, Gonzalez L, Vande Loock K, Decordier I. 2011. The in vitro MN assay in 2011: Origin and fate, biological significance, protocols, high throughput methodologies and toxicological relevance. Arch Toxicol. 85(8):873–899. 10.1007/s00204-011-0691-4 21537955
Klahn S. 2014. Chemotherapy safety in clinical veterinary oncology. Vet Clin North Am Small Anim Pract. 44(5):941–963. 10.1016/j.cvsm.2014.05.009 25174909
Knobloch A, Mohring SA, Eberle N, Nolte I, Hamscher G, Simon D. 2010. Drug residues in serum of dogs receiving anticancer chemotherapy. J Vet Intern Med. 24(2):379–383. 10.1111/j.1939-1676.2009.0469.x 20102504
Konate A, Poupon J, Villa A, Garnier R, Hasni-Pichard H, Mezzaroba D, Fernandez G, Pocard M. 2011. Evaluation of environmental contamination by platinum and exposure risks for healthcare workers during a heated intraperitoneal perioperative chemotherapy (HIPEC) procedure. J Surg Oncol. 103(1):6–9. 10.1002/jso.21740 20886552
Kopjar N, Garaj-Vrhovac V. 2001. Application of the alkaline comet assay in human biomonitoring for genotoxicity: A study on Croatian medical personnel handling antineoplastic drugs. Mutagenesis. 16(1):71–78. 10.1093/mutage/16.1.71 11139601
Kopjar N, Garaj-Vrhovac V, Kasuba V, Rozgaj R, Ramic S, Pavlica V, Zeljezic D. 2009. Assessment of genotoxic risks in Croatian health care workers occupationally exposed to cytotoxic drugs: A multi-biomarker approach. Int J Hyg Environ Health. 212(4):414–431. 10.1016/j.ijheh.2008.10.001 19049854
Kopp B, Crauste-Manciet S, Guibert A, Mourier W, Guerrault-Moro MN, Ferrari S, Jomier JY, Brossard D, Schierl R. 2013 a. Environmental and biological monitoring of platinum-containing drugs in two hospital pharmacies using positive air pressure isolators. Ann Occup Hyg. 57(3):374–383. 10.1093/annhyg/mes073 23091112
Kopp B, Schierl R, Nowak D. 2013 b. Evaluation of working practices and surface contamination with antineoplastic drugs in outpatient oncology health care settings. Int Arch Occup Environ Health. 86(1):47–55. 10.1007/s00420-012-0742-z 22311009
Korczowska E, Jankowiak-Gracz H. 2013. How can we improve safe handling of antineoplastic drugs: Can devices be helpful. Eur J Onc Pharm. 7(1):5–7.
Krepinsky A, Bryant DW, Davison L, Young B, Heddle J, McCalla DR, Douglas G, Michalko K. 1990. Comparison of three assays for genetic effects of antineoplastic drugs on cancer patients and their nurses. Environ Mol Mutagen. 15(2):83–92. 10.1002/em.2850150205 2407531
Krstev S, Perunicic B, Vidakovic A. 2003. Work practice and some adverse health effects in nurses handling antineoplastic drugs. Med Lav. 94(5):432–439. 14619181
Ladeira C, Viegas S, Pádua M, Gomes M, Carolino E, Gomes MC, Brito M. 2014. Assessment of genotoxic effects in nurses handling cytostatic drugs. J Toxicol Environ Health A. 77(14-16):879–887. 10.1080/15287394.2014.910158 25072720
Laffon B, Teixeira JP, Silva S, Loureiro J, Torres J, Pasaro E, Mendez J, Mayan O. 2005. Genotoxic effects in a population of nurses handling antineoplastic drugs, and relationship with genetic polymorphisms in DNA repair enzymes. Am J Ind Med. 48(2):128–136. 10.1080/15287394.2014.910158 16032741
Lawson CC, Rocheleau CM, Whelan EA, Lividoti Hibert EN, Grajewski B, Spiegelman D, Rich-Edwards JW. 2012. Occupational exposures among nurses and risk of spontaneous abortion. Am J Obstet Gynecol. 206(4):327.e321–327.e328. 10.1016/j.ajog.2011.12.030 22304790
Lawson CC, Whelan EA, Hibert EN, Grajewski B, Spiegelman D, Rich-Edwards JW.2009. Occupational factors and risk of preterm birth in nurses. Am J Obstet Gynecol. 200(1):51 e51-58. 10.1016/j.ajog.2008.08.006
Li ML, Zhang YY, Wang QX, Pei Y, Xiao CS. 2005. [Effects of antineoplastics drug on T-lymphocytes subsets in nurses of occupational exposure to antineoplastic drugs]. Zhonghua Lao Dong Wei Sheng Zhi Ye Bing Za Zhi. 23(6):450–451. 16405783
Lie J, Andersen A, Kjaerheim K. 2007. Cancer risk among 43000 Norwegian nurses. Scand J Work Environ Health. 33(1):66–73. 10.5271/sjweh.1066 17353967
Lorente C, Cordier S, Bergeret A, De Walle HE, Goujard J, Ayme S, Knill-Jones R, Calzolari E, Bianchi F. 2000. Maternal occupational risk factors for oral clefts. Occupational Exposure and Congenital Malformation Working Group. Scand J Work Environ Health. 26(2):137–145. 10.5271/sjweh.523 10817379
Machado-Santelli GM, Cerqueira EM, Oliveira CT, Pereira CA. 1994. Biomonitoring of nurses handling antineoplastic drugs. Mutat Res. 322(3):203–208. 10.1016/0165-1218(94)90007-8 7521520
Mader RM, Kokalj A, Kratochvil E, Pilger A, Rudiger HW. 2009. Longitudinal biomonitoring of nurses handling antineoplastic drugs. J Clin Nurs. 18(2):263–269. 10.1111/j.1365-2702.2007.02189.x 18624785
Maeda S, Miyawaki K, Matsumoto S, Oishi M, Miwa Y, Kurokawa N. 2010. Evaluation of environmental contaminations and occupational exposures involved in preparation of chemotherapeutic drugs. Yakugaku Zasshi. 130(6):903–910. 10.1248/yakushi.130.903 20519870
Mahmoodi M, Soleyman-Jahi S, Zendehdel K, Mozdarani H, Azimi C, Farzanfar F, Safari Z, Mohagheghi MA, Khaleghian M, Divsalar K, 2017. Chromosomal aberrations, sister chromatid exchanges, and micronuclei in lymphocytes of oncology department personnel handling anti-neoplastic drugs. Drug Chem Toxicol. 40(2):235–240. 10.1080/01480545.2016.1209678 27461518
Mahrous HS, Ismail SR, Hashishe MM, Kohail HM. 1998. Sister chromatid exchanges and chromosome aberrations in lymphocytes of medical personnel handling cytostatic drugs. J Egypt Public Health Assoc. 73(3-4):297–323. 17219926
Maluf SW, Erdtmann B. 2000 a. Evaluation of occupational genotoxic risk in a Brazilian hospital. Genet Mol Biol. 23(2):485–488.10.1590/S1415-47572000000200040
Maluf SW, Erdtmann B. 2000 b. Follow-up study of the genetic damage in lymphocytes of pharmacists and nurses handling antineoplastic drugs evaluated by cytokinesis-block micronuclei analysis and single cell gel electrophoresis assay. Mutat Res. 471(1-2):21–27. 10.1016/S1383-5718(00)00107-8 11080657
Martins I, Apostoli P, Della Rosa HV. 2008. Cyclophosphamide levels in sites of preparation and administration of antineoplastic drugs. Lat Am J Pharm. 27(2):217–223.
Mateuca R, Lombaert N, Aka PV, Decordier I, Kirsch-Volders M. 2006. Chromosomal changes: Induction, detection methods and applicability in human biomonitoring. Biochimie. 88(11):1515–1531. 10.1016/j.biochi.2006.07.004 16919864
McAbee RR, Gallucci BJ, Checkoway H. 1993. Adverse reproductive outcomes and occupational exposures among nurses: An investigation of multiple hazardous exposures. AAOHN J. 41(3):110–119. 10.1177/216507999304100301 8476440
McDevitt JJ, Lees PS, McDiarmid MA. 1993. Exposure of hospital pharmacists and nurses to antineoplastic agents. J Occup Med. 35(1):57–60. 8423505
McDiarmid MA, Kolodner K, Humphrey F, Putman D, Jacobson-Kram D. 1992. Baseline and phosphoramide mustard-induced sister-chromatid exchanges in pharmacists handling anti-cancer drugs. Mutat Res. 279(3):199–204. 10.1016/0165-1218(92)90067-A 1377335
McDiarmid MA, Oliver MS, Roth TS, Rogers B, Escalante C. 2010. Chromosome 5 and 7 abnormalities in oncology personnel handling anticancer drugs. J Occup Environ Med. 52(10):1028–1034. 10.1097/JOM.0b013e3181f73ae6 20881619
McDiarmid MA, Rogers B, Oliver MS. 2014. Chromosomal effects of non-alkylating drug exposure in oncology personnel. Environ Mol Mutagen. 55(4):369–374. 10.1002/em.21852 24449410
McDonald AD, McDonald JC, Armstrong B, Cherry NM, Cote R, Lavoie J, Nolin AD, Robert D. 1988 a. Congenital defects and work in pregnancy. Br J Ind Med. 45(9):581–588. 3179232
McDonald AD, McDonald JC, Armstrong B, Cherry NM, Cote R, Lavoie J, Nolin AD, Robert D. 1988 b. Fetal death and work in pregnancy. Br J Ind Med. 45(3):148–157. 3348991
Medková J. 1990. Cytogenetic analysis of peripheral lymphocytes in occupationally exposed health personnel. Acta Univ Palacki Olomuc Fac Med. 126:93–106. 2151105
Medková J. 1991 a. An analysis of the health condition of personnel exposed to cytostatics at an oncology unit. Acta Univ Palacki Olomuc Fac Med. 130:311–322. 1838883
Medková J. 1991 b. Analysis of the health condition of the children born to the personnel exposed to cytostatics at an oncology unit. Acta Univ Palacki Olomuc Fac Med. 130:323–332. 1838884
Meijster T, Fransman W, Veldhof R, Kromhout H. 2006. Exposure to antineoplastic drugs outside the hospital environment. Ann Occup Hyg. 50(7):657–664. 10.1093/annhyg/mel023 16679337
Merger D, Tanguay C, Langlois E, Lefebvre M, Bussieres JF. 2014. Multicenter study of environmental contamination with antineoplastic drugs in 33 Canadian hospitals. Int Arch Occup Environ Health. 87(3):307–313. 10.1007/s00420-013-0862-0 23471647
Milković-Kraus S, Horvat D. 1991. Chromosomal abnormalities among nurses occupationally exposed to antineoplastic drugs. Am J Ind Med. 19(6):771–774. 10.1002/ajim.4700190609 1882854
Minoia C, Turci R, Sottani C, Schiavi A, Perbellini L, Angeleri S, Draicchio F, Apostoli P.1998. Application of high performance liquid chromatography/tandem mass spectrometry in the environmental and biological monitoring of health care personnel occupationally exposed to cyclophosphamide and ifosfamide. Rapid Commun Mass Spectrom. 12(20):1485-1493. 10.1002/(SICI)1097-0231(19981030)12:20<1485:AID-RCM333>3.0.CO;2-N
Mistry AR, Felix CA, Whitmarsh RJ, Mason A, Reiter A, Cassinat B, Parry A, Walz C, Wiemels JL, Segal MR, 2005. DNA topoisomerase II in therapy-related acute promyelocytic leukemia. N Engl J Med. 352(15):1529–1538. 10.1056/NEJMoa042715 15829534
Miyake T, Iwamoto T, Tanimura M, Okuda M. 2013. Impact of closed-system drug transfer device on exposure of environment and healthcare provider to cyclophosphamide in Japanese hospital. Springerplus. 2(1):273. 10.1186/2193-1801-2-273 23853750
Moretti M, Grollino MG, Pavanello S, Bonfiglioli R, Villarini M, Appolloni M, Carrieri M, Sabatini L, Dominici L, Stronati L, 2015. Micronuclei and chromosome aberrations in subjects occupationally exposed to antineoplastic drugs: A multicentric approach. Int Arch Occup Environ Health. 88(6):683–695. 10.1007/s00420-014-0993-y 25362515
Moretti M, Villarini M, Dominici L, Fatigoni C, Dell’omo M, Elisei E, Muzi G, Monarca S. 2013. [Evaluation of genotoxic effects in subjects occupationally exposed to antineoplastic drugs]. Ig Sanita Pubbl. 69(1):55–77. 23532161
Morton LM, Dores GM, Tucker MA, Kim CJ, Onel K, Gilbert ES, Fraumeni JF Jr, Curtis RE. 2013. Evolving risk of therapy-related acute myeloid leukemia following cancer chemotherapy among adults in the United States, 1975-2008. Blood. 121(15):2996–3004. 10.1182/blood-2012-08-448068 23412096
Mrđanović J, Jungic S, Solajic S, Bogdanovic V, Jurisic V. 2012. Effects of orally administered antioxidants on micronuclei and sister chromatid exchange frequency in workers professionally exposed to antineoplastic agents. Food Chem Toxicol. 50(8):2937–2944. 10.1016/j.fct.2012.04.027 22546365
Mušák L, Halasova E, Matakova T, Letkova L, Vodickova L, Buchancova J, Hudeckova H, Osina O, Soucek P, Vodicka P. 2009 a. Comparison of chromosomal aberrations frequency and polymorphism of GSTs genes in workers occupationally exposed to cytostatics or anaesthetics. Interdiscip Toxicol. 2(3):190–194. 10.2478/v10102-009-0016-0 21217853
Mušák L, Polakova V, Halasova E, Osina O, Vodickova L, Buchancova J, Hudeckova H, Vodicka P. 2009 b. Effect of occupational exposure to cytostatics and nucleotide excision repair polymorphism on chromosomal aberrations frequency. Interdiscip Toxicol. 2(1):13–17. 10.2478/v10102-009-0002-6 21217839
Mušák L, Smerhovsky Z, Halasova E, Osina O, Letkova L, Vodickova L, Polakova V, Buchancova J, Hemminki K, Vodicka P. 2013. Chromosomal damage among medical staff occupationally exposed to volatile anesthetics, antineoplastic drugs, and formaldehyde. Scand J Work Environ Health. 39(6):618–630. 10.5271/sjweh.3358 23525098
Mušák L, Vodicka P, Klimentova G, Soucek P, Hanova M, Mikulkova R, Buchancova J, Vodickova L, Polakova V, Pec M. 2006. Chromosomal damage and polymorphisms of DNA repair genes XRCC1 and XRCC3 in workers exposed to cytostatics. Neuroendocrinol Lett. 27 Suppl 2:57–60. 17159780
National Toxicology Program (NTP).2008. NTP-CERHR Monograph on the Potential Human Reproductive and Developmental Effects of Hydroxyurea. National Toxicology Program Center for Evaluation of Risks to Human Reproduction. Research Triangle Park, NC: US Department of Health and Human Services, Public Health Service. p. vii-viii, v, ix-III1.
National Toxicology Program (NTP). 2013. NTP Monograph: Developmental Effects and Pregnancy Outcomes Associated With Cancer Chemotherapy Use During Pregnancy. National Toxicology Program. 2014/04. 17th ed. Research Triangle Park, NC: US Department of Health and Human Services, Public Health Service; p. i-214.
National Toxicology Program (NTP).2015a. Health Assessment Workspace Collaborative (HAWC) page for occupational chemotherapy.https://hawcproject.org/assessment/196/.
National Toxicology Program (NTP).2015b. MGRAPH-5: Occupational exposure to cancer chemotherapy agents supplementary files. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program.10.22427/NTP-DATA-MONOGRAPH5.
National Toxicology Program (NTP).2016. Report on Carcinogens, 14th Edition. Research Triangle Park, NC: US Department of Health and Human Services, Public Health Service.https://ntp.niehs.nih.gov/go/roc14 [7 August 2017]
Nieuwenhuijsen M. 2003. Exposure Assessment in Occupational and Environmental Epidemiology. New York, New York: Oxford University Press, Inc. 10.1093/acprof:oso/9780198528616.001.0001
Nikula E, Kiviniitty K, Leisti J, Taskinen PJ. 1984. Chromosome aberrations in lymphocytes of nurses handling cytostatic agents. Scand J Work Environ Health. 10(2):71–74. 10.5271/sjweh.2355 6382593
Norppa H, Bonassi S, Hansteen IL, Hagmar L, Stromberg U, Rossner P, Boffetta P, Lindholm C, Gundy S, Lazutka J, 2006. Chromosomal aberrations and SCEs as biomarkers of cancer risk. Mutat Res. 600(1-2):37–45. 10.1016/j.mrfmmm.2006.05.030 16814813
Nyman HA, Jorgenson JA, Slawson MH. 2007. Workplace contamination with antineoplastic agents in a new cancer hospital using a closed-system drug transfer device. Hosp Pharm. 42(3):219–225.10.1310/hpj4203-219
Occupational Safety and Health Administration (OSHA).1986. Work practice guidelines for personnel dealing with cytotoxic (antineoplastic) drugs. OSHA Publication 8-1.1. Washington, DC: US Department of Labor, Occupational Safety and Health Administration.https://www.osha.gov/pls/oshaweb/owadisp.show_document?p_table=DIRECTIVES&p_id=1702. [June 1, 2016]
Occupational Safety and Health Administration (OSHA).1999. Technical Manual (OTM), Section VI: Chapter 2 Controlling Occupational Exposure to Hazardous Drugs. Directive number: TED 01-00-015 [TED 1-0.15A]. Washington, DC: United States Department of Labor, Occupational Safety and Health Administration.http://www.osha.gov/dts/osta/otm/otm_vi/otm_vi_2.html#2.
Odio AD, Duharte AB, Carnesoltas D, Ibrahín L, García R, Loaces EL, Almarales DC, Mora YL, Cabrera LG. 2004. Efectos citogenéticos por exposición ocupacional a citostáticos. Rev Med Inst Mex Seguro Soc. 42(6):487–492.
Odraska P, Dolezalova L, Kuta J, Oravec M, Piler P, Synek S, Blaha L. 2014. Association of surface contamination by antineoplastic drugs with different working conditions in hospital pharmacies. Arch Environ Occup Health. 69(3):148–158. 10.1080/19338244.2013.763757 24325745
Odraska P, Dolezalova L, Piler P, Oravec M, Blaha L. 2011. Utilization of the solid sorbent media in monitoring of airborne cyclophosphamide concentrations and the implications for occupational hygiene. J Environ Monit. 13(5):1480–1487. 10.1039/c0em00660b 21468422
Oestreicher U, Stephan G, Glatzel M. 1990. Chromosome and SCE analysis in peripheral lymphocytes of persons occupationally exposed to cytostatic drugs handled with and without use of safety covers. Mutat Res. 242(4):271–277. 10.1016/0165-1218(90)90045-4 2255321
Organization for Economic Cooperation and Development (OECD).2016a. Test No. 473: In Vitro Mammalian Chromosomal Aberration Test. Paris, France: OECD Publishing.10.1787/9789264264649-en [2 October 2017]
Organization for Economic Cooperation and Development (OECD).2016b. Test No. 487: In Vitro Mammalian Cell Micronucleus Test. Paris, France: OECD Publishing.10.1787/9789264224438-en. [2 October 2017]
Organization for Economic Cooperation and Development (OECD).2016c. Test No. 489: In Vivo Mammalian Alkaline Comet Assay. Paris, France: OECD Publishing.10.1787/9789264264885-en [2 October 2017]
Pedersen-Bjergaard J. 2005. Insights into leukemogenesis from therapy-related leukemia. N Engl J Med. 352(15):1591–1594. 10.1056/NEJMe048336 15829541
Pedersen-Bjergaard J, Andersen MK, Christiansen DH, Nerlov C. 2002. Genetic pathways in therapy-related myelodysplasia and acute myeloid leukemia. Blood. 99(6):1909–1912. 10.1182/blood.V99.6.1909 11877259
Peelen S, Roeleveld N, Heederik D, Kromhout H, De Kort W. 1999. Reproductietoxische effecten bij ziekenhuispersoneel. The Hague, Netherlands: Dutch Ministry of Social Affairs and Employment; [Toxic effects on reproduction in hospital personnel]].
Pethran A, Schierl R, Hauff K, Grimm CH, Boos KS, Nowak D. 2003. Uptake of antineoplastic agents in pharmacy and hospital personnel. Part I: Monitoring of urinary concentrations. Int Arch Occup Environ Health. 76(1):5–10. 10.1007/s00420-002-0383-8 12592576
Pilger A, Kohler I, Stettner H, Mader RM, Rizovski B, Terkola R, Diem E, Franz-Hainzl E, Konnaris C, Valic E, 2000. Long-term monitoring of sister chromatid exchanges and micronucleus frequencies in pharmacy personnel occupationally exposed to cytostatic drugs. Int Arch Occup Environ Health. 73(7):442–448. 10.1007/s004200000164 11057412
Pohlová H, Cerna M, Rossner P. 1986. Chromosomal aberrations, SCE and urine mutagenicity in workers occupationally exposed to cytostatic drugs. Mutat Res. 174(3):213–217. 10.1016/0165-7992(86)90154-5 3724784
Poupeau C, Tanguay C, Plante C, Gagne S, Caron N, Bussieres JF. 2017. Pilot study of biological monitoring of four antineoplastic drugs among Canadian healthcare workers. J Oncol Pharm Pract. 23(5):323–332. 10.1177/1078155216643860 27084515
Quansah R, Jaakkola JJ. 2010. Occupational exposures and adverse pregnancy outcomes among nurses: A systematic review and meta-analysis. J Womens Health (Larchmt). 19(10):1851–1862. 10.1089/jwh.2009.1876 20809857
Ramphal R, Bains T, Goulet G, Vaillancourt R. 2015. Occupational exposure to chemotherapy of pharmacy personnel at a single centre. Can J Hosp Pharm. 68(2):104–112. 10.4212/cjhp.v68i2.1435 25964681
Ramphal R, Bains T, Vaillancourt R, Osmond MH, Barrowman N. 2014. Occupational exposure to cyclophosphamide in nurses at a single center. J Occup Environ Med. 56(3):304–312. 10.1097/JOM.0000000000000097 24481248
Ratner PA, Spinelli JJ, Beking K, Lorenzi M, Chow Y, Teschke K, Le ND, Gallagher RP, Dimich-Ward H. 2010. Cancer incidence and adverse pregnancy outcome in registered nurses potentially exposed to antineoplastic drugs. BMC Nurs. 9:15. 10.1186/1472-6955-9-15 20846432
Rekhadevi PV, Sailaja N, Chandrasekhar M, Mahboob M, Rahman MF, Grover P. 2007. Genotoxicity assessment in oncology nurses handling anti-neoplastic drugs. Mutagenesis. 22(6):395–401. 10.1093/mutage/gem032 17855733
Rodríguez-Montero HM, Argote-Pelegrino E, Díaz-Curbelo A, Cuétara-Lugo EB. 2016. Genotoxicity biomarkers for monitoring occupational exposure to antineoplastic drugs. J Pharm Pharmacogn Res. 4(3):122–133.
Rogers B, Emmett EA. 1987. Handling antineoplastic agents: Urine mutagenicity in nurses. Image J Nurs Sch. 19(3):108–113. 10.1111/j.1547-5069.1987.tb00604.x 3311973
Rombaldi F, Cassini C, Salvador M, Saffi J, Erdtmann B. 2009. Occupational risk assessment of genotoxicity and oxidative stress in workers handling anti-neoplastic drugs during a working week. Mutagenesis. 24(2):143–148. 10.1093/mutage/gen060 19011124
Rooney AA, Boyles AL, Wolfe MS, Bucher JR, Thayer KA. 2014. Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 122(7):711–718. 10.1289/ehp.1307972 24755067
Rooney AA, Cooper GS, Jahnke GD, Lam J, Morgan RL, Boyles AL, Ratcliffe JM, Kraft AD, Schunemann HJ, Schwingl P, 2016. How credible are the study results? Evaluating and applying internal validity tools to literature-based assessments of environmental health hazards. Environ Int. 92-93:617–629. 10.1016/j.envint.2016.01.005 26857180
Roth S, Norppa H, Jarventaus H, Kyyronen P, Ahonen M, Lehtomaki J, Sainio H, Sorsa M. 1994. Analysis of chromosomal aberrations, sister-chromatid exchanges and micronuclei in peripheral lymphocytes of pharmacists before and after working with cytostatic drugs. Mutat Res. 325(4):157–162. 10.1016/0165-7992(94)90079-5 7527908
Roussel C, Witt KL, Shaw PB, Connor TH. 2017. Meta-analysis of chromosomal aberrations as a biomarker of exposure in healthcare workers occupationally exposed to antineoplastic drugs. Mutat Res. 770:35–45. 10.1016/j.mrrev.2017.08.002 31416576
Rubeš J, Kucharova S, Vozdova M, Musilova P, Zudova Z. 1998. Cytogenetic analysis of peripheral lymphocytes in medical personnel by means of FISH. Mutat Res. 412(3):293–298. 10.1016/S1383-5718(97)00201-5 9600697
Sabatini L, Barbieri A, Lodi V, Violante FS. 2012. Biological monitoring of occupational exposure to antineoplastic drugs in hospital settings. Med Lav. 103(5):394–401. 23077799
Sarto F, Trevisan A, Tomanin R, Canova A, Fiorentino M. 1990. Chromosomal aberrations, sister chromatid exchanges, and urinary thioethers in nurses handling antineoplastic drugs. Am J Ind Med. 18(6):689–695. 10.1002/ajim.4700180607 2264567
Sasaki M, Dakeishi M, Hoshi S, Ishii N, Murata K. 2008. Assessment of DNA damage in Japanese nurses handling antineoplastic drugs by the comet assay. J Occup Health. 50(1):7–12. 10.1539/joh.50.7 18285639
Saurel-Cubizolles MJ, Job-Spira N, Estryn-Behar M. 1993. Ectopic pregnancy and occupational exposure to antineoplastic drugs. Lancet. 341(8854):1169–1171. 10.1016/0140-6736(93)91000-C 8098075
Schaumburg I, Olsen J. 1989. Time to pregnancy among Danish pharmacy assistants. Scand J Work Environ Health. 15:222–226. 10.5271/sjweh.1859 2781252
Schaumburg I, Olsen J. 1990 a. Congenital malformations and death among the offspring of Danish pharmacy assistants. Am J Ind Med. 18(5):555–564. 10.1002/ajim.4700180506 2244628
Schaumburg I, Olsen J. 1990 b. Risk of spontaneous abortion among Danish pharmacy assistants. Scand J Work Environ Health. 16(3):169–174. 10.5271/sjweh.1797 2382119
Schaumburg I, Olsen J. 1991. Birth weight and gestational age among children of Danish pharmacy assistants. J Epidemiol Commun H. 45(1):49–51. 10.1136/jech.45.1.49 2045745
Schierl R, Masini C, Groeneveld S, Fischer E, Bohlandt A, Rosini V, Paolucci D. 2016. Environmental contamination by cyclophosphamide preparation: Comparison of conventional manual production in biological safety cabinet and robot-assisted production by APOTECAchemo. J Oncol Pharm Pract. 22(1):37–45. 10.1177/1078155214551316 25227229
Schmaus G, Schierl R, Funck S. 2002. Monitoring surface contamination by antineoplastic drugs using gas chromatography-mass spectrometry and voltammetry. Am J Health Syst Pharm. 59(10):956–961. 10.1093/ajhp/59.10.956 12040735
Schreiber C, Radon K, Pethran A, Schierl R, Hauff K, Grimm CH, Boos KS, Nowak D. 2003. Uptake of antineoplastic agents in pharmacy personnel. Part II: Study of work-related risk factors. Int Arch Occup Environ Health. 76(1):11–16. 10.1007/s00420-002-0385-6 12592577
Selevan SG, Lindbohm ML, Hornung RW, Hemminki K. 1985. A study of occupational exposure to antineoplastic drugs and fetal loss in nurses. N Engl J Med. 313(19):1173–1178. 10.1056/NEJM198511073131901 4058490
Sessink PJ, Anzion RB, Van den Broek PH, Bos RP. 1992 a. Detection of contamination with antineoplastic agents in a hospital pharmacy department. Pharm Weekbl Sci. 14(1):16–22. 10.1007/BF01989220 1553250
Sessink PJ, Boer KA, Scheefhals AP, Anzion RB, Bos RP. 1992 b. Occupational exposure to antineoplastic agents at several departments in a hospital. Environmental contamination and excretion of cyclophosphamide and ifosfamide in urine of exposed workers. Int Arch Occup Environ Health. 64(2):105–112. 10.1007/BF00381477 1399019
Sessink PJ, Cerna M, Rossner P, Pastorkova A, Bavarova H, Frankova K, Anzion RB, Bos RP. 1994 a. Urinary cyclophosphamide excretion and chromosomal aberrations in peripheral blood lymphocytes after occupational exposure to antineoplastic agents. Mutat Res. 309(2):193–199. 10.1016/0027-5107(94)90092-2 7520976
Sessink PJ, Connor TH, Jorgenson JA, Tyler TG. 2011. Reduction in surface contamination with antineoplastic drugs in 22 hospital pharmacies in the US following implementation of a closed-system drug transfer device. J Oncol Pharm Pract. 17(1):39–48. 10.1177/1078155210361431 20156932
Sessink PJ, Friemel NS, Anzion RB, Bos RP. 1994 b. Biological and environmental monitoring of occupational exposure of pharmaceutical plant workers to methotrexate. Int Arch Occup Environ Health. 65(6):401–403. 10.1007/BF00383251 8034364
Sessink PJ, Kroese ED, van Kranen HJ, Bos RP. 1995. Cancer risk assessment for health care workers occupationally exposed to cyclophosphamide. Int Arch Occup Environ Health. 67(5):317–323. 10.1007/BF00385647 8543380
Sessink PJ, Leclercq GM, Wouters DM, Halbardier L, Hammad C, Kassoul N. 2015. Environmental contamination, product contamination and workers exposure using a robotic system for antineoplastic drug preparation. J Oncol Pharm Pract. 21(2):118–127. 10.1177/1078155214522840 24567041
Sessink PJ, Trahan J, Coyne JW. 2013. Reduction in surface contamination with cyclophosphamide in 30 US hospital pharmacies following implementation of a closed-system drug transfer device. Hosp Pharm. 48(3):204–212. 10.1310/hpj4803-204 24421463
Sessink PJ, Van de Kerkhof MC, Anzion RB, Noordhoek J, Bos RP. 1994 c. Environmental contamination and assessment of exposure to antineoplastic agents by determination of cyclophosphamide in urine of exposed pharmacy technicians: Is skin absorption an important exposure route? Arch Environ Health. 49(3):165–169. 10.1080/00039896.1994.9940377 8185386
Sessink PJ, Verplanke AJ, Herber RF, Bos RP. 1997 a. Occupational exposure to antineoplastic agents and parameters for renal dysfunction. Int Arch Occup Environ Health. 69(3):215–218. 10.1007/s004200050139 9049673
Sessink PJ, Wittenhorst BC, Anzion RB, Bos RP. 1997 b. Exposure of pharmacy technicians to antineoplastic agents: Reevaluation after additional protective measures. Arch Environ Health. 52(3):240–244. 10.1080/00039899709602893 9169636
Sessink PJM, Joost HCdR, Pierik FH, Anzion RBM, Bos RP. 1993. Occupational exposure of animal caretakers to cyclophosphamide. J Occup Med. 35(1):47–52. 8423503
Shahrasbi AA, Afshar M, Shokraneh F, Monji F, Noroozi M, Ebrahimi-Khojin M, Madani SF, Ahadi-Barzoki M, Rajabi M. 2014. Risks to health professionals from hazardous drugs in Iran: A pilot study of understanding of healthcare team to occupational exposure to cytotoxics. EXCLI J. 13:491–501. 26417276
Shepard TH, Lemire RJ. 2004. Catalog of Teratogenic Agents. Baltimore, MD: The Johns Hopkins University Press.
Shortridge LA, Lemasters GK, Valanis B, Hertzberg V. 1995. Menstrual cycles in nurses handling antineoplastic drugs. Cancer Nurs. 18(6):439–444. 10.1097/00002820-199512000-00003 8564939
Sibaud V, Lamant L, Maisongrosse V, Delord JP. 2013. [Adverse skin reactions induced by BRAF inhibitors: a systematic review]. Ann Dermatol Venereol. 140(8-9):510–520. 10.1016/j.annder.2013.02.031 24034635
Siderov J, Kirsa S, McLauchlan R. 2009. Surface contamination of cytotoxic chemotherapy preparation areas in Australian Hospital Pharmacy Departments. J Pharm Pract Res. 39(2):117–121.10.1002/j.2055-2335.2009.tb00434.x
Sill H, Olipitz W, Zebisch A, Schulz E, Wolfler A. 2011. Therapy-related myeloid neoplasms: Pathobiology and clinical characteristics. Br J Pharmacol. 162(4):792–805. 10.1111/j.1476-5381.2010.01100.x 21039422
Skov T, Maarup B, Olsen J, Rorth M, Winthereik H, Lynge E. 1992. Leukaemia and reproductive outcome among nurses handling antineoplastic drugs. Br J Ind Med. 49(12):855–861. 10.1136/oem.49.12.855 1472444
Sorsa M, Pyy L, Salomaa S, Nylund L, Yager JW. 1988. Biological and environmental monitoring of occupational exposure to cyclophosphamide in industry and hospitals. Mutat Res. 204(3):465–479. 10.1016/0165-1218(88)90042-0 3347217
Sottani C, Porro B, Comelli M, Imbriani M, Minoia C. 2010. An analysis to study trends in occupational exposure to antineoplastic drugs among health care workers. J Chromatogr B Analyt Technol Biomed Life Sci. 878(27):2593–2605. 10.1016/j.jchromb.2010.04.030 20478752
Sottani C, Porro B, Imbriani M, Minoia C. 2012. Occupational exposure to antineoplastic drugs in four Italian health care settings. Toxicol Lett. 213(1):107–115. 10.1016/j.toxlet.2011.03.028 21477641
Sottani C, Rinaldi P, Leoni E, Poggi G, Teragni C, Delmonte A, Minoia C. 2008. Simultaneous determination of cyclophosphamide, ifosfamide, doxorubicin, epirubicin and daunorubicin in human urine using high-performance liquid chromatography/electrospray ionization tandem mass spectrometry: Bioanalytical method validation. Rapid Commun Mass Spectrom. 22(17):2645–2659. 10.1002/rcm.3657 18666202
Spatari G, Fenga C, Minciullo PL, Di Pasquale G, Cacciola A, Ventura-Spagnolo E, Gangemi S.2005. Modification of interleukin-15 serum levels in workers exposed to chemotherapeutic agents. Mediators Inflamm. 2005(1):60-62. 10.1155/MI.2005.60
Stiller A, Obe G, Boll I, Pribilla W. 1983. No elevation of the frequencies of chromosomal alterations as a consequence of handling cytostatic drugs. Analyses with peripheral blood and urine of hospital personnel. Mutat Res. 121(3-4):253–259. 10.1016/0165-7992(83)90211-7 6621588
Stücker I, Caillard JF, Collin R, Gout M, Poyen D, Hemon D. 1990. Risk of spontaneous abortion among nurses handling antineoplastic drugs. Scand J Work Environ Health. 16(2):102–107. 10.5271/sjweh.1811 2353192
Stücker I, Hirsch A, Doloy T, Bastie-Sigeac I, Hemon D. 1986. Urine mutagenicity, chromosomal abnormalities and sister chromatid exchanges in lymphocytes of nurses handling cytostatic drugs. Int Arch Occup Environ Health. 57(3):195–205. 10.1007/BF00405788 3957439
Stücker I, Mandereau L, Hemon D. 1993. Relationship between birthweight and occupational exposure to cytostatic drugs during or before pregnancy. Scand J Work Environ Health. 19(3):148–153. 10.5271/sjweh.1488 8367691
Sugiura S, Asano M, Kinoshita K, Tanimura M, Nabeshima T. 2011 a. Risks to health professionals from hazardous drugs in Japan: A pilot study of environmental and biological monitoring of occupational exposure to cyclophosphamide. J Oncol Pharm Pract. 17(1):14–19. 10.1177/1078155209358632 20179165
Sugiura S, Nakanishi H, Asano M, Hashida T, Tanimura M, Hama T, Nabeshima T. 2011 b. Multicenter study for environmental and biological monitoring of occupational exposure to cyclophosphamide in Japan. J Oncol Pharm Pract. 17(1):20–28. 10.1177/1078155210369851 20472603
Suspiro A, Prista J. 2011. Biomarkers of occupational exposure do anticancer agents: A minireview. Toxicol Lett. 207(1):42–52. 10.1016/j.toxlet.2011.08.022 21911042
Tanimura M, Yamada K, Sugiura S, Mori K, Nagata H, Tadokoro K, Miyake T, Hamaguchi Y, Sessink P, Nabeshima T. 2009. An environmental and biological study of occupational exposure to cyclophosphamide in the pharmacy of a japanese community hospital designated for the treatment of cancer. J Health Sci. 55(5):750–756.10.1248/jhs.55.750
Taskinen H, Kyyronen P, Hemminki K, Hoikkala M, Lajunen K, Lindbohm ML. 1994. Laboratory work and pregnancy outcome. J Occup Environ Med. 36(3):311–319. 10.1097/00043764-199403000-00008 8195901
Taskinen H, Lindbohm ML, Hemminki K. 1986. Spontaneous abortions among women working in the pharmaceutical-industry. Br J Ind Med. 43(3):199–205. 10.1136/oem.43.3.199 3947584
Teschke K, Olshan AF, Daniels JL, De Roos AJ, Parks CG, Schulz M, Vaughan TL. 2002. Occupational exposure assessment in case-control studies: Opportunities for improvement. Occup Environ Med. 59(9):575–593, discussion 594. 10.1136/oem.59.9.575 12205230
Testa A, Giachelia M, Palma S, Appolloni M, Padua L, Tranfo G, Spagnoli M, Tirindelli D, Cozzi R. 2007. Occupational exposure to antineoplastic agents induces a high level of chromosome damage. Lack of an effect of GST polymorphisms. Toxicol Appl Pharmacol. 223(1):46–55. 10.1016/j.taap.2007.05.006 17631926
Thiringer G, Granung G, Holmen A, Hogstedt B, Jarvholm B, Jonsson D, Persson L, Wahlstrom J, Westin J. 1991. Comparison of methods for the biomonitoring of nurses handling antitumor drugs. Scand J Work Environ Health. 17(2):133–138. 10.5271/sjweh.1724 2047815
Thulin H, Sundberg E, Hansson K, Cole J, Hartley-Asp B. 1995. Occupational exposure to nor-nitrogen mustard: Chemical and biological monitoring. Toxicol Ind Health. 11(1):89–97. 10.1177/074823379501100108 7652754
Tigha Bouaziz N, Tourab D, Nezzal AM. 2016. Study of cardiovascular morbidity in nurses exposed to cytostatic drugs: Multivaried approach analysis. Ann Cardiol Angeiol (Paris). 65(3):179–184. 10.1016/j.ancard.2016.04.014 27209491
Tompa A, Biro A, Jakab M. 2016. Genotoxic monitoring of nurses handling cytotoxic drugs. Asia Pac J Oncol Nurs. 3(4):365–369. 10.4103/2347-5625.196484 28083554
Tompa A, Jakab M, Biro A, Magyar B, Fodor Z, Klupp T, Major J. 2006 a. Chemical safety and health conditions among Hungarian hospital nurses. Ann N Y Acad Sci. 1076:635–648. 10.1196/annals.1371.054 17119241
Tompa A, Jakab M, Biro A, Major J. 2015. [Genetic and immune-toxicologic studies on abnormal thyroid functions in hospital employees exposed to cytostatic drugs]. Orv Hetil. 156(2):60–66. 10.1556/oh.2015.30064 25563683
Tompa A, Magyar B, Toth F, Biro A, Fodor Z, Jakab M, Major J.2006b. The state of health of oncology nurses characterized by genetic and immunotoxicologic biomarkers. Magy Onkol. 50(2):153–161. 16888679
Touzin K, Bussieres JF, Langlois É, Lefebvre M. 2009. Evaluation of surface contamination in a hospital hematology-oncology pharmacy. J Oncol Pharm Pract. 15(1):53–61. 10.1177/1078155208096904 18772214
Turci R, Minoia C, Sottani C, Coghi R, Severi P, Castriotta C, Del Bianco M, Imbriani M. 2011. Occupational exposure to antineoplastic drugs in seven Italian hospitals: The effect of quality assurance and adherence to guidelines. J Oncol Pharm Pract. 17(4):320–332. 10.1177/1078155210381931 20823049
Turci R, Sottani C, Ronchi A, Minoia C. 2002. Biological monitoring of hospital personnel occupationally exposed to antineoplastic agents. Toxicol Lett. 134(1-3):57–64. 10.1016/S0378-4274(02)00163-7 12191861
Ündeğer U, Basaran N, Kars A, Guc D. 1999. Assessment of DNA damage in nurses handling antineoplastic drugs by the alkaline COMET assay. Mutat Res. 439(2):277–285. 10.1016/S1383-5718(99)00002-9 10023083
Ursini CL, Cavallo D, Colombi A, Giglio M, Marinaccio A, Iavicoli S. 2006. Evaluation of early DNA damage in healthcare workers handling antineoplastic drugs. Int Arch Occup Environ Health. 80(2):134–140. 10.1007/s00420-006-0111-x 16761155
Valanis B, Vollmer W, Labuhn K, Glass A. 1997. Occupational exposure to antineoplastic agents and self-reported infertility among nurses and pharmacists. J Occup Environ Med. 39(6):574–580. 10.1097/00043764-199706000-00013 9211216
Valanis B, Vollmer WM, Steele P. 1999. Occupational exposure to antineoplastic agents: Self-reported miscarriages and stillbirths among nurses and pharmacists. J Occup Environ Med. 41(8):632–638. 10.1097/00043764-199908000-00004 10457505
Valanis BG, Hertzberg V, Shortridge L. 1987. Antineoplastic drugs. Handle with care. AAOHN J. 35(11):487–492. 3675751
Valanis BG, Vollmer WM, Labuhn KT, Glass AG. 1993 a. Acute symptoms associated with antineoplastic drug handling among nurses. Cancer Nurs. 16(4):288–295. 10.1097/00002820-199308000-00005 8402605
Valanis BG, Vollmer WM, Labuhn KT, Glass AG. 1993 b. Association of antineoplastic drug handling with acute adverse effects in pharmacy personnel. Am J Hosp Pharm. 50(3):455–462. 10.1093/ajhp/50.3.455 8442461
Valverde M, Rojas E. 2009. Environmental and occupational biomonitoring using the Comet assay. Mutat Res. 681(1):93–109. 10.1016/j.mrrev.2008.11.001 19056514
Van Calsteren K, Heyns L, De Smet F, Van Eycken L, Gziri MM, Van Gemert W, Halaska M, Vergote I, Ottevanger NFA. 2010. Cancer during pregnancy: An analysis of 215 patients emphasizing the obstetrical and the neonatal outcomes. J Clin Oncol. 28(4):683–689. 10.1200/JCO.2009.23.2801 19841323
Vandenbroucke J, Robays H. 2001. How to protect environment and employees against cytotoxic agents, the UZ Ghent experience. J Oncol Pharm Pract. 6:146–152.10.1177/107815520100600403
Villa AF, El Balkhi S, Aboura R, Sageot H, Hasni-Pichard H, Pocard M, Elias D, Joly N, Payen D, Blot F, 2015. Evaluation of oxaliplatin exposure of healthcare workers during heated intraperitoneal perioperative chemotherapy (HIPEC). Ind Health. 53(1):28–37. 10.2486/indhealth.2014-0025 25327298
Villarini M, Dominici L, Fatigoni C, Muzi G, Monarca S, Moretti M. 2012. Biological effect monitoring in peripheral blood lymphocytes from subjects occupationally exposed to antineoplastic drugs: Assessment of micronuclei frequency. J Occup Health. 54(6):405–415. 10.1539/joh.12-0038-OA 22986622
Villarini M, Dominici L, Piccinini R, Fatigoni C, Ambrogi M, Curti G, Morucci P, Muzi G, Monarca S, Moretti M. 2011. Assessment of primary, oxidative and excision repaired DNA damage in hospital personnel handling antineoplastic drugs. Mutagenesis. 26(3):359–369. 10.1093/mutage/geq102 21112930
Villarini M, Gianfredi V, Levorato S, Vannini S, Salvatori T, Moretti M.2016. Occupational exposure to cytostatic/antineoplastic drugs and cytogenetic damage measured using the lymphocyte cytokinesis-block micronucleus assay: A systematic review of the literature and meta-analysis. Mutat Res. 770(Pt A):35-45. 10.1016/j.mrrev.2016.05.001
Waksvik H, Klepp O, Brogger A. 1981. Chromosome analyses of nurses handling cytostatic agents. Cancer Treat Rep. 65(7-8):607–610. 7248981
Walusiak J, Wagrowska-Koski E, Palczynski C. 2003. [Health effects of occupational exposure to cytostatics in medicinal personnel in the light of compulsory prophylactics: a cross-sectional study]. Med Pr. 54(3):229–236. 14669575
Wick C, Slawson MH, Jorgenson JA, Tyler LS. 2003. Using a closed-system protective device to reduce personnel exposure to antineoplastic agents. Am J Health Syst Pharm. 60(22):2314–2320. 10.1093/ajhp/60.22.2314 14652980
Yager JW, Sorsa M, Selvin S. 1988. Micronuclei in cytokinesis-blocked lymphocytes as an index of occupational exposure to alkylating cytostatic drugs. IARC Sci Publ.(89):213–216. 3198202
Yang D, Xu S, Wang J. 2002 a. [The study of DNA damage of peripheral lymphocytes in the nurses occupationally exposed to anticancer drugs]. Zhonghua Lao Dong Wei Sheng Zhi Ye Bing Za Zhi. 20(3):197–199. 14694639
Yang DP, Xu SJ, Wang JX. 2002 b. Study on chromosome damage among nurses occupationally exposed to antineoplastic drugs in an oncology department. Biomed Environ Sci. 15(3):268–270. 12500668
Yin H, Xu XQ, Lin LY. 2010. [DNA damage of antineoplastic drugs exposure on nurses]. Zhonghua Lao Dong Wei Sheng Zhi Ye Bing Za Zhi. 28(3):218–219. 20635702
Yoshida J, Koda S, Nishida S, Nakano H, Tei G, Kumagai S. 2013. Association between occupational exposure and control measures for antineoplastic drugs in a pharmacy of a hospital. Ann Occup Hyg. 57(2):251–260. 10.1093/annhyg/mes061 23002276
Yoshida J, Kosaka H, Tomioka K, Kumagai S. 2006. Genotoxic risks to nurses from contamination of the work environment with antineoplastic drugs in Japan. J Occup Health. 48(6):517–522. 10.1539/joh.48.517 17179646
Yoshida J, Tei G, Mochizuki C, Masu Y, Koda S, Kumagai S. 2009. Use of a closed system device to reduce occupational contamination and exposure to antineoplastic drugs in the hospital work environment. Ann Occup Hyg. 53(2):153–160. 10.1093/annhyg/men081 19261696
Yuki M, Ishida T, Sekine S. 2015. Secondary exposure of family members to cyclophosphamide after chemotherapy of outpatients with cancer: A pilot study. Oncol Nurs Forum. 42(6):665–671. 10.1188/15.ONF.42-06AP 26488834
Zack E. 2012. Chemotherapy and biotherapeutic agents for autoimmune diseases. Clin J Oncol Nurs. 16(4):E125–E132. 10.1188/12.CJON.E125-E132 22842697
Zare Sakhvidi MJ, Hajaghazadeh M, Mostaghaci M, Mehrparvar AH, Zare Sakhvidi F, Naghshineh E. 2016. Applicability of the comet assay in evaluation of DNA damage in healthcare providers’ working with antineoplastic drugs: A systematic review and meta-analysis. Int J Occup Environ Health. 22(1):52–67. 10.1080/10773525.2015.1123380 27110842
Zhang X, Zheng Q, Lv Y, An M, Zhang Y, Wei Y, Feng W. 2016. Evaluation of adverse health risks associated with antineoplastic drug exposure in nurses at two Chinese hospitals: The effects of implementing a pharmacy intravenous admixture service. Am J Ind Med. 59(4):264–273. 10.1002/ajim.22553 26898889
Ziegler E, Mason HJ, Baxter PJ. 2002. Occupational exposure to cytotoxic drugs in two UK oncology wards. Occup Environ Med. 59(9):608–612. 10.1136/oem.59.9.608 12205233