# Conclusions

The NTP evaluation concluded that there is a moderate level of evidence for spontaneous abortion and genetic toxicity associated with occupational exposure to cancer chemotherapy agents. Data on other health effects was inadequate to reach level-of-evidence conclusions due to limitations in the body of evidence (e.g., few studies, small case sizes and, in some cases, heterogeneity in the outcomes assayed). Environmental monitoring and biomonitoring studies report that workplace contamination with cancer chemotherapy agents continues to occur, although maximum levels of surface contamination detected have declined. Considering the potential for exposure, the association between exposure and DNA damage in workers, and the widespread use of cancer chemotherapy agents (e.g., veterinary use, home health care), there is a continued need to improve exposure characterization (e.g., improved analytical chemistry methods, daily diaries of drug handling) and health surveillance as well as to identify the most effective safe handling practices and exposure control equipment to reduce potential adverse health outcomes of occupationally exposed personnel.