# Discussion

Based on a systematic review of the literature, NTP concludes that there is a moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with spontaneous abortion and genetic toxicity. The review identified several studies evaluating other health outcomes; however, there were few studies available for most organ systems and there was heterogeneity in the outcomes assessed for many of them, which limited the ability to compare results between studies. Despite the issuance of guidelines for safe handling of cancer chemotherapy, increased usage of personal protective equipment, and improved safety containment equipment, studies of environmental monitoring and biomonitoring demonstrated that workplace contamination and exposure of workers continues to occur even as recently as from 2011 to 2016.

A clear majority of the genetic toxicity studies in the NTP evaluation reported significantly higher levels of structural CA, MN induction, and DNA damage measured by the comet assay. Fourteen of the 18 studies evaluating more than one assay reported significantly greater DNA damage in exposed subjects relative to unexposed subjects. Most of the studies reporting no effect of occupational exposure also documented the availability of containment devices (e.g., ducted biological safety cabinets), isolated rooms for drug preparation and/or the high usage of personnel protective equipment (e.g., aprons, gloves, and respiratory protection) among occupationally exposed personnel. The NTP conclusion of a moderate level of evidence for genetic toxicity reflects moderate confidence in the body of evidence including consideration of study quality in terms of risk of bias and other factors that could decrease or increase confidence. The inclusion of risk-of-bias assessment in this evaluation is more extensive than previous study quality assessment methods (e.g., “quality” scoring by consideration of study features) used in three recent meta-analyses of the genetic toxicity and occupational exposure (Roussel et al. 2017; Villarini et al. 2016; Zare Sakhvidi et al. 2016). A recent meta-analysis of studies reported that occupational exposure to cancer chemotherapy agents was associated with a significantly higher occurrence of MN induction compared to unexposed subjects (Villarini et al. 2016). The authors reported an overall meta-estimate for MN frequency of 1.67 (95% CI = 1.41–1.98; analyzed as a random ratio of means) for exposed subjects compared to control subjects, and the analysis included studies measuring both the number of cells with MN as well as studies measuring the number of MN (Villarini et al. 2016). Another recent systematic review and meta-analysis of healthcare providers handling cancer chemotherapy agents reported a significantly higher DNA damage index (measured by the comet assay) compared to unexposed workers (Zare Sakhvidi et al. 2016); the authors reported an overall meta-estimate of DNA damage index of 1.93 (95% CI = 1.15–2.71; analyzed as an estimated standardized mean difference). Finally, a meta-analysis of healthcare workers occupationally exposed to cancer chemotherapy agents reported a significantly higher rate of cells with CA or number of CA per cells scored compared to unexposed subjects (Roussel et al. 2017). The overall test results for a pooled standardized mean difference were 1.006, z = 4.25, p < 0.0001 (Roussel et al. 2017). The overall results of these three meta-analyses corroborated the NTP’s level-of-evidence conclusions for genetic toxicity in the current evaluation.

Many cancer chemotherapy agents are known or reasonably anticipated to be human carcinogens based on the induction of secondary cancers in patients therapeutically treated with these drugs for cancer and toxicological studies in laboratory rodents (IARC 1966; 1980; 1981; 1990; 2000; 2012; Mistry et al. 2005; NTP 2016 ; Pedersen-Bjergaard 2005). Therapy-related acute myeloid leukemia (t-AML) is the most frequently diagnosed secondary cancer and was recently reported to occur 4.70 times more frequently in patients previously administered cancer chemotherapy than in the general population of the United States in 1975–2008 (Morton et al. 2013). Secondary cancers of the bladder, lung, skin, and uterus are also reported to occur more frequently following administration of cancer chemotherapy agents to patients or laboratory animal models, including following treatment with alkylating agents, antimetabolites, and topoisomerase II inhibitors (IARC 2012). The data on cancer incidence evaluated in the NTP monograph were inadequate to reach level-of-evidence conclusions (three studies) due to the availability of only one or two studies and a low number of cases. Two risk assessments estimated the risk of leukemia, skin cancer, and bladder cancer in nurses handling cyclophosphamide based on their average measurements of dermal exposure (Fransman et al. 2014) or urine levels (Sessink et al. 1995) and cancer incidence in experimental animal studies or primary and secondary cancers in patients receiving cyclophosphamide as a treatment for cancer. Both risk assessments reported that the estimated cancer incidence based on average occupational exposure was within the prohibitory risk level (i.e., no risk higher than 100 per million a year); however, the authors point out that these assessments were based on only one cancer chemotherapy agent when many are used, and there are individuals exposed to higher than average levels, which could increase their risk of developing cancer.

Adverse reproductive outcomes were the second most frequently evaluated health outcome category associated with occupational exposure to cancer chemotherapy. There is strong biological support and concern for potential adverse reproductive health outcomes because many cancer chemotherapy agents are known teratogens or embryo toxicants as identified in toxicology studies in animals and observational studies of patients receiving these drugs for treatment of cancer and other health conditions (NTP 2016; Shepard and Lemire 2004). The NTP monograph observed a higher occurrence of spontaneous abortions in nursing and pharmacy personnel responsible for handling cancer chemotherapy agents compared to controls. One recent review and meta-analysis (Dranitsaris et al. 2005) and a systematic review (Quansah and Jaakkola 2010) of healthcare providers working with cancer chemotherapy agents reached similar conclusions that exposure was associated with spontaneous abortions. The NTP conclusions extended the evaluation of spontaneous abortion by these two reviews (Dranitsaris et al. 2005; Quansah and Jaakkola 2010) by assessing the quality of the studies (Dranitsaris et al. (2005) did not include this step), and by the addition of studies published since the previous reviews (Lawson et al. 2012; Zhang et al. 2016). While other reproductive outcomes were reported in the published literature, there was insufficient evidence to reach level-of-evidence conclusions on the body of literature for a variety of reasons. For example, while 12 studies assessed congenital malformations, only three studies limited exposure to the first trimester and the results were inconsistent. Several studies reported no association of stillbirth with occupational exposure to cancer chemotherapy agents. While the lack of an association of stillbirth with occupational exposure to cancer chemotherapy was contrary to the observed higher rate of stillbirth in women administered cancer chemotherapy during pregnancy reviewed collectively in a recent NTP monograph (NTP 2013), the results on stillbirth risk with occupational exposure to cancer chemotherapy appear to be consistent with the results of two pregnancy registry studies of women exposed to cancer chemotherapy for treatment of cancer compared to pregnancies of unexposed cancer patients (Cardonick et al. 2010; Van Calsteren et al. 2010). However, it was determined that the body of evidence was inadequate for reaching level-of-evidence conclusions due to the inability to reach a high level of confidence needed to determine no effect, given the designs of the available studies (retrospective cohort and cross-sectional studies) and the lack of dose-response data (see OHAT Handbook for Conducting a Literature-Based Health Assessment [[underlined: https://ntp.niehs.nih.gov/go/systematic_review]]).

## Impact of Exposure Protection Efforts

Several studies suggested that adherence to good practices, implementation of safety containment equipment, and other exposure mitigation efforts can be successful at reducing occupational exposure and, thus, lowering the potential for adverse health outcomes. While studies only measuring environmental monitoring and/or biomonitoring of occupational exposure to cancer chemotherapy agents following improvements to reduce exposure were not systematically reviewed in this report, the studies are briefly mentioned here because of the importance that reducing occupational exposure has in ultimately reducing adverse health outcomes. For example, a study of four hospital pharmacies in Italy from 1998 to 2007 observed decreases in positive urine samples from pharmacy staff and wipe samples of the work environment that coincided with the implementation of safe handling guidelines for handling these drugs in 1999, and the usage of personal protective equipment (e.g., chemotherapy gloves, gowns, hair covers) in the 2000s (Sottani et al. 2010). Reductions in the levels of cancer chemotherapy agents detected in exposed workers’ urine samples or environmental monitoring of workspaces where cancer chemotherapy drugs are prepared and/or handled have also been observed with the implementation of a centralized system for the preparation of doses (Sabatini et al. 2012) or closed-system drug transfer devices, which limit the chance of drug spills or the escape of vapor during drug preparation and intravenous drug administration (Sessink et al. 2011; Sessink et al. 2013; Wick et al. 2003; Yoshida et al. 2009).

Of the studies reporting health outcomes that were all systematically reviewed, only one study assessed health outcomes before and after implementation of exposure control methods. The study in China reported a significant reduction in a variety of adverse health outcomes (i.e., incidence of spontaneous abortion, infertility, and hematotoxicity) in oncology nurses 2 years after the implementation of a PIVAS at the hospital, compared to the frequency of these adverse health outcomes at the time the PIVAS was first established (Zhang et al. 2016). In addition, several studies reporting no difference in the number of MN between occupationally exposed employees and controls attributed this lack of effect to the documented usage of personal protective equipment, available biological safety cabinets, and/or centralized units for drug preparation by the occupationally exposed workers (Bolognesi et al. 2005; Cavallo et al. 2005; Ensslin et al. 1997; Harris et al. 1992; Laffon et al. 2005; Pilger et al. 2000; Thiringer et al. 1991).

## Limitations of the Evidence Base

### Study Design Limitations

Recall bias can occur in retrospective cohort studies and case-control studies, and most of the studies reporting on reproductive outcomes or cancer in the NTP monograph were retrospective. Recall bias is most likely when both the exposure and disease status are known at time of study, and it is recommended that the study design does not explicitly reveal the purpose of questions in an interview or survey and/or uses a validated questionnaire (Andrews et al. 2002). For example, parents of children with autism associated the condition with exposure to the MMR (mumps-measles-rubella) vaccine after this hypothesis was published in 1998; whereas, parents did not associate this exposure with MMR prior to publication of the hypothesis (Andrews et al. 2002). However, studies report that women have accurate recall of pregnancy outcomes (Axelsson 1990; Joffe et al. 1993), and nurses have accurate recall of pregnancy outcomes and health data for many outcomes (Colditz et al. 1986; Colditz et al. 1987). Thus, studies of reproductive health and major disease outcomes in medical personnel are considered of greater reliability despite the retrospective study design (Axelsson 1990). Furthermore, a study of pharmacists demonstrated accurate recall of occupational exposure to cancer chemotherapy agents using a self-reported questionnaire was corroborated by their supervisor (McDiarmid et al. 1992). Many of the studies reporting health outcomes were of the cross-sectional study design, and this study design generally cannot assure that exposure occurred prior to outcome so reverse causation is possible. Following the Hill considerations on causality (which are embedded in the OHAT adaptations of the GRADE approach to assessing confidence in the body evidence used here), there is less confidence that the relationship between exposure and outcome is causal. The initial confidence rating for cross-sectional studies is generally low confidence based on only two features: individual outcomes assessed, and that a comparison group was used. In this evaluation, the cross-sectional studies of genetic toxicity were rated moderate initial confidence, based primarily on the rapidity of the genetic toxicity mechanism (hours to days). Therefore, for genetic toxicity, NTP considered cross-sectional studies to provide sufficiently clear evidence that exposure preceded outcome, based on the fact that the studies measured rapidly developing health outcomes (hours to days versus years), the subjects worked full time the week the samples were drawn, and most subjects had worked from 1 month to a year prior to the study.

### Exposure Characterization

A potential limitation of the exposure characterization of occupational exposure to cancer chemotherapy agents is the nature of the primary source of information on exposure: employment history or historical industrial hygiene data. The utility of this information is improved by use of validated questionnaires regarding work activities (e.g., drugs handled, quantities, frequency) and unusual events (i.e., accidents and needle sticks) that may influence exposure during the study period. In fact, the use of a daily diary of work activities that has been validated to estimate exposure levels has been proposed for use with genetic toxicity outcomes by the World Health Organization’s International Programme on Chemical Safety (Albertini et al. 2000). The daily diary has been proposed as the most useful source to construct exposure metrics based on the level of exposure (drugs handled, frequency of handling), use of protective measures (personal protective equipment, ventilation), variances in procedures, and adverse events (Nieuwenhuijsen 2003). Biomonitoring of urine or blood samples for levels of a cancer chemotherapy agent(s) or its metabolites may be helpful to confirm that exposure occurred, but likely only provide confirmation of only the most recent exposure. Environmental monitoring of the work environment (e.g., surface wipes, air samples, dermal pads) is a useful tool to identify contaminated areas, and, thus, the potential for exposure; however, it may or may not relate to actual internal dose due to use of safety equipment (e.g., biological safety cabinets) or personal protective equipment (e.g., gloves, mask, gown). A recent review of swipe tests compared to biomonitoring results did not find a statistically significant correlation (Kibby 2017); however, the authors did observe decreases in the levels of surface contamination detected in wipe samples and urine monitoring following improvements to personal protective equipment and safe handling techniques. Another challenge for biomonitoring and environmental monitoring assessments is the fact that most occupational exposures in the medical or veterinary setting are likely to multiple cancer chemotherapy agents, while most monitoring assessments are designed to test one or a handful of agents as surrogates of the total cancer chemotherapy exposure.

### Challenges in Evaluating Reproductive Toxicity

There were many challenges in the outcome assessment of reproductive toxicity associated with occupational exposure to cancer chemotherapy. The occurrence of some pregnancy outcomes, such as major congenital malformations, is relatively rare; thus, large sample sizes are required to detect a difference between exposed and unexposed subjects. Some adverse reproductive health outcomes may be difficult to accurately detect and, thus, may not always be fully documented in the workers’ medical records (e.g., early spontaneous abortion). However, several studies have determined that women have accurate recall of pregnancy outcomes, including spontaneous abortion (Axelsson 1990) and time to pregnancy (Cooney et al. 2009). Finally, occupational exposure to cancer chemotherapy agents was not a frequently reported exposure during pregnancy. For example, some studies evaluated the association of fetal loss or congenital malformations with a woman’s occupation (Lorente et al. 2000; McDonald et al. 1988b), or occupational exposures to a variety of hazardous chemicals in hospitals (Hemminki et al. 1985; McAbee et al. 1993), the pharmaceutical manufacturing industry (Taskinen et al. 1986), or laboratory work (Taskinen et al. 1994). The total number of workers handling cancer chemotherapy agents in these studies was small and may not be representative of the actual prevalence of fetal loss or congenital malformations in the larger population of exposed workers.

## Limitations of the Systematic Review

There were some limitations of the current systematic review. The NTP evaluation excluded studies that did not include a comparator group due to concerns that knowledge of the outcome may have influenced the association with occupational exposure to cancer chemotherapy; thus, the evaluation did not include 21 studies (e.g., case reports, case series or surveys) that reported on a variety of health outcomes, including acute effects, asthma, cancer, and reproduction. However, these studies could be useful to identify additional health outcomes that could be evaluated in future research. Secondly, the literature search may not have identified all possible studies reporting on health outcomes following occupational exposure to cancer chemotherapy, particularly if journals were not indexed for the databases that NTP searched (i.e., PubMed, Scopus, and Embase). For example, NTP identified one reference reporting on CA and MN induction in peripheral lymphocytes (Ferguson et al. 1988) and another reference reporting on MN induction in buccal cells (Odio et al. 2004) from the reference lists of recently published papers, as NTP completed its evaluation. NTP is confident it has identified the majority of papers published on these genetic toxicity outcomes and have confirmed that the results of the additional two papers reporting on CA and MN induction would not change NTP’s level-of-evidence conclusions for these endpoints or genetic toxicity overall. Finally, NTP’s literature search may not have captured the entire body of literature on environmental monitoring (e.g., contamination of drug vials, gloves) and biomonitoring studies because the literature search was primarily focused on identifying the health outcome studies. However, NTP is confident its review of this literature provides an accurate characterization of the levels of environmental contamination in the workplace and the prevalence of positive biomonitoring studies for a surrogate exposure (i.e., the commonly used cancer chemotherapy agent cyclophosphamide).

## Research Needs

The NTP evaluation identified several data gaps and research needs to improve the scientific community’s understanding of potential health risks associated with occupational exposure to cancer chemotherapy agents:

1. Expand the range of health outcomes assessed in evaluations of occupational exposure to cancer chemotherapy agents, including bone marrow function (e.g., hematotoxicity), and toxicity of the cardiovascular, kidney, and liver systems. Although some reports of these health outcomes were identified in the NTP evaluation, there was insufficient evidence to evaluate whether or not there is an association with occupational exposure to chemotherapy.
2. Expand the array of workers studied for health effects associated with occupational exposure to cancer chemotherapy agents to include support personnel (e.g., waste collectors, hospital cleaning and laundry staff), home health aides, emergency responders, and veterinary clinic staff. In addition, family caregivers could be studied as exposure to this population has been documented. There were very few studies reporting on the health outcomes or exposure levels of these worker populations, including family caregivers, in the NTP evaluation.
3. Expand the evaluation of health effects associated with occupational exposure to cancer chemotherapy agents to include emerging cancer drug therapies that target specific genes, transcription factors, or signaling molecules. Side effects have been observed in patients following administration of newer targeted drug therapies, such as monoclonal antibodies (Halsen and Kramer 2011) and B-Raf proto-oncogene inhibitors (Sibaud et al. 2013). Most studies in the NTP evaluation focused on health outcomes associated with occupational exposure primarily to antineoplastic agents.
4. Conduct more prospective cohort studies versus retrospective cohort or case-control studies to reduce the potential for recall bias in identifying occupational exposure, especially for endpoints such as cancer. Cross-sectional studies, which were among the most common study design in the NTP evaluation, also present concerns about possible reverse causation. Prospective cohort studies allow for a baseline measure of health outcomes of all subjects in the study to which subsequent health evaluations can be compared.
5. Improve exposure characterization methods:
  a. Advance analytical chemistry methods for detection of cancer chemotherapy agents to lower the LOD, allow for simultaneous detection of multiple cancer chemotherapy agent exposures (e.g., most oncology nurses and pharmacists handle multiple agents), and develop techniques to detect metabolites of the agents (e.g., most biomonitoring assays only measure the parent agent). While many of the environmental monitoring studies did evaluate more than one agent, most of the biomonitoring studies assessed only one agent. Those studies that assessed multiple agents tended to evaluate them sequentially. Very few biomonitoring studies (16 of 82 studies) tested for metabolites of cancer chemotherapy agents.
  b. Continue research on ways to effectively use daily diaries that are assessed and validated to estimate exposure levels (e.g., frequency of handling, dose levels, as well as incorporation of information on use of personal protective equipment and safety containment equipment). Although many studies collected information about drugs handled, doses, and frequency of handling, these data were not generally incorporated into the association with the health outcome. In contrast, two studies of the same population that characterized exposure by daily diary allowed for an analysis that considered the individual’s health outcome by the individual’s drug handling activity (McDiarmid et al. 2010; McDiarmid et al. 2014).
6. Design studies to evaluate the effectiveness of different types of personal protective equipment and other exposure control strategies (e.g., closed-system drug transfer devices, centralized drug preparation units) to reduce occupational exposure (environmental monitoring and biomonitoring) and to reduce possible adverse health outcomes. The impact of exposure control strategies was evaluated in only one study reporting on health outcomes and a handful of environmental monitoring and/or biomonitoring studies reviewed in the NTP monograph.