# Results and Evidence Synthesis

## Literature Search Results

The electronic database searches retrieved 5,584 unique references, and an additional 58 references were identified by experts and by reviewing published reviews and reference lists of included studies. From the total references retrieved: 4,433 were excluded during the title-and-abstract screening and 953 were excluded during the full-text review. The screening results are outlined in a study selection diagram with reasons for exclusion documented at the full-text review (Figure 4). A total of 110 studies reported primary or secondary health outcomes, which were data extracted and processed for risk-of-bias (Objective 1); the included health studies are listed in Appendix B, including 12 non-English language studies that were professionally translated to English language. A total number of 171 studies evaluated contamination of the workplace (environmental monitoring) or biomonitoring of personnel handling cancer chemotherapy agents (Objective 2), including 18 studies that reported on both environmental monitoring and biomonitoring.

Figure 4

Study Selection Diagram

The total number of included studies was 251, including 110 studies reporting on health outcomes. Seventeen studies on health outcome also reported on biomonitoring (n = 7), environmental monitoring (n = 3), or both (n = 7). Eighteen exposure studies reported on both biomonitoring and environmental monitoring.

Twenty-one studies were excluded from the body of evidence of health effects in reaching health effects conclusions because of methodological considerations and the relatively large body of evidence that reported data using preferred methods. Studies were excluded from the evidence synthesis step because they did not use the preferred measurements for genetic toxicity, including: the inclusion of gaps for CA (Goloni-Bertollo et al. 1992; Mahrous et al. 1998), and the number of binucleated lymphocytes with one, two, three or four micronuclei without analyzing the total binucleated lymphocytes with micronuclei (Fucic et al. 1998). Eight studies, including Fucic et al. (1998), reporting on CA were excluded because they only reported the number of individual types of CA per 100 cells, instead of the total number of CA per 100 cells (Benhamou et al. 1988; Boughattas et al. 2010; Fucic et al. 1998; Harris et al. 1992; Oestreicher et al. 1990; Sarto et al. 1990; Stiller et al. 1983; Waksvik et al. 1981). While the OECD protocol recommends reporting of the frequency of individual CA (OECD 2016a), these studies did not consistently report on the same types of individual CA or grouped data (e.g., chromosome breaks, chromatid breaks), which made it difficult to compare between the studies. Six studies were excluded because they included preliminary data (Maluf and Erdtmann 2000a; Villarini et al. 2012) or they included data that were published in prior publications. For example, Cavallo et al. (2007; 2009) were excluded because they evaluated the effect of gene polymorphisms on micronuclei and comet assay data published in a prior publications (Cavallo et al. 2005; Ursini et al. 2006), and two studies reporting on number of CA per 100 cells scored (Mušák et al. 2009a; Mušák et al. 2009b) were excluded because the data were published in (Mušák et al. 2006). One study was excluded because it reported on combined, instead of individual outcomes: adverse pregnancy outcomes combined, which included spontaneous abortion, stillbirth and congenital malformations (Rogers and Emmett 1987). Finally, four studies reporting on the percentage of cells with CA of the same population of nurses in Hungary were excluded due to a lack of adjustment for significant effects of co-exposure to ionizing radiation on exposed subjects, which made it unclear whether the significant finding of higher percentage of cells with CA was due to occupational exposure to cancer chemotherapy agents or to the co-exposed individuals (Tompa et al. 2016; Tompa et al. 2006a; Tompa et al. 2015; Tompa et al. 2006b).

The main findings for each category of health outcome are summarized below, and the number of studies per health outcome are reported in Table 4. The results and evidence synthesis sections include a detailed analysis of the evidence on spontaneous abortion and genetic toxicity. The risk-of-bias assessment of individual studies and for the body of evidence were considered in developing the confidence ratings for each health effect. The key risk-of-bias questions were: confounding, exposure characterization, and outcome assessment (see protocol in Appendix I); they are discussed in the consideration of the body of evidence for each health effect. While no study was excluded based on concerns for risk of bias, confidence conclusions were considered with and without the high risk-of-bias studies (e.g., studies rating probably high or definitively high risk of bias for two key risk-of-bias questions) to assess the influence of the high risk-of-bias studies. The risk-of-bias assessment for all included studies is in Appendix C.

Table 4 Categories of Health Outcomes for 110 Included Studies

Health Outcome^a^ | DNA Damage^b^ | Reproduc-tive and Develop-mental Toxicity | Immune System Alterations | Acute Effects | Kidney Toxicity | Liver Toxicity | Cancer | Cardiac System Toxicity
Primary (Direct) | 66 studies^b^ | 30 studies (e.g., spontaneous abortion) | 1 study (e.g., immune-related diseases) | 10 studies (e.g., nausea) | 1 study (e.g., kidney disease) | 1 study (e.g., liver disease) | 3 studies | 1 study (e.g., cardiovas-cular disease)
Secondary (Indirect) | – | – | 10 studies (e.g., lymphocyte activation) | – | 4 studies (e.g., kidney biochemistry) | 3 studies (e.g., liver biochemistry) | – | 1 study (e.g., cardiac functional endpoints)

^a^ Individual studies often reported more than one health outcome.

^b^ DNA damage studies included only those evaluating chromosomal aberrations (n = 29), micronucleus induction (n = 35), and DNA damage measured by the comet assay (n = 21).

### Health Outcomes with Inadequate Evidence

For many of the health outcomes, there is inadequate evidence to determine whether there is an association with occupational exposure to cancer chemotherapy. The published studies were considered inadequate to evaluate potential reproductive or development toxicity on endpoints other than spontaneous abortion because most of the studies had a small number of cases for each health outcome, and some outcomes had very few studies. These outcomes included: cancer, congenital malformations, menstrual irregularities, ectopic pregnancy, stillbirth, preterm birth, low birth weight/small for gestational age, sex ratio, and time to pregnancy or infertility. The body of evidence was inadequate to evaluate potential effects on the immune system (e.g., hematotoxicity) because there was heterogeneity in the endpoints examined and, when evaluated in more than one study, the results were inconsistent. The body of evidence was also inadequate for liver or kidney toxicity because these health effects were only reported in one or two studies with inconsistent results. In addition, the number of cases were low (e.g., n = 3–6 cases out of 44 exposed medical personnel for liver or kidney toxicity, respectively), and there was considerable heterogeneity in the endpoints examined. The results, evidence synthesis and risk-of-bias assessment for the health outcomes with inadequate evidence are in Appendix E.

### Spontaneous Abortion

Spontaneous abortion (also called miscarriage) is the noninduced termination of a pregnancy before 20 weeks of gestation. NTP identified 16 studies reporting on spontaneous abortion in women or spouses of men occupationally exposed to cancer chemotherapy agents. Among the studies in this evaluation, spontaneous abortion was most commonly defined as spontaneous pregnancy loss at ≤20 weeks of gestation; however, one study defined spontaneous abortion as pregnancy loss at less than 24 weeks of gestation (Zhang et al. 2016) and two studies defined it as pregnancy loss at less than 28 weeks of gestation (McDonald et al. 1988b; Stücker et al. 1990). The level-of-evidence conclusion is based only on studies that reported spontaneous abortions, and did not include studies that reported spontaneous abortion and stillbirth as a combined outcome (McAbee et al. 1993; Rogers and Emmett 1987).

#### Summary

Based on the available studies, there is moderate confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with spontaneous abortion. Seven of the 16 studies identified were considered to be more informative regarding exposure assessment because the studies identified exposed nursing or pharmacy staff based on the task they performed (e.g., prepared and administered cancer chemotherapy agents) and, in some studies, the frequency of handling these agents (e.g., number of times hourly or weekly) (Fransman et al. 2007c; Lawson et al. 2012; Peelen et al. 1999; Selevan et al. 1985; Stücker et al. 1990; Valanis et al. 1999; Zhang et al. 2016). The body of evidence from these seven studies was used for rating confidence in the conclusions because of their exposure characterization and concerns for high risk of bias for exposure characterization as well as other key risk-of-bias factors (confounding and outcome assessment) in the remaining nine studies. The results were inconsistent for the nine studies that evaluated occupational exposure to any chemical or work stressor (e.g., shift work, heavy lifting) (Hemminki et al. 1985; McDonald et al. 1988b; Schaumburg and Olsen 1990b; Taskinen et al. 1994; Taskinen et al. 1986) or risk-of-bias issues regarding exposure characterization (Skov et al. 1992; Walusiak et al. 2003) and/or outcome assessment (Elshamy et al. 2010; Medková 1991a). There were no changes from the initial rating of moderate confidence in the body of evidence (seven studies) after considering factors that may increase or decrease confidence (Figure 5). The final rating of moderate confidence in the body of evidence translates directly into a moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with a higher risk of spontaneous abortion.

Figure 5

Confidence in the Body of Evidence for Spontaneous Abortions

^a^Spontaneous abortion references: (Fransman et al. 2007c; Hemminki et al. 1985; Lawson et al. 2012; Medková 1991a; Peelen et al. 1999; Schaumburg and Olsen 1990b; Selevan et al. 1985; Skov et al. 1992; Stücker et al. 1990; Taskinen et al. 1994; Taskinen et al. 1986; Valanis et al. 1999; Walusiak et al. 2003; Zhang et al. 2016).

^b^The final confidence in the body of literature was based on seven high-quality studies of highly exposed workers that reported higher case numbers of spontaneous abortions, including: one retrospective cohort (Lawson et al. 2012), one case-control (Selevan et al. 1985), and five cross-sectional studies (Fransman et al. 2007c; Lawson et al. 2012; Peelen et al. 1999; Selevan et al. 1985; Stücker et al. 1990; Valanis et al. 1999; Zhang et al. 2016).

^c^One research group conducted case-control studies of the same population of nurses in France; however, the nurses evaluated in each study were slightly different: Selevan et al. (1985) evaluated nurses with high usage of cancer chemotherapy agents and Hemminki et al. (1985) studied the occupational exposure in nurses from departments of the hospitals with lesser exposure to these agents.

^d^Two cross-sectional studies evaluated the same study population and data set using different exposure characterization methods: job title and work tasks only (Peelen et al. 1999) or estimated dermal exposure based on job title, work tasks and measured glove and skin contamination (Fransman et al. 2007c).

#### Overview

The available 16 epidemiological studies in the body of evidence that evaluated the association between occupational exposure to cancer chemotherapy and spontaneous abortions included four retrospective cohort studies, four case-control studies, and eight cross-sectional studies of 13 unique study populations (Table 5). While all studies evaluated the pregnancy outcomes of occupationally exposed female subjects, two studies also evaluated spontaneous abortion among female spouses of occupationally exposed male subjects (Valanis et al. 1999; Walusiak et al. 2003). The majority of the studies evaluated nurses, one study evaluated pharmaceutical employees (Taskinen et al. 1986), and one evaluated laboratory workers (Taskinen et al. 1994). The studies were conducted in 11 countries: Denmark (two studies), Finland (four studies; two studies overlapped in population being evaluated), the Netherlands (two studies evaluated the same population and same data), the United States (two studies), and one study each from Canada, China, Czech Republic, Egypt, France, and Poland. All the studies used retrospective exposure characterization that relied primarily on job title and self-reported questionnaires with questions about work tasks, exposures, and use of safety equipment (e.g., biological safety cabinets and personal protective equipment during or prior to pregnancy). Two studies evaluating the same study population also reported on biomonitoring or environmental monitoring: swipe tests for cyclophosphamide, ifosfamide, 5-flurouracil and urine biomonitoring for cyclophosphamide (Peelen et al. 1999), and glove and hand wash sampling for cyclophosphamide (Fransman et al. 2007c). The occurrence of spontaneous abortion was identified from medical records (five studies) or via questionnaire (interviewer-led questionnaire, four studies; self-reported questionnaire, six studies). Data collection on the study participants ranged from the years of 1970 to 2013: five studies (four unique populations) reported data prior to 1985, two studies overlapped with 1985 U.S. guidance on handling hazardous drugs, and eight studies (six unique populations) reporting data collected after 1985. Six of these studies also reported data on other reproductive outcomes, cancer, and/or acute effects (see Appendix E for discussion of the other health outcomes).

Table 5 Studies Reporting on Spontaneous Abortion

Study | Study Design (Occupation, Location, Years Data Collected, Sex) | No. of Pregnancies (Unless Otherwise Stated) | Exposure Measure | Outcome Assessment | Analysis | Results
Elshamy et al. (2010) | Cross-sectional (Nurses, Egypt, 2006, F) | 35 exposed, 29 unexposed | Job title, length of employment, self-administered questionnaire about drug handling, frequency of handling, number of accidents with cancer chemotherapy in past year, usage of personal protective equipment, and training. Note: Only 42.9% of nurses reported using gloves when handling patient waste, and 45.7% of nurses admitted to eating in the drug preparation area | Self-reported questionnaire; no definition of abortions was provided [assumed it was spontaneous abortion] | Chi-square test with continuity correction, if indicated | Significantly (p<0.05) higher rates of spontaneous abortions in exposed (22.6%; 8 cases) versus unexposed (10.3%; 3 cases)
Fransman et al. (2007c) | Cross-sectional (Nurses, the Netherlands, 1990–1997, F) Note: Same data as Peelen 1997 | Exposed: 279 background, 146 low, 145 medium, 134 high; 555 unexposed | Estimated dermal exposure based on job title, self-reported questionnaire, and glove usage in first month of pregnancy (or during time trying to get pregnant), combined with data on CP glove monitoring conducted in 1996–1997 and glove and hand monitoring in 2003–2007; categorized as: unexposed, background, low (≤0.20 μg CP/wk), medium (>0.20−0.74 μg CP/wk) or high exposure (>0.74 μg CP/wk) | Self-reported questionnaire on most recent pregnancy; defined as pregnancy loss at <20 weeks of gestation | Logistic regression analysis; adjusted a priori for age at conception, parity, smoking, alcohol consumption, coffee intake during 1st trimester of pregnancy, vitamin/folic acid use during pregnancy as well as work factors (e.g., co-exposures) | No difference in odds of spontaneous abortions compared to unexposed pregnancies (log-linear association OR = 1.01, 95% CI = 0.93–1.10; 36 exposed cases). Using dermal exposure estimates, the odds of spontaneous abortion for exposed pregnancies were: low exposure, adjOR = 1.2 (95% CI = 0.6–2.7); medium exposure, adjOR = 0.8 (95% CI = 0.3–2.0); and high exposure, adjOR = 1.2 (95% CI 0.6–2.7)
Hemminki et al. (1985) | Case-control (Nurses, 1973–1979, Finland, F) Note: population overlaps with Selevan 1985 | 169 cases, 469 controls; only 53 pregnancies exposed | Central Registry of Health Care Personnel and a questionnaire to head hospital nurses regarding each subjects’ occupational exposures (type of occupational exposure, shift work, etc.) Note: Exposed nurses were from non-oncology departments (i.e., anesthesia, intensive care, operating room, or internal medicine) where exposure was relatively uncommon | Medical records | Logistic model of conditional likelihood function adjusted for shift work and co-exposures (e.g., ionizing radiation) | No difference in odds of spontaneous abortion between cytostatic agents ≥ once weekly and unexposed (OR = 0.8, 95% CI = 0.3–1.7; 12 exposed cases versus 41 unexposed cases)
Lawson et al. (2012) | Cohort, retrospective (Nurses' Health Study II, USA, 1993–2002, F) | 775 cases, 6,707 live births; 302 exposed, 7,180 unexposed | Job title and self-reported questionnaire, including questions for each trimester of pregnancy on exposure to 5 occupational exposures: anesthesia, cancer chemotherapy agents, anti-viral drugs, sterilizing agents, and X-ray radiation | Self-reported questionnaire on most recent pregnancy; defined as pregnancy loss at <20 weeks of gestation | Logistic regression adjusted for age; multivariate analysis included all 5 work exposures, parity, shift work, and hours worked | Significantly higher odds of spontaneous abortion in nurses exposed ≥1 hour per day compared to unexposed pregnancies (adjOR = 1.94, 95% CI = 1.32–2.86; 48 exposed cases); appeared to be due to spontaneous abortions occurring at <12 weeks
McDonald et al. (1988b) | Cohort, retrospective (Working women, 1982–1984, Canada, F) | 22,713 (only 63 pregnancies exposed to cancer chemotherapy agents) | Job title and interviewer-led questionnaire, and chemical exposure information from published and unpublished studies, and occupational surveillance by local health departments and Montreal surveillance for cancer, and other reports Note: Medical questionnaire also asked nurses or physicians if they administered cancer chemotherapy agents in the month after the first missed menstrual period | Interviewer-led questionnaire on previous pregnancies; defined as pregnancy at <28 weeks of gestation | Poisson regression; evaluated factors: age, gravidity, history of previous abortion, ethnic group, educational level as well as smoking habit and alcohol consumption | No association with spontaneous abortion compared to unexposed pregnancies (O/E = 0.97, 13 exposed cases); maternal age, gravidity, previous spontaneous abortion, smoking, and alcohol consumption were significant factors [but the data do not appear to be adjusted for these significant factors]
Medková (1991a) | Cross-sectional (Physicians, nurses, auxiliary workers, Czech Republic, Year NR, FM) | 74 exposed, 11 unexposed (to partners of exposed subjects) | Job title and interviewer-led questionnaire (≥5 years, n = 25; 6–10 years, n = 14; 11–15 years, n = 4; and 16–20 years, n = 1) Note: All exposed personnel used gloves and gowns; isolated room for drug preparation only used by 25% of exposed subjects | Interviewer-led questionnaire; [no definition provided for early and late spontaneous abortion] | NR | Higher number of early spontaneous abortions compared to unexposed pregnancies (early: 8 exposed vs. 0 unexposed); whereas, there were 2 late spontaneous abortions in unexposed versus 0 in exposed
Peelen et al. (1999) | Cross-sectional (Nurses, the Netherlands, 1990–1997, F) Note: Same data as Fransman et al. 2007c | 249 exposed, 1,010 unexposed | Job title, self-reported questionnaire, biomonitoring, and environmental monitoring | Self-reported questionnaire on most recent pregnancies; [definition same as Fransman et al. 2007c] | [Logistic regression]; adjusted for age, coffee consumption, smoking, alcohol consumption, pregnancy, physical strain, and co-exposures (e.g., ionizing radiation, disinfectants), as needed | Non-significant, but slightly higher, odds of spontaneous abortion compared to unexposed pregnancies (adjOR = 1.4, 95% CI = 0.8–2.6; 18 exposed cases); 30% of urine samples from exposed nurses tested positive for CP and 40% tested positive for IF; unexposed subjects were not tested
Schaumburg and Olsen (1990b) | Cohort, retrospective (Pharmacy assistants, Denmark, 1979–1984, F) | 1,882 births, 177 spontaneous abortions, 109 induced abortions; only 8 pregnancies exposed to cancer chemotherapy agents | Membership in national union of pharmacy assistants and self-reported questionnaire | Medical records | Unconditional logistic regression model | No spontaneous abortions were reported for the 8 pregnancies of occupationally exposed personnel
Selevan et al. (1985) | Case-control (Nurses, Finland, 1973–1980, F) | 124 cases, 321 controls; only 92 pregnancies exposed | Central Registry of Health Care Personnel and self-reported questionnaire Note: Exposed nurses identified as having high usage of cancer chemotherapy agents | Medical records | Conditional logistic regression; factors considered: smoking, alcohol use, medications in first trimester, gravidity, prior fetal loss, exposure prior to pregnancy | Significantly higher odds of spontaneous abortion with first trimester exposure (OR = 2.3, 95% CI = 1.2–4.39; 18 exposed cases); prior fetal loss was significant factor and results were the same when adjusted for this factor; exposure prior to pregnancy NS
Skov et al. (1992) | Cohort, retrospective (Nurses, Denmark, 1977–1988, F) | 281 exposed, 809 unexposed | Employment records of 5 oncology hospitals, and data from head nurses regarding drug handling and administration of individual subjects; evaluated data as exposed versus unexposed and by level of exposure [details not provided] versus unexposed | Medical records | Logistic regression analysis with adjustment for maternal age | No difference in odds of spontaneous abortion compared to unexposed nurses (adjOR = 0.74, 95% CI = 0.40–1.38; 18 exposed cases); spontaneous abortion rate was similar when considering first pregnancies only; no exposure-response observed
Stücker et al. (1990) | Cross-sectional (Nurses, France, 1985–1986, F) | 139 exposed, 357 unexposed | Job title and interviewer-led questionnaire Note: At time of study, no special protective equipment was in operation and use of PPE was not uniform | Interviewer-led questionnaire; defined as pregnancy loss at <28 weeks of gestation | Logistic regression analysis; evaluated effect of maternal age, parity and smoking, exposure duration and frequency of handling | Significantly higher odds of spontaneous abortion in the first exposed pregnancy compared to unexposed pregnancies (adjOR = 1.7, 95% CI = 1.0-2.8); 36 exposed cases; exclusion of 24 cases prior to pregnancy did not change significance (rate ratio = 1.7, 95% CI = 1.1–2.5)
Taskinen et al. (1986) | Case-control (Pharmaceutical industry workers, Finland, 1973–1980, F) | 44 cases, 130 controls; only 6 exposed pregnancies | Factory physician completed-questionnaire on exposure during pregnancy through health cards, labor protection chiefs, and department foremen regarding occupation, main tasks, exposures, lifting, standing, or sitting; employed at least one week during the first trimester | Medical records | Logistic regression analysis based on conditional maximum likelihood | No statistically significant higher odds of spontaneous abortions compared to unexposed pregnancies (OR = 2.8, 95% CI = 0.6–1.4; 3 exposed cases)
Taskinen et al. (1994) | Case-control (Laboratory assistants, Finland, 1970–1986, F) | 206 cases, 329 controls; only 8 exposed pregnancies | Employment records and self-reported questionnaire regarding frequency of specific exposures during first trimester | Medical records | Logistic regression based on conditional likelihood; covariate included smoking, alcohol use, employment status | No statistically significant higher odds of spontaneous abortion compared to unexposed pregnancies (adjOR = 4.0, 95% CI = 0.8–19.3; 5 exposed cases)
Valanis et al. (1999) | Cross-sectional (Nurses, nurses’ aides, pharmacists, and pharmacy technicians, USA, 1988–1989, FM) | 1,448 exposed, 5,297 unexposed | Job title and self-reported questionnaire Note: Exposed subjects were involved in mixing, administering, and/or handling the excreta of patients administered cancer chemotherapy agents | Self-reported questionnaire; defined as pregnancy loss at ≤20 weeks | Logistic regression for (1) independence model and (2) generalized estimating equations model; all models adjusted for age, gravidity at time of pregnancy, maternal smoking during pregnancy; outcome of prior fetal loss | Significantly higher odds of spontaneous abortion in pregnancies of exposed female subjects exposed during pregnancy (adjOR = 1.5, 95% CI = 1.2–1.8; 223 exposed cases) or prior to pregnancy (adjOR = 1.5, 95% CI = 1.3–1.9) compared to unexposed pregnancies; pregnancies of exposed female subjects affected more than pregnancies of spouses of exposed male subjects
Walusiak et al. (2003) | Cross-sectional (Physicians, nurses, orderlies, Year NR, Poland, FM) | 84 exposed, 169 unexposed | Job title and self-reported questionnaire (11.0 ± 9.3 years, range 5–44 years) | [Interviewer-led] questionnaire; defined as pregnancy loss at <24 weeks of gestation | Mann-Whitney U-test | Greater, but NS, number of spontaneous abortions compared to unexposed nurses (unexposed = 9 cases, 5.3% prevalence; exposed = 7 cases, 8.3% prevalence)
Zhang et al. (2016) | Cross-sectional (Nurses, China, 2011 pre-PIVAS and 2013 (post-PIVAS) in Hospital A, F) | Pre-PIVAS: 106 unexposed, 30 exposed non-oncology, 82 exposed oncology; Post-PIVAS: 108 unexposed, 29 exposed non-oncology, 87 exposed oncology, and 112 exposed oncology nurses at Hospital B) | Job title and self-reported questionnaire (≥2 years in current job) Note: All exposed nurses involved in mixing and/or administration of cancer chemotherapy agents | Self-reported questionnaire; pregnancy loss at <24 weeks of gestation | [Student] t-test, Chi-square, and Wilcoxon [signed-rank sum] test | No difference in rate of spontaneous abortion compared to unexposed nurses prior to PIVAS at Hospital A; after implementation of PIVAS, the rate of spontaneous abortions in exposed oncology nurses was significantly (p<0.05) lower compared to pre-PIVAS values as well as non-significant reductions in the rates for unexposed and exposed non-oncology nurses. Significantly (p<0.01) higher rate of spontaneous abortions was reported for exposed oncology nurses at Hospital B (no PIVAS) compared to post-PIVAS exposed oncology nurses at Hospital A

adjOR = adjusted odds ratio; CI = confidence interval, CP = cyclophosphamide, F = female, IF = ifosfamide; M = male, NR = not reported, NS = not significant, OR = odds ratio, PIVAS = pharmacy intravenous admixture service, and USA = United States of America, wk = week.

#### Evidence Synthesis

The evidence synthesis for spontaneous abortion was based on 16 studies, including: four retrospective cohort studies (Lawson et al. 2012; McDonald et al. 1988b; Schaumburg and Olsen 1990b; Skov et al. 1992), four case-control studies (Hemminki et al. 1985; Selevan et al. 1985; Taskinen et al. 1994; Taskinen et al. 1986), and eight cross-sectional studies (Elshamy et al. 2010; Fransman et al. 2007c; Medková 1991a; Peelen et al. 1999; Stücker et al. 1990; Valanis et al. 1999; Walusiak et al. 2003; Zhang et al. 2016) (Table 5). The results were consistent for a higher risk of spontaneous abortions associated with cancer chemotherapy agents when evaluating studies of nursing or pharmacy personnel with higher handling activities of these agents (Figure D-1) (Fransman et al. 2007c; Lawson et al. 2012; Peelen et al. 1999; Selevan et al. 1985; Stücker et al. 1990; Valanis et al. 1999). For example, a case-control study of Finnish nurses reported significantly greater odds of spontaneous abortion (OR = 2.3, 95% CI = 1.2–4.39) in nurses with high usage of cancer chemotherapy drugs compared to nurses with less than once weekly exposure in the first trimester (Selevan et al. 1985). A cross-sectional study in France by Stucker et al. (1990) reported significantly higher odds of spontaneous abortion (adjusted odds ratio (adjOR) = 1.7, 95% CI = 1.0–2.8) in exposed nurses employed in a cancer center or hospital oncology wards compared to unexposed nurses from consulting medical, cardiology, endocrinology, and general medical units. Similarly, a cross-sectional study of female nurses, nurses’ aides, pharmacists, and pharmacy technicians in the United States reported significantly increased odds of spontaneous abortion (adjOR = 1.5, 95% CI = 1.2–1.8) in medical personnel who either prepared or administered doses, and/or handled the excreta of patients administered cancer chemotherapy agents during pregnancy than unexposed subjects (Valanis et al. 1999). In a study evaluating the influence of occupational exposure in the Nurses’ Health Study II in the United States, Lawson et al. (2012) reported significantly greater odds of spontaneous abortion in nurses exposed ≥1 hour per day to cancer chemotherapy agents (adjOR= 1.94, 95% CI = 1.32–2.86), with the highest odds of spontaneous abortion occurring at <12 weeks of gestation; the analyses were adjusted for other co-exposures and work conditions (i.e., anesthetic gases, sterilizing agents, anti-viral agents, ionizing radiation, and shift work).

Further support for a relationship between occupational exposure to cancer chemotherapy agents and spontaneous abortion was reported in a cross-sectional study of nurses handling cancer chemotherapy agents employed in an oncology ward and non-oncology ward compared to unexposed nurses in a hospital in China at the beginning of the implementation of a pharmacy intravenous admixture service (PIVAS) versus an open plan treatment area, with a follow-up study 2 years later (Zhang et al. 2016). The PIVAS was a closed system that reduced exposure by adding safety equipment (e.g., biological safety cabinets, sealed bags for transport of prepared drugs), increased use of personal protective equipment when handling these agents, and protocols for storage, transport, disposal, and management of spills as well as safety training. Prior to implementation of the PIVAS, the rate of spontaneous abortions was non-significantly higher in nurses handling cancer chemotherapy in oncology (14.6%) compared to unexposed nurses (9.4%). In a follow-up study 2 years later, the authors observed a significant reduction in the rate of spontaneous abortions in nurses working in the oncology ward 2 years after PIVAS implementation (4.6%) compared to the rates before PIVAS (14.6%), as well as compared to spontaneous abortion rates in oncology nurses from a hospital in China with no PIVAS (22.3%) (Zhang et al. 2016).

In contrast, two studies of one population observed no association of spontaneous abortion (Fransman et al. 2007c; Peelen et al. 1999). Peelen et al. (1999) reported a slightly higher, but not statistically significant, odds of spontaneous abortion in oncology nurses from 121 hospitals in the Netherlands based on job title and work tasks (OR = 1.4, 95% CI = 0.8–2.6). In a second analysis of the same data from the Dutch oncology nurses, Fransman et al. (2007c) reported no association of spontaneous abortions with estimated dermal exposure to cyclophosphamide; the dermal exposure estimate was based on job title tasks, use of PPE as well as glove and hand contamination. The author commented that the study may have underestimated exposure of the nurses because the administered dose levels of cancer chemotherapy agents have decreased over time, and the outcome data were collected in 1990–1997, while the glove and hand monitoring studies were conducted in 1996–1997 and 2001–2003.

The remaining nine studies evaluating spontaneous abortion were less informative for a variety of reasons. Hemminki et al. (1985) conducted a case-control study of the same population of nurses in France as Selevan et al. (1985) to evaluate the association with occupational exposure to anesthesia gases, sterilizing agents, ionizing radiation, cancer chemotherapy agents, and other exposures. The authors observed no association between occupational exposure to cancer chemotherapy agents and spontaneous abortion (Hemminki et al. 1985); however, the authors stated that the nurses were from hospital departments with reduced exposure to cancer chemotherapy agents (i.e., anesthesia surgery, intensive care, operating room or internal medicine department of a general hospital) relative to the nurses with high levels of handling and administering these agents reported in the study by Selevan et al. (1985). A retrospective study of oncology nurses in five hospitals in Denmark from 1977–1988 reported that spontaneous abortion was not associated with occupational exposure to cancer chemotherapy agents when evaluating exposed versus unexposed nurses or in an exposure level (low, moderate, high exposure) analysis conducted by head nurses consulting hospital drug-handling logs (Skov et al. 1992). However, the authors did not provide details on how they categorized the nurses into the exposure levels, and there was no information on use of personal protective equipment; the authors hypothesized that part of the lack of effect might be due to the implementation of safety handling procedures for cancer chemotherapy agents after 1980.

One retrospective cohort study of 2,168 pregnancies of pharmacy assistants in Denmark observed no spontaneous abortions among the eight pregnancies exposed to cancer chemotherapy agents; however, the workers may not have been highly exposed (characterized as daily or weekly exposure versus unexposed) (Schaumburg and Olsen 1990b). No association of spontaneous abortion with occupational exposure to cancer chemotherapy agents was observed in a cross-sectional study assessing occupational exposures of nurses and doctors in Canada; however, there was no information provided about the tasks or frequency of drug handling of the exposed individuals (McDonald et al. 1988b). Two case-control studies evaluating the influence of various occupational exposures of pharmaceutical workers (Taskinen et al. 1986) and laboratory assistants (Taskinen et al. 1994) reported higher, but non-significant, odds for spontaneous abortion with exposure to cancer chemotherapy agents; however, these studies included very few exposed pregnancies (6–8 pregnancies) with very few cases (3–5 cases) and the range of exposure during pregnancy was insufficient to determine a difference between groups (controls: 1–2 days per week versus exposed: ≥3 days per week). A cross-sectional study of physicians, nurses, and auxiliary workers handling cancer chemotherapy agents in the Czech Republic reported a higher occurrence of early spontaneous abortions in exposed subjects compared to unexposed spouses of the exposed subjects across all pregnancies (Medková 1991a); however, the authors did not provide a definition of early spontaneous abortion, no statistical analyses were reported, and there were only two unexposed subjects with pregnancy outcome data compared to 38 exposed subjects with pregnancy outcome data. A cross-sectional study of doctors, nurses, and orderlies in Poland reported that there was no difference in spontaneous abortion in the exposed subjects versus the unexposed personnel (Walusiak et al. 2003). The authors reported that doctors were the least exposed of the medical personnel, but they do not explain how they characterized exposure and they did not run an analysis with only the nurses and orderlies (Walusiak et al. 2003). Finally, a cross-sectional study of oncology nurses in Egypt employed in the same position for >10 years reported a significantly (p<0.05) higher rate of abortions—which was not defined, but was presumed to be spontaneous abortions—relative to controls (22.6%) compared to unexposed nurses (10.3%); the authors reported poor adherence to safety measures of the exposed nurses, such as eating in the drug administration area (45.7%) and only 42.9% used gloves when cleaning up spills or handling patient waste.

#### Risk-of-bias Assessment

Risk-of-bias assessments were conducted on all studies included in the evidence synthesis for spontaneous abortion (Figure D-2 and Figure D-3). Approximately 60% of the studies reporting on the occurrence of spontaneous abortion were rated probably low risk of bias for confounding (e.g., appropriate confounders were considered and adjusted when necessary), exposure characterization, and outcome assessment.

Most studies (10 of 16) were rated probably low or definitely low risk of bias for confounding. Schaumburg and Olsen (1990b) did not adjust for confounders or control for multiple exposures among the pharmacy assistants working with cancer chemotherapy drugs on a daily or weekly basis; however, this study was rated as probably low risk of bias because no spontaneous abortions were observed among the eight exposed pregnancies. One study was rated as probably high risk of bias (Medková 1991a); the author did not adjust for differences in age or smoking, and it was not clear whether both the male employees and their pregnant spouses were smokers or whether second hand smoke was addressed. Five studies were rated probably high risk of bias for lack of adjustment for confounding variables (Elshamy et al. 2010; McDonald et al. 1988b; Skov et al. 1992; Taskinen et al. 1986; Walusiak et al. 2003). One study of female pharmaceutical workers did not appear to adjust for possible co-exposures (e.g., ionizing radiation) in their analysis, and the authors did not report whether they evaluated for confounders of smoking or alcohol consumption (Taskinen et al. 1986). McDonald et al. (1988b) identified significant differences in the prevalence of several confounders (i.e., maternal age, gravidity, previous spontaneous abortion, smoking, and alcohol consumption) between the exposed and unexposed nurses and doctors, but did not report whether they adjusted for these confounders. Skov et al. (1992) did not evaluate smoking or alcohol consumption in their retrospective cohort of oncology nurses; however, the authors comment that nurses were likely to have similar rates of these two possible confounders, regardless of occupational exposure. A study of oncology nurses in Egypt did not report an assessment of potential confounders for either exposed or controls (e.g., smoking, ionizing radiation) (Elshamy et al. 2010). Finally, Walusiak et al. (2003) reported data on the sex, age, and smoking status of the exposed and unexposed nurses in their study, but did not present any statistical analysis evaluating possible differences in these confounders.

Ten of 16 studies were rated probably low risk of bias for exposure characterization. For example, Fransman et al. (2007c) estimated exposure using data on self-reported tasks of oncology nursing staff (preparation, administration, handling patient urine, washing a patient, removing bed sheets, cleaning toilets) and PPE use with task-based exposure measurements of glove and hand (dermal) contamination of cyclophosphamide. In another study, Lawson et al. (2012) characterized exposure from the Nurses’ Health Study, a well-established cohort, using a self-reported questionnaire with questions regarding occupational exposure to cancer chemotherapy agents as well as other genetic toxicant exposures (e.g., anesthetic gases, sterilizing agents, x-rays), shiftwork, and anti-viral medication. The questionnaire included examples for each class of exposures, which has been demonstrated to improve the accuracy of the exposure recall (Teschke et al. 2002). While use of questionnaires (self-report or interviewer-led) to characterize exposure in retrospective cohort studies can be influenced by recall bias, support for accurate recall of exposure by medical staff has been demonstrated by a study of pharmacists whose self-reported questionnaire was corroborated by their supervisor (McDiarmid et al. 1992). Six studies were rated probably high risk of bias for exposure characterization (Hemminki et al. 1985; McDonald et al. 1988b; Skov et al. 1992; Taskinen et al. 1994; Taskinen et al. 1986; Walusiak et al. 2003). Two studies were rated probably high risk of bias for a lack of details regarding exposure characterization; for example, Walusiak et al. (2003) only provided job title as the description of physicians, nurses, and orderlies handling cancer chemotherapy agents although they stated that doctors were less exposed, and Skov et al. (1992) provided no description of the semi-quantitative categories of exposure of oncology nurses from two hospitals (Skov et al. 1992). Two studies did not provide a sufficient range or variance in exposure measures across groups (Taskinen et al. 1994; Taskinen et al. 1986); e.g., these studies compared female laboratory workers (Taskinen et al. 1994) or pharmaceutical factory workers (Taskinen et al. 1986) exposed (1994) 1–2 days per week (considered rarely handled) versus ≥3 days per week (considered frequently handled) during pregnancy. Another study reported the exposure of each participant was assessed by questionnaire of the head nurse of the hospital on behalf of the study participants, which may lead to high potential for recall bias (Hemminki et al. 1985). Finally, McDonald et al. (1988b) exposure was assessed by interviewer-led questionnaire to doctors and nurses regarding what chemicals (including antineoplastic agents) they were exposed to while at work in the first four weeks past their first missed menstrual period; thus, the study assessed only whether they were exposed or not exposed to cancer chemotherapy agents with no details about frequency of use or personal protective equipment use.

Regarding outcome assessment, most studies included in the evidence synthesis were rated definitely low risk of bias or probably low risk of bias because they assessed outcome by identifying cases from hospital discharge records or collected data from questionnaires from which the participants were not aware of the connection between outcome and exposure. For example, Fransman et al. (2007c) and Peelen et al. (1999) conducted their self-reported questionnaire of oncology nurses in the Netherlands as a study of reproductive outcomes in nurses. The interviewer-led questionnaire by Stucker et al. (1990) presented the purpose of the study as an assessment of reproductive characteristics in hospital personnel. Similarly, exposure was not likely to influence the outcome assessment from the Nurses’ Health Study II as it is a well-established cohort study, which collects data on all types of lifestyle, exposure and health data (Lawson et al. 2012). While recall error can be a limitation of questionnaires assessing health outcomes, women have accurate recall of pregnancy outcomes (Axelsson 1990; Joffe et al. 1993), and nurses have accurate recall of health data (Colditz et al. 1986; Colditz et al. 1987). Thus, even when participants were advised of the purpose of the study as in three studies reporting on spontaneous abortion (McDonald et al. 1988b; Valanis et al. 1999; Walusiak et al. 2003), it would not likely influence their recall of spontaneous abortion or other pregnancy outcomes. Two studies were rated as probably high risk of bias due to a lack of definitions for early and late spontaneous abortions (Medková 1991a) or abortions [presumed to be spontaneous abortions] (Elshamy et al. 2010).

#### Confidence Ratings and Level-of-evidence Conclusions

The initial rating of moderate confidence in the body of evidence for spontaneous abortion was not downgraded or upgraded for any factor (Figure 5). The confidence rating was based on seven studies with the lowest risk of bias (defined as none or no more than one probably high risk-of-bias rating for one of three key questions of confounding, exposure characterization, and outcome assessment) and the most highly exposed personnel (Fransman et al. 2007c; Lawson et al. 2012; Peelen et al. 1999; Selevan et al. 1985; Stücker et al. 1990; Valanis et al. 1999; Zhang et al. 2016). The remaining studies had higher risk of bias and/or provided less detail to determine level of drug handling; thus, there were no changes in the initial rating of moderate confidence in the body of evidence after considering factors that may increase or decrease confidence (Figure 5). Thus, the final rating was moderate confidence in the body of evidence. The final rating of moderate confidence directly translates into a moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with spontaneous abortion.

### Genetic Toxicity: DNA Damage

Genetic toxicity assays have been used to evaluate whether occupational exposure to cancer chemotherapy agents results in chromosomal or DNA damage. These types of assays are often used in surveillance programs as biomarkers of exposure (i.e., to determine if occupational exposure to the chemical(s) of interest has occurred) (Kirsch-Volders et al. 2011; Mateuca et al. 2006). Nearly all of the classes of cancer chemotherapy agents are known to induce genetic toxicity [reviewed in Suspiro and Prista (2011) and Alam et al. (2011)]. NTP evaluated the effects of occupational exposure to cancer chemotherapy agents on three types of genetic toxicity assays in this review: induction of structural CA, MN, and DNA damage measured by the alkaline comet assay. All three of these assays have standardized testing protocols validated by the OECD, and are used to evaluate genetic toxicity in both epidemiological studies and laboratory animal toxicity testing of environmental and occupational exposures (OECD 2016a; 2016b; 2016c). Both CA and MN induction are considered early biomarkers of effect of cancer incidence (Bonassi et al. 2007; Bonassi et al. 2004; Norppa et al. 2006) and are frequently included in support of a carcinogenic agent listing in IARC and NTP’s Report on Carcinogens (IARC 1966; 1980; 1981; 1990; 2000; NTP 2016). There is much interest in the comet assay to measure DNA damage as a biomarker of effect in environmental and occupational biomonitoring due to its affordability and relative ease of use (Valverde and Rojas 2009; Zare Sakhvidi et al. 2016); however, its association to cancer has not been established. All three assays rely on cells obtained in samples of peripheral blood.

The NTP evaluation identified 66 studies of 53 unique populations reporting structural CA, MN induction, and/or DNA damage measured by the comet assay (Table F-1). The available epidemiological studies in the body of evidence that evaluated the association between occupational exposure to cancer chemotherapy and the three DNA damage assays included: one prospective cohort study of pharmacists (Roth et al. 1994), one longitudinal cohort study of nurses (Mader et al. 2009), and 64 cross-sectional studies of medical personnel (e.g., nurses, physicians, pharmacists, pharmacy technicians) as well as chemists, laboratory assistants, and production or manufacturing workers). Most of the studies evaluated nursing or pharmacy personnel, while drug production, manufacturing employees, chemists, and laboratory assistants were the least studied (only four studies). The studies varied greatly in size (from 12 to 594 subjects), and length of time in job position (1 month to 30 years). The studies originated from 27 different countries, mainly in Europe (n = 42); there were three studies from the United States (all on the same study population) and one study from Canada.

#### Overall Summary of Genetic Toxicity Evidence

Summary: Based on the available studies, there is a moderate confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with genetic toxicity. A clear majority of studies reported significant effects of structural CA (22 of 29 studies measuring either percentage of cells with CA and number of CA per 100 cells scored), MN induction (24 of 36 studies measuring either number of micronucleated cells or number of MN per 1,000 cells scored) or DNA damage by comet assay (18 of 21 studies reporting on either percentage of tail DNA, tail length, tail moment and DNA damage (Table F-1). Of the 18 studies that reported on measurements of more than one of the three genetic toxicity assays, 16 reported consistent effects. The initial rating of moderate confidence in the body of evidence for each genetic toxicity assay was not downgraded or upgraded for various factors (Figure 6, Figure 7, and Figure 8). Therefore, the final rating of moderate confidence in the body of evidence directly translates into a rating of a moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with genetic toxicity as measured by structural CA, MN induction, and DNA damage measured by comet assay.

Figure 6

Confidence in the Body of Evidence for Structural Chromosomal Aberrations (Excluding Gaps)

^a^Initial confidence of cross-sectional studies of genetic toxicity started as moderate due to the determination that knowledge of exposure status would not influence the results of the CA assays.

^b^% cells with CA references: (Anwar et al. 1994; Burgaz et al. 2002; El-Ebiary et al. 2013; Hola et al. 1988; Jakab et al. 2001; Kopjar et al. 2009; Medková 1990; Mušák et al. 2013; Nikula et al. 1984; Pohlová et al. 1986; Roth et al. 1994; Rubeš et al. 1998; Sessink et al. 1994a; Sorsa et al. 1988).

^c^Number of CA references: (Bouraoui et al. 2011; Cavallo et al. 2005; Cooke et al. 1991; El-Ebiary et al. 2013; Grummt et al. 1993; Jakab et al. 2001; Kopjar et al. 2009; Krepinsky et al. 1990; Mahmoodi et al. 2017; Milković-Kraus and Horvat 1991; Moretti et al. 2015; Mušák et al. 2006; Sorsa et al. 1988; Stücker et al. 1986; Testa et al. 2007; Thulin et al. 1995; Yang et al. 2002b).

^d^Number of aberrations on chromosome 5, 7, or 11 references (presented as incidence rate ratios): (McDiarmid et al. 2010; McDiarmid et al. 2014).

Figure 7

Confidence in the Body of Evidence for Micronucleus Induction

^a^Initial confidence of cross-sectional studies of genetic toxicity started as moderate due to the determination that knowledge of exposure status would not influence the results of the MN assays.

^b^Number of cells with MN/1,000 binucleated lymphocytes scored references: (Anwar et al. 1994; Boughattas et al. 2010; Buono-Michel et al. 2000; Deng et al. 2006; Deng et al. 2005; Kašuba et al. 1999; Kopjar et al. 2009; Maluf and Erdtmann 2000b; Rombaldi et al. 2009; Roth et al. 1994; Yang et al. 2002b).

^c^Number of cells with MN/1,000 buccal cells scored references: (Machado-Santelli et al. 1994; Rodríguez-Montero et al. 2016).

^d^Number of MN/1,000 binucleated lymphocytes scored references: (Bolognesi et al. 2005; Bouraoui et al. 2011; Burgaz et al. 1999; Cavallo et al. 2005; Cornetta et al. 2008; Deng et al. 2006; Deng et al. 2005; El-Ebiary et al. 2013; Ensslin et al. 1997; Garaj-Vrhovac and Kopjar 1998; Harris et al. 1992; Hessel et al. 2001; Kašuba et al. 1999; Kevekordes et al. 1998; Kopjar et al. 2009; Ladeira et al. 2014; Laffon et al. 2005; Mahmoodi et al. 2017; Moretti et al. 2015; Moretti et al. 2013; Mrđanović et al. 2012; Pilger et al. 2000; Rekhadevi et al. 2007; Sorsa et al. 1988; Thiringer et al. 1991; Yager et al. 1988).

^e^Number of MN/1,000 buccal cells scored references: (Bolognesi et al. 2005; Burgaz et al. 1999; Cavallo et al. 2005; Rekhadevi et al. 2007).

Figure 8

Confidence in the Body of Evidence for DNA Damage Measured by the Comet Assay

^a^Initial confidence of cross-sectional studies of genetic toxicity started as moderate due to the determination that knowledge of exposure status would not influence the results of the comet assays.

^b^% tail DNA: (Buschini et al. 2013; Connor et al. 2010; Cornetta et al. 2008; Kopjar and Garaj-Vrhovac 2001; Moretti et al. 2013; Villarini et al. 2011; Yin et al. 2010).

^c^Tail length: (Deng et al. 2006; Deng et al. 2005; Kopjar and Garaj-Vrhovac 2001; Kopjar et al. 2009; Laffon et al. 2005; Rekhadevi et al. 2007; Sasaki et al. 2008; Villarini et al. 2011; Yang et al. 2002a; Yin et al. 2010; Yoshida et al. 2006).

^d^Tail moment: (Connor et al. 2010; Deng et al. 2006; Deng et al. 2005; Kopjar and Garaj-Vrhovac 2001; Sasaki et al. 2008; Ursini et al. 2006; Yin et al. 2010).

^e^DNA damage assessed by manual scoring and binning: (Izdes et al. 2009; Mader et al. 2009; Maluf and Erdtmann 2000b; Rombaldi et al. 2009; Ündeğer et al. 1999).

#### Overall Risk-of-bias Assessment of Genetic Toxicity Evidence

Risk-of-bias ratings of individual genetic toxicity studies are available in Figure D-4 and Figure D-5. A general discussion of the common issues for this dataset on the key risk-of-bias questions (confounding, exposure characterization, and outcome assessment) is included below. Additional detailed discussion of specific risk-of-bias issues that impact the bodies of evidence for individual measures (i.e., structural CA, MN induction, and DNA damage measured by comet assay) are presented in the following sections.

Risk-of-bias assessment of potential confounders included age, sex, smoking, and co-exposure to other known or suspected genetic toxicants (e.g., anesthetic gases, ionizing radiation, and organic solvents). Most studies (73%) measuring CA, MN induction or DNA damage measured by comet assay controlled for these potential confounders resulting in definitely low or probably low risk of bias. Among the remaining 27% of studies, 14 studies (21%) were identified as probably high risk of bias due to lack of reporting on one or more confounders and modifiers, or the authors did not statistically analyze whether the confounders or modifiers were significantly different between the exposure groups (Figure D-4 and Figure D-5). Six percent of studies (four studies) were rated as definitely high risk of bias for lack of adjustment of confounding or modifying variables, including age, sex, smoking status (Cooke et al. 1991; Ensslin et al. 1997; Kašuba et al. 1999; Kopjar and Garaj-Vrhovac 2001), or genetic toxicant co-exposures [e.g., ionizing radiation (Kašuba et al. 1999)].

Risk-of-bias assessment of the exposure characterization assessed the consistency and reliability of the exposure measures regarding the use of established test methods and whether exposure was assessed in a relevant time-window for development of the outcome. Most of the studies assessing genetic toxicity as probably low risk of bias for exposure characterization because they reported data on work tasks (e.g., preparing drugs, administering drugs, or cleaning up patient excreta) and drug handling (e.g., drug types, frequency of handling, doses, duration of exposure); the data were usually collected by self-reported or interviewer-led questionnaire. Data on work practices, safety equipment availability, and use of personal protective equipment also supported a rating of probably low risk of bias. Three studies characterized exposure using a daily diary in which exposed subjects recorded their work activities and usual events (e.g., accidents), which improved the exposure characterization by allowing for an analysis of number of drug-handling events, handling events for the drugs that were measured, lifetime handling of antineoplastic drugs, job classification, and class of drugs (alkylating, non-alkylating) (Connor et al. 2010) or an incidence rate ratio of CA per the frequency of drug-handling events (based on a daily diary of exposure) (McDiarmid et al. 2010; McDiarmid et al. 2014); these studies were also rated probably low risk of bias because frequency of drug-handling events is considered an acceptable approach for exposure assessment of mixed exposures such as cancer chemotherapy agents (Albertini et al. 2000; Nieuwenhuijsen 2003). Two studies were rated probably high risk of bias because they only reported on the job title of the exposed population, but did not provide any further details characterizing the exposure (Garaj-Vrhovac and Kopjar 1998; Mušák et al. 2006).

Risk-of-bias evaluation of the outcome assessment considered the use of established methods, whether the outcome had been assessed consistently across all groups and whether the outcome assessors had been blinded to the study groups or exposure levels prior to assessing the outcomes. Most of the studies measuring DNA damage as CA, MN induction or DNA damage measured by comet assay were rated probably or definitely low risk of bias for outcome assessment. All studies used standard methods for assessing CA, MN induction, and DNA damage by comet assay (see protocol in [underlined: Appendix I]). Most studies reported the OECD recommended measurements or common measurements for each of these genetic toxicity assays and assessed outcomes consistently across all groups. Most studies also reported blinding of the outcome assessor. In addition, the outcome assessment was automated for some studies reporting on MN induction and comet assay; thus, for these studies, there was less of a concern if there was a lack of reporting on whether blinding occurred. Eight studies were also rated probably high risk of bias for lack of details regarding assessment methods for MN (Ensslin et al. 1997) or sample processing for comet assay (Cornetta et al. 2008; Deng et al. 2006; Deng et al. 2005; Mader et al. 2009; Ündeğer et al. 1999; Yang et al. 2002a; Yin et al. 2010). Only one study (Ursini et al. 2006) received a ranking of definitely high risk of bias for outcome assessment for maintaining blood samples at room temperature until processing; this action may have biased the results toward the null because DNA repair enzymes are known to begin working within 30 minutes of sample collection unless they are chilled. The authors reported no difference in tail moment between the exposed and unexposed groups (Ursini et al. 2006).

#### Overall Confidence Ratings and Level-of-evidence Conclusions for Genetic Toxicity

Across the three measures of genetic toxicity (increased structural CA, MN induction, and DNA damage measured by the comet assay), there is moderate confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with genetic toxicity. The body of evidence across a total of 66 studies presents a consistent pattern of findings of higher levels of CA, MN induction, and DNA damage measured by comet assay in occupationally exposed subjects. Furthermore, studies that evaluated more than one genetic toxicity assay (e.g., CA, MN, or DNA damage measured by comet assay) were largely consistent in the direction of their results: 14 of 18 studies reported significantly higher levels of DNA damage across multiple assays and two studies reported no difference between exposure groups; two studies reported inconsistent effects across more than one genetic toxicity assay. A potential upgrade in the overall confidence for genetic toxicity was considered based on consistent evidence across multiple effect measures. However, no change was made in the confidence rating because these three indications of genetic toxicity are closely related measures of an effect without support for an independent mechanism. Two of the genetic toxicity assays (CA and MN induction) had the same mechanism of action, and comet assay is a biomarker of effect, which has not yet been associated with any downstream health outcome. The final rating of moderate confidence directly translates into a moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with genetic toxicity.

#### Structural Chromosomal Aberrations

The NTP evaluation identified 29 studies of 26 unique populations reporting structural CA (i.e., breaks, deletions, duplications, translocations, inversions, and rings) resulting from direct DNA breakage, replication on a damaged DNA template, inhibition of DNA synthesis and other mechanisms (e.g., inhibition of topoisomerase II enzymes) in peripheral blood lymphocytes arrested at metaphase. The evaluation focused the level-of-evidence conclusions on studies reporting on the two measurements of CA: percent of cells with CA per 100 cells scored (excluding chromosomal gaps), which are referred to here as percentage of cells with CA (excluding gaps) (Figure D-6), and the number of CA per 100 cells scored (excluding gaps) (Figure D-7). The percentage of cells with CA (excluding gaps) is a measure of the frequency of cells that exhibited any type of CA, and is a recommended measurement for CA by the OECD (2016a). The number of CA per 100 cells (excluding gaps) scored is a less precise, but commonly reported, measure than percentage of cells with CA (without gaps) because some cells have more than one CA; however, it is included because it is commonly reported in the published literature. Chromosomal and chromatid gaps (also called gaps or achromatic lesions) are lightly stained bands in the chromosomes and chromatids and are not accepted as a measure of damage because they occur naturally in apparently unexposed populations, their identification is highly subjective, and the implication of gaps is not known. The OECD Test Guideline 473 for the in vitro mammalian CA test recommends to count the gaps, but not to include them in the measure of total CA (OECD 2016a). NTP also considered studies that measured aberrations in chromosome 5, 7, or 11 to support the CA data because a higher number of aberrations in these three chromosomes have been reported in patients following administration of cancer chemotherapy agents for treatment of cancer [reviewed in McDiarmid et al. (2010)].

##### Summary

Based on the available studies, there is a moderate confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with increased structural CA. A clear majority of studies reporting on percentage of cells with CA and number of aberrations per 100 cells scored reported significantly higher effects in individuals with occupational exposure to chemotherapy agents (Table F-1). Eleven of 14 studies reporting on percentage of cells with CA and 11 of 17 studies reporting on the number of aberrations per 100 cells scored reported significantly higher effects on exposed subjects compared to control subjects. Four studies evaluated both CA measurements and reported similar results for each endpoint (El-Ebiary et al. 2013; Jakab et al. 2001; Kopjar et al. 2009; Sorsa et al. 1988). Similarly, a preliminary study by Mušák et al. (2006) reported a non-significant (p = 0.07) number of CA in healthcare workers in Slovakia, which was corroborated by a larger study of the same population that reported significantly higher percentage of cells with CA compared to unexposed subjects (Mušák et al. 2013). Furthermore, two studies evaluating CA in chromosomes 5, 7, and 11 also support higher number of CA for individuals with occupational chemotherapy exposure. Specifically, samples from the same population of nursing and pharmacy personnel reported a significantly higher number of CA on chromosome 5 following occupational exposure to alkylating (McDiarmid et al. 2010) as well as non-alkylating agents compared to unexposed subjects (McDiarmid et al. 2014). The initial rating of moderate confidence in the body of evidence was not downgraded or upgraded for various factors (Figure 6). Therefore, the final rating of moderate confidence in the body of evidence directly translates into a rating of a moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with structural CA.

##### Overview

The NTP evaluation identified 29 studies of 26 unique populations reporting structural CA (% of cells with CA, number of CA/100 cells scored, or incidence rate ratio of CA) resulting from direct DNA breakage, replication on a damaged DNA template, inhibition of DNA synthesis and other mechanisms (e.g., inhibition of topoisomerase II enzymes) in peripheral blood lymphocytes arrested at metaphase. The available epidemiological studies in the body of evidence that evaluated the association between occupational exposure to cancer chemotherapy and CA included: 28 cross-sectional studies of medical personnel as well as chemists, laboratory assistants, and production or manufacturing workers, and one prospective cohort study of pharmacists (Table F-1). The majority of the studies evaluated nurses or pharmacy personnel, while drug production or manufacturing employees were the subject of only three studies. The studies varied greatly in continent where the study was conducted (Europe = 20 studies, Middle East = five studies, North America = three studies, and Asia = one study), size (from 12 to 594 subjects), and length of time in job position (>6 months to 25 years). Some of the studies also measured other DNA damage endpoints, such as MN induction or comet assay (see following sections for discussion of these other health outcomes).

##### Evidence Synthesis

The evidence synthesis for percentage of cells with CA (excluding gaps) was based on 14 studies (Table F-1), including one prospective cohort study of pharmacists (Roth et al. 1994) and 13 cross-sectional studies evaluating nurses, pharmacists, physicians, and other health workers as well as studies evaluating employees of drug production and manufacturing facilities (Anwar et al. 1994; Burgaz et al. 2002; El-Ebiary et al. 2013; Hola et al. 1988; Jakab et al. 2001; Kopjar et al. 2009; Medková 1990; Mušák et al. 2013; Nikula et al. 1984; Pohlová et al. 1986; Rubeš et al. 1998; Sessink et al. 1994a; Sorsa et al. 1988). The results show a consistent increase in CA as measured by an increase in the percentage of cells with CA in occupationally exposed subjects. Eleven of the 14 studies reported significantly higher percentage of cells with CA in exposed subjects relative to controls (Figure D-6). Of the three studies reporting no difference between exposed and unexposed subjects, a study of exposed nurses in Turkey reported a non-significant higher percentage of cells with CA compared to unexposed, and exposure was a significant factor in the analysis of variance (Burgaz et al. 2002). The remaining two studies attributed the lack of effect on CA to the availability of safety equipment and use of personal protective equipment by the exposed subjects. A single prospective cohort of pharmacists in Finland reported no difference between exposed subjects and controls (Roth et al. 1994); the authors reported that all exposed subjects used personal protective equipment and prepared the drugs in a vertical laminar flow safety cabinet in an isolated negative-pressured laboratory, separate from other work areas. Sorsa et al. (1988) attributed the lack of difference in percentage off cells with CA to improvements in the proper exposure prevention practices; however, the controls in the factory had higher number of CA than controls from outside the factory.

The evidence synthesis for the number of CA per 100 cells scored (excluding gaps) was based on 17 cross-sectional studies of nurses, pharmacists, and physicians handling cytostatic agents as well as workers in production and manufacturing of these agents (Table F-1) (Bouraoui et al. 2011; Cavallo et al. 2005; Cooke et al. 1991; El-Ebiary et al. 2013; Grummt et al. 1993; Jakab et al. 2001; Kopjar et al. 2009; Krepinsky et al. 1990; Mahmoodi et al. 2017; Milković-Kraus and Horvat 1991; Moretti et al. 2015; Mušák et al. 2006; Sorsa et al. 1988; Stücker et al. 1986; Testa et al. 2007; Thulin et al. 1995; Yang et al. 2002b). The results show a consistent increase in CA as measured by the number of CA per 100 cells in occupationally exposed subjects. Eleven of the 17 cross-sectional studies reported that occupational exposure to cancer chemotherapy agents resulted in a significantly higher number of CA per 100 cells scored (Figure D-7). Of the six studies that did not report a significant association for CA, a study of health workers in Slovakia reported that exposed subjects tended (p = 0.07) to have a higher number of CA than controls (Mušák et al. 2006); the authors subsequently published a larger study of the same population that found a significantly higher percentage of cells with ≥1 CA (Mušák et al. 2013). Two studies of drug production workers in Finland (Sorsa et al. 1988) and Sweden (Thulin et al. 1995) reported similar number of CA compared to unexposed workers; the authors stated that employees wore appropriate personal protective equipment and used safety equipment (e.g., personal fresh-air devices, gas-protective suits). Cooke et al. (1991) attributed the lack of difference between exposed pharmacists and nurses and the control subjects in the United Kingdom to the appropriate use of personal protective equipment and safety equipment (i.e., biological safety cabinets), and the fact the exposed nurses were only responsible for administering, but not preparing, the cancer chemotherapy doses. In a study of nurses in France, Stucker et al. (1986) suggested that the lack of effect on the number of CA may be due to less frequent handling of cancer chemotherapy agents in the pneumology department of this study, relative to studies that examine medical staff working in oncology departments. Finally, Krepinsky et al. (1990) suggested that the variability in the dose and frequency of handling of cancer chemotherapy agents among the exposed nurses in may have contributed to the observation of no difference compared to unexposed nurses.

Further support for an association between occupational exposure to cancer chemotherapy agents and induction of CA was provided by McDiarmid and colleagues, who examined the number of aberrations at chromosomes 5, 7, and 11 in a group of nurses, pharmacists, and pharmacy technicians in three university-based hospital cancer centers in the United States (McDiarmid et al. 2010; McDiarmid et al. 2014). The exposed subjects were asked to maintain a 6-week daily diary of the types and frequency of cancer chemotherapy drugs they handled as well as any unusual events (e.g., accidents). The data were presented as incidence rate ratios (IRR) that described the association between the number of CA predicted by the model at the select drug-handling frequencies compared with the number of CA at zero drug-handling events (controls). Significantly higher IRRs of aberrations were observed in chromosome 5 as the number of handling events increased for either alkylating agents (McDiarmid et al. 2010) or non-alkylating agents (e.g., anthracycline antibiotics, biologics, antimetabolites) (McDiarmid et al. 2014). The IRRs of aberrations at chromosome 7 and 11 were also increased in a dose-related manner for either alkylating agents or non-alkylating agents, but did not reach statistical significance (McDiarmid et al. 2010; McDiarmid et al. 2014).

##### Risk-of-bias Assessment

Risk of bias was assessed for all 29 included studies reporting on percentage of cells with CA, number of CA per 100 cells scored, (Figure D-8 and Figure D-9) and number of aberrations on chromosome 5, 7, or 11 (data not graphed).

Most studies were rated probably low risk of bias for confounding because they evaluated the key confounders and addressed differences in age, sex, smoking status, and possible co-exposure to other genetic toxicants (e.g., ionizing radiation). One study was rated definitely high risk of bias for confounding because the authors did not adjust for age although they reported that controls were significantly older than exposed pharmacists, which could bias the results toward the null (Cooke et al. 1991); the authors reported no difference in number of CA/100 cells. Nine studies receiving a rating of probably high risk of bias for confounding due to either lack of adjustment for confounding variables or insufficient information on how confounders were assessed (Hola et al. 1988; Jakab et al. 2001; Medková 1990; Mušák et al. 2006; Rubeš et al. 1998; Sessink et al. 1994a; Stücker et al. 1986; Thulin et al. 1995; Yang et al. 2002b). Lack of adjustment for confounders did not appear to influence the outcome for one study; thus, it was rated as probably low risk of bias for confounding (Nikula et al. 1984). Specifically, a study of nurses from Finland reported that 6 of 16 unexposed subjects were exposed to other chemicals (e.g., organic solvents) while exposed subjects were not similarly co-exposed (Nikula et al. 1984); the co-exposure did not appear to influence the results toward the null as the exposed subjects had a significantly greater percentage of cells with CA.

Most studies were rated probably low risk of bias for exposure characterization because exposure was based on job title in combination with work tasks (e.g., preparation and/or administration of cancer chemotherapy agents, handling patient excreta) and drug handling (e.g., frequency of drug handling, doses administered). Many studies also collected and reported on the level of safety protection available (e.g., biological safety cabinet, isolated room for drug preparation) and personal protective equipment used (e.g., gloves, masks, aprons). Two studies were ranked probably low risk of bias for exposure characterization because the authors further characterized exposure by requiring exposed participants to maintain a 6-week daily diary of the agents used, the frequency of handling each agent as well as any usual events (e.g., accidents) (McDiarmid et al. 2010; McDiarmid et al. 2014), which allowed the authors to analyze the data number of handling events. Biomonitoring further supported a rating of probably low risk of bias because a majority of the exposed subjects (eight of 12 exposed drug manufacturing workers) had levels of cyclophosphamide in their urine above the LOD, while urine samples from all control subjects were below the LOD (Sessink et al. 1994a). Three other studies reporting on biomonitoring of urine samples did not provide further support for a rating of probably low risk of bias rating because two studies reported very few of the urine samples had levels of the agent(s) above the LOD (Cavallo et al. 2005; Moretti et al. 2015), and another study detected cyclophosphamide in the urine samples 12 of the 12 exposed subjects tested, but did not test samples from unexposed subjects (Burgaz et al. 2002).

For outcome assessment, all studies included in the evidence synthesis followed a standard protocol and most studies included blinding of outcome assessors to the exposure status of the participants resulting in a rating of probably low risk of bias. Five studies did not report whether there was blinding for outcome assessment [two studies measuring percentage of cells with CA (Hola et al. 1988; Rubeš et al. 1998) and three studies reporting on the number of CA/100 cells (Krepinsky et al. 1990; Stücker et al. 1986; Yang et al. 2002b)], which resulted in a rating of probably high risk of bias for outcome assessment.

##### Confidence Ratings and Level-of-evidence Conclusions

The initial rating of moderate confidence in the body of evidence for CA, including percentage of cells with CA and number of CA per 100 cells scored, was not downgraded or upgraded for various factors (Figure 6). The final rating of moderate confidence in the body of evidence did not change when NTP excluded the study with definitely high risk of bias for confounding (Cooke et al. 1991).

#### Micronucleus Induction

The NTP evaluation identified 35 studies of 32 unique populations reporting MN induction and focused the level-of-evidence conclusions on studies reporting on the number of micronucleated cells per 1,000 cells scored (also called number of cells with micronuclei (MN)) and the number of MN per 1,000 cells scored. This assay detects MN in the cytoplasm of interphase cells, which may arise from acentric chromosome fragments or whole chromosomes that cannot migrate to the poles during cell division. Micronucleus induction signify structural or numerical chromosomal alterations that have been transmitted to daughter cells. The number of micronucleated cells per 1,000 cells scored is the most precise measure and is recommended by the 2014 OECD Testing Guidelines for the In Vitro Micronucleus Test (OECD 2016b). NTP also evaluated the number of MN per 1,000 cells scored because it is a frequently reported endpoint; however, this measure is considered slightly less reliable because a cell can have more than one micronucleus. Micronuclei induction was evaluated in two cells types: binucleated lymphocytes and buccal cells. The NTP evaluation used the abbreviation MN for both the singular (micronucleus) and plural forms (micronuclei) of the word, as applicable.

##### Summary

Based on the available studies, there is moderate confidence in the body of evidence that occupational exposure to cancer chemotherapy is associated with greater MN induction. Eleven of 13 studies measuring the number of cells with MN and 16 of 26 studies reporting on the number of MN per 1,000 cells scored reported significantly greater effects in exposed subjects compared to unexposed subjects (Table F-1). Four studies evaluated both measurements of MN and reported similar results for each endpoint (Deng et al. 2006; Deng et al. 2005; Kašuba et al. 1999; Kopjar et al. 2009). In addition, three sets of studies—(Boughattas et al. 2010; Bouraoui et al. 2011), (Garaj-Vrhovac and Kopjar 1998; Kašuba et al. 1999), and (Sorsa et al. 1988; Yager et al. 1988)—evaluated the three similar or overlapping populations and reported consistent results with the exception of Yager et al. (1988), which included an extra group of oncology nurses with a high number of MN compared to Sorsa et al. (1988). The initial rating of moderate confidence in the body of evidence was not downgraded or upgraded for various factors (Figure 7). The final confidence rating in the body of evidence directly translates into a rating of moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with MN induction.

##### Overview

The available epidemiological studies in the body of evidence that evaluated the association between occupational exposure to cancer chemotherapy and MN induction included 34 cross-sectional studies of medical personnel as well as chemists, laboratory assistants, and production or manufacturing workers; and one prospective cohort study of pharmacists (Table F-1). Most studies evaluated nurses, while drug production or manufacturing employees were the least studied (four studies). The studies varied greatly in country of origin (Europe = 20, Middle East = 5, Asia = 4, South America = 3, and North and Central America = 2), size (from n = 20 to 156), and length of time in job position (1 month to 30 years). Some of the studies also measured other DNA damage endpoints, such as CA or comet assay (see other sections of Results and Evidence Synthesis for discussion of these other health outcomes).

##### Evidence Synthesis

The evidence synthesis for the number of cells with MN per 1,000 cells scored was based on 13 studies (Table F-1): one prospective cohort study of pharmacists (Roth et al. 1994) and 12 cross-sectional studies evaluating nurses, doctors, pharmacists and production workers (Anwar et al. 1994; Boughattas et al. 2010; Buono-Michel et al. 2000; Deng et al. 2006; Deng et al. 2005; Kašuba et al. 1999; Kopjar et al. 2009; Machado-Santelli et al. 1994; Maluf and Erdtmann 2000b; Rodríguez-Montero et al. 2016; Rombaldi et al. 2009; Yang et al. 2002b). The results show a consistently higher number of cells with MN per 1,000 cells scored in exposed subjects relative to controls (Figure D-10). Eleven of the 13 studies reported a significantly higher number of cells with MN in exposed subjects relative to controls. Of the two studies reporting negative a lack of effect on MN, a study of nurses and pharmacists in Brazil reported no difference in the number of cells with MN compared to unexposed subjects following an adjustment in the work schedule to limit exposure and the hiring of additional employees (Maluf and Erdtmann 2000b); four years prior, this population reported a significantly higher number of cells with MN in exposed subjects than controls. A prospective cohort of pharmacists in Finland reported no difference between exposed subjects and controls (Roth et al. 1994), which the authors attribute to the use of personal protective equipment and the availability of a vertical laminar flow safety cabinet for drug preparation in an isolated negative-pressured laboratory, separate from other work areas.

The evidence synthesis for the number of MN/1,000 cells scored was based on 26 cross-sectional studies evaluating 23 unique populations of nurses, doctors, pharmacists and drug production workers (Table F-1) (Bolognesi et al. 2005; Bouraoui et al. 2011; Burgaz et al. 1999; Cavallo et al. 2005; Cornetta et al. 2008; Deng et al. 2006; Deng et al. 2005; El-Ebiary et al. 2013; Ensslin et al. 1997; Garaj-Vrhovac and Kopjar 1998; Harris et al. 1992; Hessel et al. 2001; Kašuba et al. 1999; Kevekordes et al. 1998; Kopjar et al. 2009; Ladeira et al. 2014; Laffon et al. 2005; Mahmoodi et al. 2017; Moretti et al. 2015; Moretti et al. 2013; Mrđanović et al. 2012; Pilger et al. 2000; Rekhadevi et al. 2007; Sorsa et al. 1988; Thiringer et al. 1991; Yager et al. 1988). The results show a consistent increase in MN induction as measured by an increase in the number of MN/1,000 cells scored in exposed subjects relative to control subjects (Figure D-11 and Figure D-12). Sixteen of 26 studies reported a significantly higher number of MN/1,000 cells scored in exposed subjects compared to controls. Of the nine studies reporting no effect of exposure, a study of exposed medical workers including nurses, pharmacy personnel, one physician, and one orderly in Germany did not observe any difference in the number of MN compared to unexposed office workers (Hessel et al. 2001); frequency of drug handling of the exposed subjects was not reported. Moretti et al. (2013) reported no significant differences in the number of MN between exposed workers in a hospital in Italy responsible for preparation, transport, administration, and disposal of cancer chemotherapy agents unexposed blood donors, but did report a significantly higher level of DNA damage measured by tail intensity in exposed subjects. Eight studies reported a lack of effect of occupational exposure on the number of MN in nursing and pharmacy personnel that used personal protective equipment and/or prepared drugs in vertical laminar flow safety cabinets (Bolognesi et al. 2005; Cavallo et al. 2005; Ensslin et al. 1997; Harris et al. 1992; Laffon et al. 2005; Moretti et al. 2013; Pilger et al. 2000; Thiringer et al. 1991). Harris et al. (1992) also observed that nurses with low and moderate exposure that used gloves <100% of the time had significantly higher number of MN compared to nurses using gloves 100% of the time. Finally, one study of drug production and manufacturing workers, and associated laboratory technicians in Finland reported a non-significant higher number of MN compared to unexposed workers following exposure safety protection improvements (Sorsa et al. 1988). Of note, two studies reported contrasting results for number of MN from studies overlapping in the population under study. While Sorsa et al. (1988) reported no effect on the number of MN, Yager et al. (1988) tested the same population and included an extra group of exposed workers in their study (oncology nurses) who had a higher number of MN than the other exposed groups; the authors combined the data for all the exposed workers and observed a significantly higher number of MN when analyzed by an ANOVA of the log-transformed data (Yager et al. 1988).

##### Risk-of-bias Assessment

Risk-of-bias assessment was conducted on all studies included in the evidence synthesis for MN induction presented number of cells with MN per 1,000 cells scored and number of MN per 1,000 cells scored (Figure D-13 and Figure D-14). Similar to the body of evidence for CA, most studies on MN induction were rated probably low risk of bias for confounding (e.g., appropriate confounders were considered and adjusted when necessary) and outcome assessment (e.g., the assessors were generally blinded to treatment), as well as probably high risk of bias for exposure characterization due to exposure classification by job position without confirmation of exposure from biomonitoring measurements.

Most studies were rated as probably low risk of bias for confounding. Two studies were rated as definitely high risk of bias for confounding (Ensslin et al. 1997; Kašuba et al. 1999). In a study reporting no difference in the number of MN per 1,000 cells scored between exposed pharmacists (n = 13 subjects) and controls (n = 13 subjects) in Germany, Ensslin et al. (1997) did not adjust for reported differences in sex and smoking status between exposed and control subjects (women: controls = 11 of 13 and exposed = 8 of 13; smoking: controls = 4 of 13 and exposed = 1 of 13), which could have biased the results toward the null. Kašuba et al. (1999) did not adjust for a higher number of exposed subjects co-exposed to ionizing radiation (7 of 20) compared to controls exposed (1 of 16), which could have biased the results away from the null; this study observed a significantly higher number of MN per 1,000 cells scored in exposed nurses relative to control subjects. Four studies did not report confounding variables or the methods used to collect data on confounding (Deng et al. 2006; Garaj-Vrhovac and Kopjar 1998; Harris et al. 1992; Yager et al. 1988; Yang et al. 2002b). One study was rated probably low risk of bias even though the authors did not adjust for significant covariates. Hessel et al. (2001) did not directly adjust the results for a significantly greater number of men in the controls versus the exposed pharmacy personnel in Germany, which could have biased the results away from the null: however, there was no difference in the number of MN/1,000 cells scored between exposure groups.

Similar to studies assessing CA, most studies were rated probably low risk of bias for exposure characterization because exposure was based on job title in combination with work tasks (e.g., preparation and/or administration of cancer chemotherapy agents, handling patient excreta) and drug handling (e.g., frequency of drug handling, doses administered). Many studies also collected and reported on the level of safety protection available (e.g., biological safety cabinet, isolated room for drug preparation) and personal protective equipment used (e.g., gloves, masks, aprons). Urine biomonitoring results did not provide further support for a rating of probably low risk of bias for five studies testing urine samples from both exposed and unexposed subjects (Bolognesi et al. 2005; Cavallo et al. 2005; Ensslin et al. 1997; Moretti et al. 2015; Pilger et al. 2000) as none of the studies reported positive samples for a majority of the exposed subjects. Another MN study that measured cyclophosphamide in urine of exposed and unexposed occupationally exposed hospital, pharmacy, and medical personnel reported no correlation between a positive urine sample ≥ LOD versus urine samples that measured < LOD (Hessel et al. 2001). Two studies reported positive biomonitoring results in a majority of exposed subjects, but did not test unexposed subjects (Burgaz et al. 1999; Rekhadevi et al. 2007); specifically, cyclophosphamide was above the LOD in urine samples of 19 of 25 (Burgaz et al. 1999) and 42 of 52 exposed nurses (Rekhadevi et al. 2007).

Regarding risk of bias for outcome assessment, 11 studies did not report blinding and the authors did not respond to NTP’s request for information (Bolognesi et al. 2005; Boughattas et al. 2010; Buono-Michel et al. 2000; Cornetta et al. 2008; Deng et al. 2006; Deng et al. 2005; Ensslin et al. 1997; Garaj-Vrhovac and Kopjar 1998; Kašuba et al. 1999; Yager et al. 1988; Yang et al. 2002b).

##### Confidence Ratings and Level-of-evidence Conclusions

The initial rating of moderate confidence in the body of evidence for MN, including number of cells with MN/1,000 cells scored and number of MN/1,000 cells scored, was not downgraded or upgraded for various factors (Figure 7). The final rating of moderate confidence in the body of evidence did not change when NTP excluded the studies with definitely high risk of bias for confounding.

#### DNA Damage Measured by the Comet Assay

The NTP evaluation identified 21 studies of 18 unique populations reporting DNA damage measured by the comet assay. The level-of-evidence conclusions were based on studies reporting the following four measurements: the percent of tail DNA (also called % tail intensity), tail length (μm), tail moment, and DNA damage index. The percent of tail DNA corresponds to the fraction of DNA intensity of the comet tail relative to total intensity (head plus tail); this comet assay measurement is recommended for use by the OECD Testing Guideline for In Vivo Mammalian Comet Assay (OECD 2016c). Tail length is the maximum length of DNA migration and is measured either from the center of the head or the leading edge of the head to the tip of the tail. Tail moment may be measured as extent tail moment (% tail DNA multiplied by tail length) or Olive tail moment (% tail DNA multiplied by tail moment length; tail moment is calculated as length from the center of the head to the center of the tail). Tail length and tail moment are considered acceptable measurements if an image analysis software system is used to score slides. However, tail moment is not a recommended measurement for comet assay due to variability in the methods to calculate tail moment (OECD 2016c) and the fact that tail moment has no units attached to it. Another commonly reported measurement of comet assay was a DNA damage index, which was a sum of the cells with DNA damage weighted by the severity of damage; this method is not among the recommended measured by the OECD (2016c). The majority of studies evaluated either lymphocytes or leukocytes. For accurate comet assay results, the OECD guidelines state that samples must be kept ice-cold, or frozen, until processing. Otherwise, enzymes will act to repair any damaged DNA and may cause the test results to be inaccurate.

##### Summary

Based on the available studies, there is a moderate confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with increased DNA damage measured by the comet assay. Five of seven studies reporting on percent of tail DNA, 10 of 11 studies reporting on tail length (μm), and five of five studies reporting a DNA damage index reported significantly higher rates of DNA damage compared to unexposed subjects (Table F-1). Only two of seven studies reporting on tail moment reported significantly higher levels of DNA damage in exposed subjects than controls; however, tail moment is not recommended measurement by the OECD due to variability in methods to calculate tail moment (OECD 2016c). Seven studies evaluated two or more tail measurements (Connor et al. 2010; Deng et al. 2006; Deng et al. 2005; Kopjar and Garaj-Vrhovac 2001; Sasaki et al. 2008; Villarini et al. 2011; Yin et al. 2010); however, only three studies reported consistent results between each endpoint (Connor et al. 2010; Kopjar and Garaj-Vrhovac 2001; Yin et al. 2010); tail length and tail moment were the most common endpoint with no difference compared to unexposed subjects. The initial rating of moderate confidence in the body of evidence was not downgraded or upgraded for various factors (Figure 8). The final rating of moderate confidence in the body of evidence directly translates into a rating of moderate level of evidence that occupational exposure to cancer chemotherapy agents is associated with DNA damage measured by comet assay.

##### Overview

The available epidemiological studies in the body of evidence that evaluated the association between occupational exposure to cancer chemotherapy and DNA damage measured by comet assay included one prospective cohort study (Mader et al. 2009) and 20 cross-sectional studies of medical personnel as well as chemists, laboratory assistants, and production or manufacturing workers); and one prospective cohort study of pharmacists (Table F-1). Most the studies evaluated nursing and pharmacy personnel, while drug production or manufacturing employees were the least studied (only two studies). The studies originated from 10 countries: Italy (n = 5), China (n = 4), Brazil (n = 2), Croatia (n = 2), Japan (n = 2), Turkey (n = 2), Austria (n = 1), India (n = 1), Portugal (n = 1), and United States (n = 1). The studies varied in number of participants (from n = 15 to 167), and length of time in job position (2.4 months to 23 years). Some of the studies also measured other DNA damage endpoints, such as CA or MN induction (see other sections of Results and Evidence Synthesis for discussion of these other health outcomes).

##### Evidence Synthesis

The evidence synthesis for percent of tail DNA was based on the seven cross-sectional studies of nurses, pharmacists, and health workers handling cytostatic agents (Table F-1) (Buschini et al. 2013; Connor et al. 2010; Cornetta et al. 2008; Kopjar and Garaj-Vrhovac 2001; Moretti et al. 2013; Villarini et al. 2011; Yin et al. 2010). The results show a consistently higher rate of DNA damage measured by comet assay as measured by percent of tail DNA in exposed subjects relative to controls (Figure D-15). Five of seven studies reported that exposed subjects had a higher percent of tail DNA than controls (Cornetta et al. 2008; Kopjar and Garaj-Vrhovac 2001; Moretti et al. 2013; Villarini et al. 2011; Yin et al. 2010). The observation of no effect of exposure in a study of nurses in Italy may have been due to the lack of chilling the blood samples upon collection (Buschini et al. 2013); a lack of chilling may allow DNA repair enzymes to correct DNA damage thus biasing toward the null. A study of nurses, pharmacists, and pharmacist technicians in the United States reported a lack of effect of exposure, which the authors attributed to adequate provision of safety equipment and use of personal protective equipment by the exposed personnel (Connor et al. 2010).

The evidence synthesis for tail length was based on 11 cross-sectional studies reporting on nurses, physicians, and production workers handling cancer chemotherapy agents (Table F-1). The results show a consistently higher rate of DNA damage measured by comet assay as measured by tail length in exposed subjects relative to controls (Figure D-16). Ten of 11 studies reported significantly greater tail length (μm) in exposed subjects relative to controls (Deng et al. 2006; Deng et al. 2005; Kopjar and Garaj-Vrhovac 2001; Kopjar et al. 2009; Laffon et al. 2005; Rekhadevi et al. 2007; Sasaki et al. 2008; Yang et al. 2002a; Yin et al. 2010; Yoshida et al. 2006). One study of health workers in Italy reported no difference in tail length between exposed and control subjects (Villarini et al. 2011); however, the authors reported significantly greater percent of tail DNA in exposed subjects than controls from the same study.

The evidence synthesis for tail moment was based on seven cross-sectional studies reporting on nurses, pharmacists, physicians, and production workers working with cancer chemotherapy agents (Table F-1). The results for tail moment showed a less consistent effect of higher DNA damage measured by comet assay as were observed for percent of tail DNA or tail length, with only two studies reporting significantly greater mean tail moment compared to unexposed subjects (Kopjar and Garaj-Vrhovac 2001; Yin et al. 2010) (Figure D-17). Of the five studies reporting a lack of effect on tail moment, Connor et al. (2010) also reported no effect on percent of tail DNA or tail length, which the authors attributed to proper use of personal protective equipment and other safe handling practices. Tail moment appeared to be a less sensitive DNA damage endpoint for three other studies that reported significant effects of occupational exposure on percent of tail DNA (Villarini et al. 2011) or tail length (Deng et al. 2006; Deng et al. 2005). Ursini et al. (2006) reported that exposed nurses had similar tail moment values to unexposed nurses, which they attributed to the use of personal protective equipment and the use of specialized pharmacy to use the drugs, which meant that the nurses were not involved in drug preparation. However, the authors did not chill blood samples prior to processing, which may have contributed to the lack of difference in tail moment between exposed subjects and controls (Ursini et al. 2006). Another study reported no difference in the log-transformed values of mean tail moment between exposed nurses and unexposed nurses (Sasaki et al. 2008).

The evidence synthesis for studies reporting a DNA damage index measured by comet assay was based on one longitudinal cohort study spanning 9 months (Mader et al. 2009) and four cross-sectional studies reporting on nurses and pharmacists (Izdes et al. 2009; Maluf and Erdtmann 2000b; Rombaldi et al. 2009; Ündeğer et al. 1999) (Table F-1). The results for DNA damage measured as DNA damage index by comet assay were consistent with all five studies reporting significantly higher number of cells with DNA damage than controls (Figure D-18). All five studies evaluated the proportion of DNA fragments in the tail; however, the number of cells evaluated, the number of categories, and the data presentation differed among the studies (see footnote of Figure D-18 for more details).

##### Risk-of-bias Assessment

Risk-of-bias assessment was conducted on all included studies reporting on DNA damage measured by comet assay including measurements of percent of tail DNA, tail length, tail moment, and DNA damage index (Figure D-19 and Figure D-20). Like the body of evidence for CA and MN, most studies on DNA damage measured by comet assay were rated probably low risk of bias for confounding (e.g., appropriate confounders were considered and adjusted when necessary), exposure assessment, and outcome assessment (e.g., the assessors were generally blinded to treatment).

Regarding confounding, a study reporting significantly higher tail length in exposed physicians and nurses in Croatia versus controls was rated definitely high risk of bias because there was no adjustment for sex even though all exposed subjects were females compared to 50% of control subjects, which could bias the results away from the null (Kopjar and Garaj-Vrhovac 2001). One study was rated probably high risk of bias: a cross-sectional study reporting a greater tail length in exposed nurses in China versus controls did not report the gender of the participants [presumed female] and did not adjust for age differences between controls were younger than exposed subjects (average age 18 years versus 29 years), which could have biased the results away from the null (Yang et al. 2002a).

All studies were rated probably low risk of bias for exposure characterization because exposure was based on job title in combination with work tasks (e.g., preparation and/or administration of cancer chemotherapy agents, handling patient excreta) and drug handling (e.g., frequency of drug handling, doses administered). Many studies also collected and reported on the level of safety protection available (e.g., biological safety cabinet, isolated room for drug preparation) and personal protective equipment used (e.g., gloves, masks, aprons). Urine biomonitoring was conducted in both exposed and unexposed subjects of three studies (Connor et al. 2010; Ursini et al. 2006; Villarini et al. 2011); none of the studies reported positive samples for a majority of the exposed subjects and the biomonitoring was consistent with no difference in comet assay measurements compared to unexposed subjects of these studies (Connor et al. 2010; Ursini et al. 2006). One study conducted biomonitoring in exposed subjects only and reported that cyclophosphamide was above the LOD in urine samples of 42 of 52 exposed nurses (Rekhadevi et al. 2007).

For outcome assessment, two studies reporting no difference in DNA damage measured by comet assay compared to unexposed subjects reported that blood samples were maintained at room temperature after sample collection, which resulted in definitely high risk of bias [tail moment in (Ursini et al. 2006)] or probably high risk of bias [% tail DNA in (Buschini et al. 2013)]; author responded to query for information about methods). For six studies, a rating of probably high risk of bias for blinding for lack of reporting on blinding was upgraded to probably low risk of bias due to use of automated methods for outcome assessment (Connor et al. 2010; Cornetta et al. 2008; Sasaki et al. 2008; Ursini et al. 2006; Yin et al. 2010; Yoshida et al. 2006). Seven studies did not report the methods used for the comet assay or sample processing details and, thus, were assigned probably high risk of bias (Cornetta et al. 2008; Deng et al. 2006; Deng et al. 2005; Mader et al. 2009; Ündeğer et al. 1999; Yang et al. 2002a; Yin et al. 2010).

##### Confidence Ratings and Level-of-evidence Conclusions

The initial rating of moderate confidence in the body of evidence for DNA damage measured by the comet assay, including percent tail DNA, tail length and tail moment, and DNA damage index, was not upgraded or downgraded for factors affecting confidence in the body of evidence (Figure 8). The final rating of moderate confidence in the body of evidence did not change when NTP excluded data on tail moment due to known heterogeneity across laboratories in calculating the outcome measurement (OECD 2016c).

## Evidence of Occupational Exposure to Cancer Chemotherapy Agents

The NTP evaluation reviewed the literature reporting on environmental monitoring of the workplace (e.g., surfaces, air) and biomonitoring surveillance (e.g., urine or blood levels) of cancer chemotherapy agents in occupationally exposed personnel to determine the prevalence of contamination of the work environment and internal doses to personnel. The studies are available in Appendix I in Supplemental Table 1 (Environmental Monitoring) and Supplemental Table 2 (Biomonitoring). The following details were collected per study: citation, publication year, study country, study setting, sampling year (date samples were collected), samples taken (type of cancer chemotherapy agent measured), sensitivity of contaminant measurements (limit of detection or limit of quantitation), and summary of results. Guidelines for safe handling of cancer chemotherapy agents were first issued in the 1980s by professional trade organizations and federal agencies of several countries, including the United States (OSHA 1986). Since that time, additional guidelines have been written and revised for handling cancer chemotherapy agents and other hazardous drugs by 13 different countries [reviewed in Bernabeu-Martinez et al. (2018)]. One of NTP’s original goals for Objective 2 of the evaluation was to identify whether levels of contamination had declined in the years since implementation of the 1986 guidelines in the United States and other countries. However, NTP found this objective was challenging to address because the data were not always expressed in the same increment of measure, the same type of sample (e.g., air versus wipe sample, urine versus blood), the same chemotherapy agent (e.g., cyclophosphamide versus 5-fluorouracil), or the same type of sample location (e.g., worktop of the biological safety cabinet versus patient drug administration area). For this reason, NTP selected cyclophosphamide as a surrogate cancer chemotherapy agent and compared studies that measured the same type of sample with the same increments of measure, regardless of the country of origin of the study.

### Environmental Monitoring

The NTP evaluation identified 104 studies reporting on environmental monitoring ranging in publication dates from 1983 to 2017 and years sampled from 1981 to 2016 (Supplemental Table 1 in Appendix I). The studies tested for contamination on a range of samples, including air, cleaning water, gloves, vials, and work surfaces (e.g., floor, biological safety cabinet, and storage shelf). The studies tested and reported on 20 different cancer chemotherapy agents; cyclophosphamide was the most frequently evaluated agent (83 studies). Other agents frequently evaluated in environmental monitoring studies included: ifosfamide (n = 42), 5-fluorouracil (n = 35), methotrexate (n = 27), and platinum (a marker for platinum-containing agents, including cisplatin, carboplatin, and oxaliplatin; n = 18). The remaining agents were evaluated in seven or fewer studies (Supplemental Table 1 in Appendix I). The environmental monitoring studies were conducted in 18 countries. Thirty-nine percent of the studies were conducted in the United States or Canada (41 studies; United States, n = 22, and Canada, n = 18, and one study reporting on both countries), while 52% of the studies were conducted in Europe (54 studies; including studies in Italy (n = 11), the Netherlands (n = 9), and Germany (n = 7). In addition, there were three environmental monitoring studies each from Australia and Japan, and two studies each conducted in Brazil and Iran.

A majority of the environmental monitoring studies (96%; 100/104 studies) reported that one or more samples (e.g., wipe test, air filters) tested above the LOD for any of the cancer chemotherapy agents evaluated (Supplemental Table 1 in Appendix I). To observe possible trends in contamination of the workplace by cancer chemotherapy agents over time, NTP focused on the studies testing for cyclophosphamide because this agent was measured and reported in a majority of the studies available over a wide range of sampling years (1983–2016). Specifically, NTP evaluated the data for two areas of the drug preparation room that are frequently monitored: the workspace of the biological safety cabinet and the floor in front of the biological safety cabinet; 26 studies were available that reported the maximal level of surface contamination for these two areas. The maximum levels detected in the workspace of the biological safety cabinet ranged from < LOD to 1,193 ng/cm^2^ for the workspace of the biological safety cabinet (n = 22 studies) and < LOD to 402.5 ng/cm^2^ for the floor in front of the biological safety cabinet (24 studies) (Figure 9). The highest levels of cyclophosphamide surface contamination were reported for these two areas in 2004–2005 (maximum levels for workspace were 17.17–44.17 ng/cm^2^ and floor were 26.8–100 ng/cm^2^) (Acampora et al. 2005; Sessink et al. 2011; Sessink et al. 2013). The frequency of studies reporting wipe samples with maximum levels above 1.5 ng/cm^2^ was lower in 2011–2016 (38%, 3/8 studies) compared to 2005–2010 (67%, 4/7 studies) based on workspace measurements. However, for the floor samples, the frequency of studies reporting wipe samples with maximum levels above 1.5 ng/cm^2^ appears to have remained the same over time (2011–2016: 29%, 2/7 studies versus 2005–2010: 25%, 4/12).

Figure 9

Maximum Levels of Cyclophosphamide Contamination Reported for the Biological Safety Cabinet Workspace and Floor in Front of the Biological Safety Cabinet from 1993 to 2016

Data included 26 studies reporting maximum levels of cyclophosphamide contamination of the workspace of biological safety cabinet (also called hood) or isolator and the floor in front of this space (n = 19): (Acampora et al. 2005; Berruyer et al. 2015; Bigelow et al. 2009; Bussières et al. 2012; Chu et al. 2012; Connor et al. 1999; Couch and dePerio 2011; Couch et al. 2012; Couch and West 2012; Crauste-Manciet et al. 2005; Hedmer et al. 2008; Janes et al. 2015; Martins et al. 2008; McDevitt et al. 1993; Merger et al. 2014; Minoia et al. 1998; Odraska et al. 2014; Odraska et al. 2011; Schmaus et al. 2002; Sessink et al. 2013; Siderov et al. 2009; Touzin et al. 2009; Vandenbroucke and Robays 2001; Wick et al. 2003) Six references reported on floor samples only (Bigelow et al. 2009; Hedmer et al. 2008; Odraska et al. 2014; Odraska et al. 2011; Schmaus et al. 2002; Siderov et al. 2009) and one reference measured biological safety cabinet samples only (Schierl et al. 2016).

### Biomonitoring

The NTP evaluation identified 82 studies reporting biomonitoring of occupationally exposed workers. The studies included data collected in 1982–2016 (Supplemental Table 2 in Appendix I). Only four biomonitoring studies were conducted prior to or including 1986, when safe handling guidelines were first published (OSHA 1986). The studies reported on a total of 16 cancer chemotherapy agents or their metabolites with cyclophosphamide (54 studies) as the most frequently evaluated agent. Other agents frequently evaluated in biomonitoring studies include: ifosfamide (n = 19), platinum (as a marker of platinum-containing agents: cisplatin, carboplatin, and oxaliplatin; n = 21), methotrexate (n = 12), alpha-fluoro-beta-alanine (a metabolite of 5-fluorouracil; n = 9), and epirubicin (n = 8). The remaining agents were evaluated in six or fewer studies: azathioprine, daunorubicin, docetaxel, doxorubicin, etoposide, gemcitabine, idarubicin, mitomycin C, paclitaxel, and pemetrexed. The biomonitoring studies were conducted in 17 countries. Most of the studies (64%, n = 54) were conducted in Europe. Only 13% were conducted in the United States (six studies) and Canada (five studies), 16 studies in Asia, and one study in Africa. Biomonitoring studies primarily evaluated urine samples, although six studies also measured blood levels only and another five studies measured both blood and urine levels of these agents.

Most studies reported the detection of one or more cancer chemotherapy agent in blood or urine of occupationally exposed individuals (89%; n = 73 of 82 total studies) (Supplemental Table 2 in Appendix I). Of the 19 studies that also evaluated control (also called unexposed) subjects, seven studies reported samples above the level of detection for both exposed and control subjects (Ensslin et al. 1994a; Fransman et al. 2007b; Konate et al. 2011; Kopp et al. 2013a; Pilger et al. 2000; Ramphal et al. 2015; Sessink et al. 1994a; Sessink et al. 1994b), which suggested that environmental contamination that may be the issue. For example, in a small study of pharmacy personnel, Ramphal et al. (2015) reported that the urine samples both exposed and unexposed pharmacy staff tested positive for cyclophosphamide on the day they received training on use of the urine sample kits in the oncology laboratory (i.e., the five unexposed pharmacy staff were exposed by entering the oncology pharmacy). In a follow-up evaluation, urine samples tested positive for cyclophosphamide in one unexposed subject who reentered the oncology laboratory, while no agent was detected in samples of four unexposed subjects who did not re-enter the area; it was determined that there was surface contamination of cyclophosphamide and methotrexate both before and after cleaning (Ramphal et al. 2015). Nurses not handling cancer chemotherapy agents, but employed in an outpatient clinic where they were administered, had detectable levels of cyclophosphamide in their urine (Fransman et al. 2007b). Of note, Hon et al. (2015) evaluated employees in five acute care sites and one cancer center in Canada and observed that workers not responsible for handling the agents in the drug administration area (e.g., volunteers, oncologist, nurse aides, and dieticians) had the highest number of positive urine samples for cyclophosphamide. The authors reported there was no correlation between urinary concentration levels and known contact with the agents; however, the urine samples with the highest levels of cancer chemotherapy agents were from employees handling the highest doses, and even higher levels of cancer chemotherapy agents were detected in urine samples from employees who did not receive training in handling these drugs versus those employees who received the training.

To observe possible trends in the number of positive subjects reported in biomonitoring efforts, NTP focused on the studies testing for cyclophosphamide because of the number of studies available (54 studies) and the wide range of years tested (1984–2015). Of the 46 studies reporting the data on a per-subject (e.g., nurse) basis, cyclophosphamide was detected in 35 studies. Twelve studies reported no detection of the agent (Figure 10), including three studies with subjects that tested positive in previous sampling years (Sabatini et al. 2012; Sottani et al. 2010; Yoshida et al. 2013). An additional six studies evaluating the data on a per-sample (not per-subject) basis also detected cyclophosphamide in more than one sample (Fransman et al. 2007a; Peelen et al. 1999; Pethran et al. 2003; Sottani et al. 2008; Turci et al. 2011; Turci et al. 2002) (data not graphed). Thus, biomonitoring studies demonstrated that workers continue to be exposed to cancer chemotherapy agents in the workplace. It is observed that the LOD of cyclophosphamide in urine has decreased over time; the LODs for the studies in Figure 10 spanned a range from 0.1 to 1.0 ng/mL in 1992, which decreased to range from 0.009 to 0.1 ng/mL from 2011 to 2016. The prevalence of positive biomonitoring samples may be due to more sensitive analytical methods, as well as a higher volume of patients administered cancer chemotherapy agents.

Figure 10

Percent of Workers with Cyclophosphamide Detected Above the Level of Detection in Urine Samples Displayed by the Year Samples Were Collected (1985–2016)

Includes only studies reporting the number of positive subjects or studies for which the number of positive subjects could be determined from the number of samples reported (i.e., one urine sample per subject). Data from 46 studies, including: (Bolognesi et al. 2005; Burgaz et al. 1999; Burgaz et al. 2002; Canal-Raffin et al. 2016; Connor et al. 2010; Ensslin et al. 1997; Ensslin et al. 1994b; Evelo et al. 1986; Hama et al. 2012; Hama et al. 2009; Hedmer et al. 2008; Hirst et al. 1984; Hon et al. 2015; Karahalil and Ilter Akkoyunlu 2004; Kiffmeyer et al. 2002; Korczowska and Jankowiak-Gracz 2013; Maeda et al. 2010; Minoia et al. 1998; Miyake et al. 2013; Moretti et al. 2015; Nyman et al. 2007; Poupeau et al. 2017; Ramphal et al. 2015; Ramphal et al. 2014; Rekhadevi et al. 2007; Sabatini et al. 2012; Schreiber et al. 2003; Sessink et al. 1992a; Sessink et al. 1992b; Sessink et al. 1994a; Sessink et al. 2015; Sessink et al. 1994c; Sessink et al. 1997b; Sessink et al. 1993; Sottani et al. 2010; Sottani et al. 2012; Sugiura et al. 2011a; Sugiura et al. 2011b; Tanimura et al. 2009; Turci et al. 2011; Turci et al. 2002; Vandenbroucke and Robays 2001; Villarini et al. 2011; Wick et al. 2003; Yoshida et al. 2013; Yoshida et al. 2009; Yuki et al. 2015; Ziegler et al. 2002).

### Other Occupationally Exposed Populations

The potential for cancer chemotherapy exposure has increased as options for administration of treatment and the patients receiving these agents have expanded. One newer technique for administering chemotherapy directly to the target organ involves surgery. A study that evaluated platinum environmental surface levels and biomonitoring following a heated intraperitoneal perioperative chemotherapy (HIPEC) procedure using oxaliplatin detected platinum on both layers of the surgeon’s gloves (external gloves: 16,284.3 to 24,857.1 ng; internal gloves: 24.3 to 83.2 ng) and a small amount on the surgeon’s bare hands (2.0–2.2 ng); however, the urine samples of the surgeon and staff were negative for the agent (Konate et al. 2011). Nursing assistants and housekeeping at home care and nursing centers as well as staff at industry laundry centers maybe exposed to cancer chemotherapy agents through their duties of cleaning patients and emptying pot/urinals, and laundering exposed bed linens, respectively (Meijster et al. 2006). Although less frequently reported, laboratory animal care and veterinary staff are also potentially exposed to cancer chemotherapy agents due to companion animals administered cancer chemotherapy agents for the treatment of cancer. Sessink et al. (1993) reported detection of cyclophosphamide (700 ng) in 1 of 87 urine samples taken from four animal care workers handling mice injected with cyclophosphamide. In a study from Canada, Hall et al. (2013) estimated that 22–24% of veterinarians and 20–22% of veterinary technicians are exposed to cancer chemotherapy agents. Exposure may occur not only in preparing and administering these agents (Couch et al. 2013; Janssens et al. 2015a), but cancer chemotherapy agents have been also been detected blood samples (Knobloch et al. 2010), urine, feces, saliva, and cerumen (ear wax) of dogs several days following treatment (Janssens et al. 2015b). In addition to occupational exposure, family members and friends of patients receiving cancer chemotherapy agents may also be exposed to these agents. A cross-sectional study of family members of patients administered cyclophosphamide for breast cancer reported that 21% of the 243 urine samples (representing six of the 10 family members) tested positive for the agent (Yuki et al. 2015). The level of cyclophosphamide detected was similar in the urine samples of 4 of 6 of the family members (101.5–252 ng) compared to patients administered the drug (108.3–181.5), while urine samples from unexposed subjects were < LOD for cyclophosphamide. Individuals sharing a common bathroom or a higher amount of time in a common space with the cancer patient had the highest levels of cyclophosphamide in their urine (Yuki et al. 2015).