# Methods

## Problem Formulation and Protocol Development

Problem formulation activities and the systematic review methodology used to conduct this review were posted in a protocol in October 2015 (Appendix I). The protocol was based on: (1) deliberation with NTP staff and consultation with scientists at other federal agencies represented on the NTP Executive Committee;^1^ (2) discussions by the evaluation design team and other technical experts with backgrounds in occupational exposure to hazardous drugs (including cancer chemotherapy agents) and systematic review (see About This Review); (3) public review of the proposed evaluation during the April 16–18, 2014 meeting of the NTP Board of Scientific Counselors (BSC);^2^ (4) guidance outlined in the OHAT Handbook for Conducting a Literature-Based Health Assessment ([underlined: https://ntp.niehs.nih.gov/go/systematic_review]); and (5) external peer review of the draft protocol. A summary of the methods is presented below.

1 The NTP Executive Committee provides programmatic and policy oversight to the NTP Director and meets once or twice a year in closed forum. Members of this committee include the heads (or their designees) from the following federal agencies: Consumer Product Safety Commission (CPSC), Department of Defense (DoD), Environmental Protection Agency (EPA), Food and Drug Administration (FDA), National Cancer Institute (NCI), National Center for Environmental Health/Agency for Toxic Substances and Disease Registry (NCEH/ATSDR), National Institute of Environmental Health Sciences (NIEHS), National Institute for Occupational Safety and Health (NIOSH), Occupational Safety and Health Administration (OSHA).

2 During that meeting, the BSC members considered the evaluation a high priority and no public comments were received.

## PECO Statement

A PECO (Population, Exposure, Comparators, and Outcomes) statement was developed as an aid to identify search terms and inclusion/exclusion criteria for Objective 1 (Table 2).

Table 2 PECO Statement for Objective 1

Element | Type of Evidence
Population | Humans who may be exposed to cancer chemotherapy agents in their workplace, without restriction based on age or sex
Exposure | Exposure to cancer chemotherapy agents, including antineoplastic agents, synthetic hormones (e.g., tamoxifen), biologicals, and targeted therapies (e.g., imatinib) based on indirect measures such as job title and direct measures such as biomonitoring data (e.g., urine, blood, or other specimens), when available
Comparators | A comparison population exposed to lower levels (or no exposure/exposure below detection levels) of cancer chemotherapy agents in their workplace
Outcomes | Primary outcomes: Any adverse health effect (e.g., cancer, reproductive and developmental toxicity, immune system effects, kidney toxicity, liver toxicity, and acute effects [i.e., alopecia, nausea]) and genetic biomarkers of effect (specifically, chromosomal aberrations, micronucleus induction, and DNA damage measured by the comet assay) Secondary outcomes: Cellular, biochemical, or clinical chemistry changes in immune system, liver, kidney, reproductive, or other organ systems

The NTP evaluation included cancer chemotherapy agents, such as antineoplastic agents (e.g., alkylating agents, anthracycline antibiotics, antimetabolites), hormone therapies (e.g., tamoxifen), biologicals (e.g., interferon alpha, trastuzmab), and targeted therapies (e.g., tyrosine kinase inhibitor imatinib). The evaluation did not include occupational exposure to targeted radionuclide therapy (also called radiopharmaceuticals) (Gudkov et al. 2015).

For the evaluation of adverse health effects associated with occupational exposure to cancer chemotherapy agents (Objective 1), the primary focus was on clinical diseases and disorders (e.g., cancer, spontaneous abortion, congenital malformations, abnormal functioning of the immune system, kidney, liver), and recognized acute effects observed in patients receiving cancer chemotherapy (e.g., alopecia, nausea) and genetic toxicity. Only three genetic toxicity assays were included in this evaluation because they test for a broad range of types of DNA damage induced by drugs or chemicals that induce genetic damage, including: structural chromosomal aberrations (CA), DNA damage as measured by comet assay, and micronucleus induction (structural and numerical chromosomal alterations). CA and micronucleus (MN) induction have been identified as good predictors of future cancer incidence (Bonassi et al. 2007; Bonassi et al. 2004; Norppa et al. 2006), and cancer chemotherapy agents are reported to induce CA or MN induction under experimental (e.g., in vitro or animal studies) or controlled exposure conditions (i.e., patients administered cancer chemotherapy agents for treatment of cancer) (Suspiro and Prista 2011). The comet assay is becoming more widely used in human biomonitoring to measure DNA damage as a biomarker of effect following exposure to chemicals known to induce genetic toxicity (Collins et al. 2014). However, a causal link between DNA damage detected by comet assay and subsequent induction of cancer has yet to be determined [reviewed in (Collins et al. 2014)]. The evaluation also collected information on secondary (less direct) health outcomes that are not as clearly indicative of an adverse effect, but they provide biological support and plausibility for the corresponding primary health outcomes (e.g., biochemical or clinical chemistry changes in organ systems). The evaluation did not include other biomarkers of effect (e.g., sister chromatid assay, hypoxanthine-guanine phosphoribosyltransferase [HPRT] mutations), or mechanisms of toxicity (e.g., oxidative stress, apoptosis) because there were fewer studies available, and/or their relevance to later health outcomes was less established. The evaluation also did not include studies evaluating urine mutagenesis, which is considered a biomarker of exposure.

For Objective 2, the evaluation included a literature survey of the studies reporting environmental monitoring of cancer chemotherapy agents in hospital, clinic facilities, or other occupational settings, as well as studies designed to detect the presence of cancer chemotherapy agents or their metabolites in urine or blood of personnel handling these agents or possibly exposed to such contamination. Publications that reported on levels of environmental monitoring or biomonitoring efforts were reviewed, and the data were extracted into tables (see Supplemental Files in [underlined: Appendix I]). These environmental monitoring and biomonitoring publications were not systematically reviewed (e.g., no risk-of-bias assessment or evaluation of confidence in the body of evidence) as that was beyond the scope of the current evaluation. The purpose of this literature survey was to gain an understanding of: (1) the frequencies and levels of positive environmental monitoring, the locations where contamination was detected, and the chemotherapy agents that were monitored and detected; (2) the extent to which worker exposures could be verified by the presence of chemotherapy agents or their metabolites in blood or urine, and (3) any possible changes in the frequency of detection or amounts of cancer chemotherapy agent detected in environmental monitoring/biomonitoring since implementation of the OSHA safe handling guidelines (OSHA 1986). Data on glove contamination or comparisons of the permeability of different glove materials are not included because the focus of this evaluation was on residual surface contamination, and not on these protective barriers that would be discarded following exposure. Also, studies validating new analytical techniques in the absence of measuring actual samples were also excluded from the review of environmental monitoring or biomonitoring studies.

## Literature Search

The literature search was developed in collaboration with a librarian trained in systematic review methodology. Five electronic databases were searched using a search strategy tailored for each database: Embase, PubMed, Scopus, Toxline, and Web of Science. The search terms for PubMed are reported in Appendix A and the search strategy for other databases in protocol are reported in the protocol ([underlined: Appendix I]). No language restrictions or publication year limits were imposed, and the databases were searched on October 23, 2014 with a final updated search on February 23, 2017. The reference lists of all included studies, relevant reviews, commentaries, and other non-research articles as well as the NIOSH webpages detailing Occupational Exposure to Antineoplastic Agents and Other Hazardous Drugs (https://www.cdc.gov/niosh/topics/antineoplastic/default.html) were manually searched for additional relevant publications.

## Study Selection

### Evidence Selection Criteria

Studies were eligible for inclusion if they satisfied the eligibility criteria in the PECO statement (Objective 1) or contain relevant environmental monitoring or biomonitoring assessment information (Objective 2). Inclusion and exclusion criteria used to screen articles for relevance and eligibility at both the title-and-abstract and full-text screening stages are summarized in Table 2. The following additional exclusion criteria were applied: (1) articles without original data (e.g., editorials or reviews); (2) studies published in abstract form only (grant awards and conference abstracts); and (3) retracted articles. There were no language restrictions for the studies reporting health outcomes (Objective 1). For studies evaluating only environmental monitoring or biomonitoring (Objective 2), only studies written in English language were included because NTP was not conducting a systematic review of the exposure-only literature.

### Screening Process

References retrieved from the literature search were screened for relevance and eligibility against the evidence selection criteria using DistillerSR^®^ (Evidence Partners; https://www.evidencepartners.com/products/distillersr-systematic-review-software/), a database software program. Screeners from the evaluation team were trained with an initial pilot phase undertaken to improve clarity of the evidence selection criteria and to improve accuracy and consistency among screeners. Two trained screeners (one of whom was the project lead) independently screened the references at the title-and-abstract level to determine whether a reference met the evidence selection criteria. References that were not excluded by reviewing the title and abstract were screened by a full-text review, including references that were considered of unclear relevance based on the title-and-abstract review. Screening conflicts were resolved through discussion. Following full-text review, the remaining studies were “included” and used for the evaluation.

## Data Extraction

### Extraction Process

Data were collected (i.e., extracted) from included studies by one member of the evaluation team and checked by a second member for completeness and accuracy. Any discrepancies in the data extraction were resolved by discussion. Information that was inferred, converted, or estimated during data extraction is annotated, e.g., using brackets [n = 10]. Authors were contacted when details were missing on key study findings. The data extraction files note if an attempt was made to contact study authors by email for missing data considered important for evaluating key study findings, and whether a response from the author was received.

### Data Availability

Data extraction was completed using the Health Assessment Workspace Collaborative (HAWC (https://hawcproject.org/portal/)), an open-source and freely available web-based interface application, for visualization and warehousing.^3^ The data extraction results for included studies are publicly available (https://hawcproject.org/assessment/196/) and can be downloaded in Excel format through HAWC (NTP 2015a). Data extraction elements are listed separately for human, animal, and in vitro studies in the protocol (Appendix I) (NTP 2015b).

3 HAWC ([underlined: H]ealth [underlined: A]ssessment [underlined: W]orkspace [underlined: C]ollaborative): A Modular Web-based Interface to Facilitate Development of Human Health Assessments of Chemicals (https://hawcproject.org/portal/).

## Quality Assessment of Individual Studies

Risk of bias was assessed for individual studies using a tool developed by OHAT (https://ntp.niehs.nih.gov/go/systematic_review); the risk-of-bias criteria were customized for the evaluation (e.g., to address occupational exposure scenarios to cancer chemotherapy agents). The OHAT risk-of-bias tool has questions tailored to specific study design types to assess risk of bias in six categories, including selection bias, confounding bias, performance bias, attrition bias, detection bias, and selective reporting (Rooney et al. 2014). Studies were independently evaluated by two trained assessors who answered all applicable risk-of-bias questions with one of four options (Figure 1) following pre-specified criteria. The criteria describe aspects of study design, conduct, and reporting required to reach risk-of-bias ratings for each question and specify factors that can distinguish among ratings (e.g., what separates “definitely low” from “probably low” risk of bias). Risk-of-bias assessments for confounding, exposure characterization, and outcome assessment were considered especially critical.

Figure 1

Risk-of-bias Assessment Ratings

Answers to the risk-of-bias (study quality) questions results in one of four risk-of-bias ratings.

Any discrepancies in ratings between assessors were resolved through discussion to reach the final recorded risk-of-bias rating for each question along with a statement of the basis for that rating. Members of the evaluation team were consulted for assistance if additional expertise was necessary to reach final risk-of-bias ratings based on specific aspects of study design or performance reported for individual studies. Information or study procedures that were not reported were assumed not to have been conducted, resulting in an assessment of “probably high” risk of bias. NTP queried authors by email to obtain missing information, and responses received were used to update risk-of-bias ratings.

The OHAT method identifies some risk-of-bias questions as more important than others because there is evidence that these areas of bias generally have a larger impact on the credibility of study results in environmental health literature (Rooney et al. 2016). The key questions for observational human studies are: confounding, exposure characterization, and outcome assessment (including blinding of outcome assessors).

## Rating Confidence in Bodies of Evidence

Groups or studies (bodies of evidence) were assessed to develop confidence ratings that reflect the certainty in the evidence that occupational exposure to chemotherapy agents are associated with health effects for each health outcome using the GRADE system as adapted by OHAT (Rooney et al. 2014). Thus, for each health outcome, bodies of evidence were assessed to develop confidence ratings that reflect the certainty in the evidence that occupational exposure to cancer chemotherapy agents are associated with health effects. More detailed guidance on reaching confidence ratings in the body of evidence as “high,” “moderate,” “low,” or “very low” is provided in the OHAT Handbook for Conducting a Literature-Based Health Assessment (https://ntp.niehs.nih.gov/go/systematic_review, see STEP 5). In brief, available studies on an outcome were initially grouped by key study design features, and each grouping of studies was given an initial confidence rating by those features (Column 1 of Figure 2), including controlled exposure, exposure prior to outcome, individual outcome data, and comparison group used. For example, cohort studies (either prospective or retrospective) are generally assigned an initial confidence rating of “moderate” because they have three factors (exposure prior to outcome, individual outcome data, and comparison group). Cross-sectional studies are, generally, assigned an initial confidence rating of “low” because they only have two factors (individual data and comparison group). The cross-sectional study design generally cannot assure that exposure occurred prior to outcome; therefore, there is decreased confidence that the relationship between exposure and outcome is causal. Concerns about possible reverse causation or the potential influence of the outcome on the exposure can limit confidence in the results of cross-sectional studies. However, there are several factors that could increase the confidence that data from cross-sectional studies more strongly supports the causal association between exposure and outcome and, thus, increase the initial confidence rating to “moderate.” Two examples of factors that could increase the confidence in data from cross-sectional studies are (1) the outcome was rapid (e.g., occurring within minutes or hours of exposure) (see section below, Adjustment of Initial Confidence Ratings of Cross-sectional Studies Evaluating Genetic Toxicity), and (2) the exposure was persistent (e.g., exposure would have preceded outcome even in a cross-sectional study design).

Figure 2

Assessing Confidence in the Body of Evidence

This figure describes how confidence in bodies of evidence (i.e., groups of studies) are considered on an outcome basis.

Potential downgrading of the confidence rating was considered for factors that decrease confidence in the results (Column 2 of Figure 2, [high risk of bias, unexplained inconsistency, indirectness or lack of applicability, imprecision, and publication bias]), and potential upgrading of the confidence rating was considered for factors that increase confidence in the results (Column 3 of Figure 2, [large magnitude of effect, dose-response, consistency across study designs/populations, consideration of residual confounding, and other factors that increase confidence in the association or effect]). Consideration of consistency across study designs or human populations is not included in the GRADE guidance (Guyatt et al. 2011); however, it is considered in the modified version of GRADE used by OHAT (Rooney et al. 2014).

Member of the evaluation review team made the confidence ratings assessments. Any discrepancies between reviewers were resolved by consensus and by consultation with technical advisors, as needed. Confidence ratings are summarized in evidence profile tables for each outcome.

### Adjustment of Initial Confidence Ratings of Cross-sectional Studies Evaluating Genetic Toxicity

For the evaluation of the three genetic toxicity assays, cross-sectional studies were assigned an initial confidence rating of “moderate” because there was compelling evidence to conclude that occupational exposure preceded outcome and reverse causation was highly unlikely. It is highly likely that the cross-sectional study design ensures that occupational exposure to the cancer chemotherapy agent preceded the health outcome for genetic toxicity assays based on three factors: (1) the rapid induction of DNA damage, (2) inclusion in most studies of only subjects who worked full time the week that their blood samples were drawn, and (3) an employment duration ranging from at least a month to more than one year at the time the study was conducted. Due to the rapid induction of genetic damage, for studies designed to measure DNA damage using the comet assay, it is recommended that blood samples be collected within 3 to 4 hours of exposure termination. For studies designed to measure induction of chromosomal damage or micronuclei, it is recommended that blood samples be obtained within 2 days of acute exposure (Albertini et al. 2000). Furthermore, reverse causation is unlikely in the cross-sectional studies of genetic toxicity as participants are not likely to know their DNA damage status such that it would influence their response to a survey of exposures.

## Preparation of Level-of-evidence Conclusions

The confidence ratings were translated into level-of-evidence conclusions that reflect the confidence in the bodies of evidence and the direction of effect (i.e., health effect or no health effect). These conclusions indicate the confidence in the available evidence that occupational exposure to chemotherapy agents are associated with health effects for each type of health outcome, separately, according to one of four statements: (1) high, (2) moderate, (3) low, or (4) inadequate (Figure 3 and Table 3).

Figure 3

Translation of Confidence Ratings into Evidence of Health Effect Conclusions

Table 3 Definitions of Level-of-evidence Descriptors

Evidence Descriptors | Definition
High Level of Evidence | There is high confidence in the body of evidence for an association between occupational exposure to cancer chemotherapy agents and the health outcome(s).
Moderate Level of Evidence | There is moderate confidence in the body of evidence for an association between occupational exposure to cancer chemotherapy agents and the health outcome(s).
Low Level of Evidence | There is low confidence in the body of evidence for an association between occupational exposure to cancer chemotherapy agents and the health outcome(s), or no data are available.
Inadequate Evidence | There is insufficient evidence available to assess if occupational exposure to cancer chemotherapy agents is associated with the health outcome(s).
Evidence of No Health Effect | There is high confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is [underlined: not] associated with the health outcome(s).