# Introduction

Cancer chemotherapy agents are designed to kill or halt the progression of cancer cells through various mechanisms of action. Due to their mechanisms of action, many cancer chemotherapy agents are reported to induce carcinogenicity and mutagenicity. Forty-two cancer chemotherapy agents are identified by the International Agency for Research on Cancer (IARC) as known (n = 18; IARC Class 1), probable (n = 11; IARC Class 2A), or possible (n = 13; IARC Class 2B) carcinogens in humans (IARC 2012; 2016). Cancer chemotherapy agents administered therapeutically for the treatment of cancer are known to cause secondary cancers, primarily therapy-related acute myeloid leukemia (Mistry et al. 2005; Morton et al. 2013; Pedersen-Bjergaard 2005; Pedersen-Bjergaard et al. 2002; Sill et al. 2011). In addition, most cancer chemotherapy agents are reported to be teratogenic and/or to induce embryo toxicity in experimental studies of laboratory animal models and limited observational reports in women administered cancer chemotherapy for treatment of cancer during pregnancy [reviewed in (NTP 2013)]. A summary of the published carcinogenicity, mutagenicity, teratogenicity, and embryo toxicity of different cancer chemotherapy drug classes following direct, intentional exposure of these agents to human patients or experimental animals are presented in Table 1. Given the observed adverse health outcomes observed following intentional, direct administration of these agents to patients, the National Toxicology Program (NTP) evaluated the literature for potential adverse health outcomes in employees who are occupationally exposed to cancer chemotherapy agents.

Table 1 Carcinogenicity, Mutagenicity, and Developmental Toxicity of Cancer Chemotherapy Agents by Drug Class Based on Direct, Intentional Exposure to Humans and Laboratory Animals

Drug Class^a^ | Carcinogenicity^b^ | Genetic Toxicity^b,c^ | Developmental Toxicity^d^
Drug Class^a^ | Carcinogenicity^b^ | Genetic Toxicity^b,c^ | Teratogenicity | Embryotoxicity
Alkylating Agents | +^e^ | + | + | +
Antimetabolites | + | + | + | +
Biological | inadequate data^f^ | −^g^ | − | −^h^
Anthracycline Antibiotics | + | + | + | +
Hormone Therapies | + | + | + | +
Mitotic Function Inhibitors | inadequate data | + | + | +
Topoisomerase II Function Inhibitors | + | + | + | +
Tyrosine Kinase Inhibitors | inadequate data | inadequate data | + | +

^a^ Examples of agents in each drug class: alkylating agents (e.g., cyclophosphamide), antimetabolites (e.g., hydroxyurea), biologicals (e.g., cytokines, such as interferon alpha, and monoclonal antibodies, such as trastuzumab), anthracycline antibiotics (e.g., doxorubicin), hormone therapies (e.g., tamoxifen), mitotic function inhibitors (e.g., vincristine), topoisomerase function inhibitors (e.g., etoposide), and tyrosine kinase inhibitors (e.g., imatinib, adalimumab).

^b^ Data reviewed in: (IARC 1966; 1980; 1981; 1990; 2000).

^c^ Data reviewed in: (NTP 2008; 2016).

^d^ Data reviewed in: (NTP 2013).

^e^ Evidence of an effect for at least one agent in this drug class.

^f^ Inadequate data; inconsistent data or a lack of data for one or more agents in this drug class.

^g^ Lack of an effect for agents in this drug class.

^h^ Trastuzumab is a reproductive developmental toxicant, which induced oligohydramnios when administered in second and/or third trimester.

Occupational exposure to cancer chemotherapy agents may occur in medical, veterinary, and manufacturing settings among personnel involved in the production, preparation and administration of these agents (Hall et al. 2013; Kiffmeyer et al. 2013; Kopp et al. 2013b) as well as other workers involved with the care of patients administered chemotherapy (e.g., unit clerks, volunteers, ward aides, dieticians, and shipper/receivers) (Hon et al. 2014). Potential routes of occupational exposure to these agents include dermal, ingestion, and inhalation. While levels of such exposures are thought to be much lower than those administered to cancer patients, occupational exposure likely involves more than one chemotherapy agent or combination therapy, and it may occur more frequently and over a longer time. Furthermore, occupational exposures are often unrecognized due to lack of systematic environmental monitoring and biomonitoring programs (OSHA 1999).

Evidence for occupational exposure began appearing in the 1970s with reports of elevated mutagenic activity in the urine of health care workers who prepared and administered such agents [reviewed in (Connor and McDiarmid 2006)]. Subsequent studies reported evidence of genetic toxicity such as chromosome aberrations, sister chromatid exchanges, and DNA damage in workers handling these agents, as well as the detection of cancer chemotherapy agents or their metabolites in workers’ urine. Guidelines for safe handling of cancer chemotherapy agents were first published in the 1980s by national health care worker agencies in Australia and the United States [reviewed in (Connor and McDiarmid 2006)]. The Occupational Safety and Health Administration in the United States published guidelines for safe handling of cancer chemotherapy agents in 1986 (OSHA 1986), and the guidelines were updated in 1999 to include all hazardous drugs (OSHA 1999). Beginning in the 1990s, numerous publications documented surface contamination of safety cabinets, countertops, floors, and equipment with cancer chemotherapy agents. While improved handling procedures and engineering controls have reduced contamination, Connor et al. (2010) reported that surface contamination persists in pharmacy and nursing areas of some hospital-based cancer centers. In addition, the potential for occupational exposure to cancer chemotherapy agents has increased with greater usage of chemotherapy for non-cancer disease conditions [e.g., autoimmune diseases (Zack 2012)], the development of new surgical techniques involving administration of chemotherapy directly into the peritoneal cavity (Villa et al. 2015), and greater usage of chemotherapy by veterinary clinics to treat cancer in companion animals (Klahn 2014).

A number of health outcomes have been assessed in health care workers exposed to cancer chemotherapy agents, including cancer, genetic damage, reproductive and pregnancy outcomes, and acute effects (e.g., hair loss, nausea) [reviewed in (Connor and McDiarmid 2006)]. The association between occupational exposure to cancer chemotherapy agents and some of these health effects have been evaluated in a literature review and meta-analysis (Dranitsaris et al. 2005), a systematic review (Quansah and Jaakkola 2010), and a recent narrative literature review by Connor et al. (2014). The review and meta-analysis by Dranitsaris and colleagues (2005) evaluated the literature on cancer, pregnancy outcomes, and acute toxic effects in nurses, pharmacists, and pharmacy technicians/assistants who work with cancer chemotherapy agents. They reported that there was insufficient literature to reach conclusions on cancer, acute effects, congenital malformations, or stillbirth; however, they did find a significant association between occupational exposure and spontaneous abortions (odds ratio (OR) = 1.46, 95% confidence interval (CI) = 1.11–1.92) (Dranitsaris et al. 2005). A systematic review and meta-analysis by Quansah and Jaakkola (2010) evaluated the association between occupational exposures and work conditions of nurses only, including cancer chemotherapy agents and risk of spontaneous abortion. The meta-analysis on spontaneous abortion by Quansah and Jaakkola (2010) did not reach statistical significance (OR = 1.21, 95% CI = 0.80−1.83); however, they included a different combination of studies than the systematic review by Dranitsaris et al. (2005). Finally, a narrative review by Connor et al. (2014) provided a survey of the literature on occupational exposure to cancer chemotherapy agents and reproductive health, including spontaneous abortion, congenital anomalies as well as other reproductive outcomes (e.g., fertility, time to pregnancy, birth weight). Overall, confidence in the findings was limited for outcomes other than spontaneous abortion (e.g., congenital malformations) due to low sample size and heterogeneity in the study designs (Connor et al. 2014; Dranitsaris et al. 2005; Quansah and Jaakkola 2010).

Accurate characterization of exposure is one of the major challenges in assessing the adverse health effects of occupational exposure to cancer chemotherapy. Occupational exposure to cancer chemotherapy agents is a complex exposure involving many different cancer chemotherapy agents per day or per week, and each agent may have different potencies to induce the same or different adverse health effects. Furthermore, usage of personal protective equipment and safety containment equipment can influence the level of occupational exposure. Exposure is generally characterized by job title or industrial hygiene data in occupational settings; however, this information alone (i.e., job title or position) does not provide much detail on level of exposure. More informative approaches for exposure characterization of occupational exposure to cancer chemotherapy agents include the use of a validated questionnaire or use of a daily diary where the subject reports on the types of drugs handled, levels handled (i.e., doses administered), frequency of handling, unusual events (e.g., spills or needle sticks), and use of protective measures (e.g., personal protective equipment) that are assessed and validated to estimate exposure levels (Albertini et al. 2000; Nieuwenhuijsen 2003). Positive environmental monitoring results (e.g., surface wipes, air samples, dermal pads) provide strong evidence for the potential for occupational exposure, but they may or may not correlate to internal doses to personnel based on possible modifying variables such as an individual’s use of personal protective equipment or availability of safety containment equipment, among other variables. Biomonitoring of urine or blood samples may determine the internal dose of levels of a cancer chemotherapy agent(s) or its metabolites, which identify that exposure has occurred; however, biomonitoring measurements likely provide confirmation of only the most recent exposure. A positive biomonitoring result requires that there be sufficient intake (which may be reduced by good work practices and usage of personal protective equipment) to exceed the limit of detection (LOD) for the agent tested, and the time between exposure and sample collection must be consistent with any biological processing (e.g., metabolism or excretion of the cancer chemotherapy agent). Additional limitations of monitoring studies (environmental monitoring and biomonitoring) of cancer chemotherapy agents are that they typically test only one or a handful of cancer chemotherapy agents, while multiple agents are handled, and biomonitoring studies generally evaluate only the parent drugs (e.g., cyclophosphamide) and not their metabolites. However, recent studies of environmental monitoring and biomonitoring of occupational exposure to cancer chemotherapy agents demonstrate that surface contamination continues to occur (Hon et al. 2011), and can lead to detectable internal dose levels (Hon et al. 2015).

## Objectives and Research Strategy

### Objectives

The primary objective (Objective 1) of this evaluation was to undertake a systematic review to develop level-of-evidence conclusions regarding whether occupational exposure to cancer chemotherapy agents is associated with adverse health effects in humans. The types of adverse health outcomes considered are described in more detail below (see section below, PECO Statement). The secondary objective (Objective 2) was to survey the literature to determine the levels of workplace contamination by cancer chemotherapy agents and the detection of parent compound or metabolites of these agents in occupationally exposed personnel to provide context for the health outcome literature. The exposure monitoring literature was not evaluated for risk of bias as this was beyond the scope of this evaluation. As possible, environmental and biosample monitoring data from these studies were used to compare the levels reported prior to the publication of the OSHA Guidelines for Handling Hazardous Drugs in 1986 to the present time (OSHA 1986). Limitations of the systematic review were noted for Objective 1 and, for both objectives 1 and 2, the limitations of the evidence base and research needs were described.

Many commonly used cancer chemotherapy agents have already been recognized as known or probable human carcinogens by IARC (2012) and the NTP’s Report on Carcinogens (NTP 2016); thus, this review did not pursue hazard identification. Instead, this review is intended to provide public health information that may be useful to workers, employers, and organizations where occupational exposure may occur to these compounds to support efforts to lower exposure. For example, genetic toxicity studies can identify the occurrence of DNA damage following exposure to occupational exposure to cancer chemotherapy agents. These data are sometimes used as surrogates for direct exposure measurements and they can also be used to provide information on potential health risks (e.g., cancer or fetal loss). This review of reproductive health outcomes associated with occupational exposure to cancer chemotherapy may also be useful to inform safety protocols for working with these agents while pregnant. The scope of this Office of Health Assessment and Translation (OHAT) evaluation is broad with the inclusion of any adverse health outcome and expands beyond the previously published reviews (Dranitsaris et al. 2005; Quansah and Jaakkola 2010), which were limited to acute effects, cancer, and/or effects on reproduction. Furthermore, the evaluation did not limit the types of exposed occupations to only medical personnel; instead, it included all reported occupational exposures to cancer chemotherapy agents (e.g., medical, manufacturing, research, veterinary, and home health care).

### Specific Aims

Objective 1

- Identify literature reporting adverse health effects associated with occupational exposure to cancer chemotherapy agents.
- Extract data from relevant studies.
- Assess the internal validity (risk of bias) of individual studies assessing health outcomes.
- Summarize the extent of evidence available.
- Synthesize the evidence for adverse health outcomes, including performance of quantitative meta-analyses if appropriate, and evaluate sources of heterogeneity.
- Rate confidence in the body of evidence for adverse health outcomes according to one of four statements: (1) high, (2) moderate, (3) low, or (4) very low/no evidence available.
- Translate confidence ratings into level of evidence for adverse health outcomes according to one of four statements: (1) high, (2) moderate, (3) low, or (4) inadequate.
- Describe limitations of the systematic review, limitations of the evidence base, and identify data gaps and key research needs.

Objective 2

- Collect and summarize the available information on levels of cancer chemotherapy agents detected in environmental monitoring studies (e.g., surface wipes, air samples of work environment) and biomonitoring (e.g., urine or blood levels) of occupationally exposed personnel.
- Describe limitations of the evidence base and identify data gaps and key research needs for exposure characterization.