# Conflict of Interest

Individuals identified as collaborators in the About This Review section have certified that they have no known real or apparent conflict of interest related to cancer chemotherapy agents.