# Appendix I Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NTP-DATA-MONOGRAPH5.

## I.1 Protocol Information

Protocol

Revised Protocol

## I.2 Monitoring References

Supplemental Table 1. Environmental Monitoring References

Supplemental Table 2. Biomonitoring References