# Appendix H Protocol History

The original and revised protocols are available in Appendix I.

Table H-1 Protocol History and Revisions

Date | Activity or Revision
May 28, 2015 | Draft evaluation protocol reviewed: sent to experts for comment/review
October 9, 2015 | Evaluation protocol posted on Office of Health Assessment and Translation website
December 7, 2018 | Revised protocol posted to reflect principal updates made during evaluation with justifications noted (date implemented): 1. Decision to evaluate evidence of all health effects, including reproductive and developmental toxicity, to make the evaluation comprehensive and ensure that the most recent papers on reproductive system effects were included (January 2016). 2. Consideration of acute effects as well as genetic toxicity as primary health outcomes, not secondary health outcomes. Genetic toxicity moved to primary health outcome because of the established association of chromosome aberrations and micronucleus induction with future cancer incidence. These changes were made based on consultation with a technical advisor and federal experts following review of a preliminary draft on the monograph (November 2016). 3. Adjustment of exposure characterization risk-of-bias assessment to include job position with work tasks and details about drug handling (e.g., types of cancer chemotherapy agents, frequency of drugs handled) via questionnaire or self-reported daily diary with validation as probably low risk of bias. These changes were made based on consultation with a technical advisor and federal experts following review of a preliminary draft on the monograph (November 2016). 4. Adjustment of initial confidence rating in the body of evidence of cross-sectional studies of genetic toxicity from low initial confidence to moderate initial confidence because the three genetic toxicity outcomes are rapidly developing (e.g., hours to days) and the period of occupational exposure began prior to development of the outcome (January 2017). 5. Removal of the hazard identification step due to lack of a formal way to integrate authoritative reviews into the integration of evidence streams step (January 2017). Note, given that level of evidence was moderate and no hazard conclusions reached, a formal public comment period was not included