# Appendix G List of Included Studies Reporting on Environmental Monitoring or Biomonitoring

Acampora A, Castiglia L, Miraglia N, Pieri M, Soave C, Liotti F, Sannolo N. 2005. A case study: Surface contamination of cyclophosphamide due to working practices and cleaning procedures in two Italian hospitals. Ann Occup Hyg. 49(7):611-618. https://dx.doi.org/10.1093/annhyg/mei029

Azari M, Panahi D, Akbari ME, Mirzaei HR, Rezvani HR, Zendehdel R, Mehrabi Y, Bayatian M. 2017. Environmental monitoring of occupational exposure to cyclophosphamide drug in two Iranian hospitals. Iran J Cancer Prev. 10(1). https://dx.doi.org/10.17795/ijcp-7229

Berruyer M, Tanguay C, Caron NJ, Lefebvre M, Bussières JF. 2015. Multicenter study of environmental contamination with antineoplastic drugs in 36 Canadian Hospitals: A 2013 follow-up study. J Occup Environ Hyg. 12(2):87-94. https://dx.doi.org/10.1080/15459624.2014.949725

Bigelow S, Schulz H, Dobish R, Chambers CR. 2009. Antineoplastic agent workplace contamination study: The Alberta Cancer Board Pharmacy perspective Phase III. J Oncol Pharm Pract. 15(3):157-160. https://dx.doi.org/10.1177/1078155208101097

Bobin-Dubigeon C, Amiand M, Percheron C, Audeval C, Rochard S, Leynia P, Bard JM. 2013. A new, validated wipe-sampling procedure coupled to LC-MS analysis for the simultaneous determination of 5-fluorouracil, doxorubicin and cyclophosphamide in surface contamination. J Anal Toxicol. 37(7):433-439. https://dx.doi.org/10.1093/jat/bkt045

Bolognesi C, Nucci MC, Colacci AM, Grilli S, Ippoliti F, Mucci N, Romano Spica V, Barbieri A, Canitano N, Chiozzotto D et al. 2005. [Biomonitoring of nurses occupationally exposed to antineoplastic drugs: The IMEPA Project]. Epidemiol Prev. 29(5-6 Suppl):91-95.

Bos RP, Weissenberger BFJ, Anzion RBM. 1998. α-Fluoro-β-alanine in urine of workers occupationally exposed to 5- fluorouracil in a 5-fluorouracil-producing factory. Biomarkers. 3(1):81-87. https://dx.doi.org/10.1080/135475098231390

Burgaz S, Karahalil B, Bayrak P, Taskin L, Yavuzaslan F, Bokesoy I, Anzion RB, Bos RP, Platin N. 1999. Urinary cyclophosphamide excretion and micronuclei frequencies in peripheral lymphocytes and in exfoliated buccal epithelial cells of nurses handling antineoplastics. Mutat Res. 439(1):97-104. https://dx.doi.org/10.1016/S1383-5718(98)00180-6

Burgaz S, Karahalil B, Canhi Z, Terzioglu F, Ancel G, Anzion RB, Bos RP, Huttner E. 2002. Assessment of genotoxic damage in nurses occupationally exposed to antineoplastics by the analysis of chromosomal aberrations. Hum Exp Toxicol. 21(3):129-135. https://dx.doi.org/10.1191/0960327102ht230oa

Bussières JF, Tanguay C, Touzin K, Langlois E, Lefebvre M. 2012. Environmental contamination with hazardous drugs in Quebec hospitals. Can J Hosp Pharm. 65(6):428-435. https://dx.doi.org/10.4212/cjhp.v65i6.1190

Canal-Raffin M, Khennoufa K, Martinez B, Goujon Y, Folch C, Ducint D, Titier K, Brochard P, Verdun-Esquer C, Molimard M. 2016. Highly sensitive LC-MS/MS methods for urinary biological monitoring of occupational exposure to cyclophosphamide, ifosfamide, and methotrexate antineoplastic drugs and routine application. J Chromatogr B. 1038:109-117. https://dx.doi.org/10.1016/j.jchromb.2016.10.021

Caneparo A, Massucco P, Vaira M, Maina G, Giovale E, Coggiola M, Cinquegrana A, Robella M, De Simone M. 2014. Contamination risk for operators performing semi-closed HIPEC procedure using cisplatin. Eur J Surg Oncol. 40(8):925-929. https://dx.doi.org/10.1016/j.ejso.2014.03.013

Caporossi L, De Rosa M, Pera A, Papaleo B. 2007. Simple analytical method for the determination of paclitaxel (Taxol^®^) levels in human plasma. Chromatographia. 66(11-12):921-924. https://dx.doi.org/10.1365/s10337-007-0427-z

Castiglia L, Miraglia N, Pieri M, Simonelli A, Basilicata P, Genovese G, Guadagni R, Acampora A, Sannolo N, Scafarto MV. 2008. Evaluation of occupational exposure to antiblastic drugs in an Italian hospital oncological department. J Occup Health. 50(1):48-56. https://dx.doi.org/10.1539/joh.50.48

Cavallo D, Ursini CL, Perniconi B, Francesco AD, Giglio M, Rubino FM, Marinaccio A, Iavicoli S. 2005. Evaluation of genotoxic effects induced by exposure to antineoplastic drugs in lymphocytes and exfoliated buccal cells of oncology nurses and pharmacy employees. Mutat Res. 587(1-2):45-51. https://dx.doi.org/10.1016/j.mrgentox.2005.07.008

Chu WC, Hon CY, Danyluk Q, Chua PP, Astrakianakis G. 2012. Pilot assessment of the antineoplastic drug contamination levels in British Columbian hospitals pre- and post-cleaning. J Oncol Pharm Pract. 18(1):46-51. https://dx.doi.org/10.1177/1078155211402106

Clark BA, Sessink PJ. 2013. Use of a closed system drug-transfer device eliminates surface contamination with antineoplastic agents. J Oncol Pharm Pract. 19(2):99-104. https://dx.doi.org/10.1177/1078155212468367

Connor TH, Anderson RW, Sessink PJ, Broadfield L, Power LA. 1999. Surface contamination with antineoplastic agents in six cancer treatment centers in Canada and the United States. Am J Health Syst Pharm. 56(14):1427-1432.

Connor TH, Anderson RW, Sessink PJ, Spivey SM. 2002. Effectiveness of a closed-system device in containing surface contamination with cyclophosphamide and ifosfamide in an i.v. admixture area. Am J Health Syst Pharm. 59(1):68-72.

Connor TH, DeBord DG, Pretty JR, Oliver MS, Roth TS, Lees PS, Krieg EF, Jr., Rogers B, Escalante CP, Toennis CA et al. 2010. Evaluation of antineoplastic drug exposure of health care workers at three university-based US cancer centers. J Occup Environ Med. 52(10):1019-1027. https://dx.doi.org/10.1097/JOM.0b013e3181f72b63

Connor TH, Sessink PJ, Harrison BR, Pretty JR, Peters BG, Alfaro RM, Bilos A, Beckmann G, Bing MR, Anderson LM et al. 2005. Surface contamination of chemotherapy drug vials and evaluation of new vial-cleaning techniques: Results of three studies. Am J Health Syst Pharm. 62(5):475-484. https://dx.doi.org/10.1093/ajhp/62.5.475

Couch J, dePerio MA. 2011. Health Hazard Evaluation Report: HETA-2010-0118-3142, September 2011. Chemotherapy drug evaluation at a medical laboratory - Pennsylvania. Govt Reports Announcements & Index. (04):24.

Couch J, Gibbins J, Connor T. 2012. Health Hazard Evaluation Report: HETA-2010-0068-3156, April 2012. Chemotherapy drug evaluation at a veterinary teaching hospital - Michigan. Govt Reports Announcements & Index. (15):32.

Couch J, West C. 2012. Health Hazard Evaluation Report: HETA-2009-0148-3158, June 2012. Chemotherapy drug exposure at an oncology clinic - Florida. Govt Reports Announcements & Index. (20):36.

Crauste-Manciet S, Sessink PJ, Ferrari S, Jomier JY, Brossard D. 2005. Environmental contamination with cytotoxic drugs in healthcare using positive air pressure isolators. Ann Occup Hyg. 49(7):619-628. https://dx.doi.org/10.1093/annhyg/mei045

Crickman R. 2017. Chemotherapy safe handling: Limiting nursing exposure with a hazardous drug control program. Clin J Oncol Nurs. 21(1):73-78. https://dx.doi.org/10.1188/17.cjon.73-78

Deschamps F, Lesage FX, Marinutti-Liberge V, Lamiable D, Millart H. 2007. Letter to the editor. Inhal Toxicol. 19(3):309. https://dx.doi.org/10.1080/08958370601069422

deWerk Neal A, Wadden RA, Chiou WL. 1983. Exposure of hospital workers to airborne antineoplastic agents. Am J Hosp Pharm. 40(4):597-601.

Ensslin AS, Huber R, Pethran A, Rommelt H, Schierl R, Kulka U, Fruhmann G. 1997. Biological monitoring of hospital pharmacy personnel occupationally exposed to cytostatic drugs: Urinary excretion and cytogenetics studies. Int Arch Occup Environ Health. 70(3):205-208. https://dx.doi.org/10.1007/s004200050208

Ensslin AS, Pethran A, Schierl R, Fruhmann G. 1994. Urinary platinum in hospital personnel occupationally exposed to platinum-containing antineoplastic drugs. Int Arch Occup Environ Health. 65(5):339-342. https://dx.doi.org/10.1007/BF00405699

Ensslin AS, Stoll Y, Pethran A, Pfaller A, Rommelt H, Fruhmann G. 1994. Biological monitoring of cyclophosphamide and ifosfamide in urine of hospital personnel occupationally exposed to cytostatic drugs. Occup Environ Med. 51(4):229-233. https://dx.doi.org/10.1136/oem.51.4.229

Evelo CT, Bos RP, Peters JG, Henderson PT. 1986. Urinary cyclophosphamide assay as a method for biological monitoring of occupational exposure to cyclophosphamide. Int Arch Occup Environ Health. 58(2):151-155. https://dx.doi.org/10.1007/BF00380766

Favier B, Gilles L, Ardiet C, Latour JF. 2003. External contamination of vials containing cytotoxic agents supplied by pharmaceutical manufacturers. J Oncol Pharm Pract. 9(1):15-20. https://dx.doi.org/10.1191/1078155203jp102oa

Fent KW, Durgam S, Mueller C. 2014. Pharmaceutical dust exposure at pharmacies using automatic dispensing machines: A preliminary study. J Occup Environ Hyg. 11(11):695-705. https://dx.doi.org/10.1080/15459624.2014.918983

Fleury-Souverain S, Mattiuzzo M, Mehl F, Nussbaumer S, Bouchoud L, Falaschi L, Gex-Fabry M, Rudaz S, Sadeghipour F, Bonnabry P. 2015. Evaluation of chemical contamination of surfaces during the preparation of chemotherapies in 24 hospital pharmacies. Eur J Hosp Pharm. 22(6):333-341. https://dx.doi.org/10.1136/ejhpharm-2014-000549

Fleury-Souverain S, Nussbaumer S, Mattiuzzo M, Bonnabry P. 2014. Determination of the external contamination and cross-contamination by cytotoxic drugs on the surfaces of vials available on the Swiss market. J Oncol Pharm Pract. 20(2):100-111. https://dx.doi.org/10.1177/1078155213482683

Floridia L, Pietropaolo AM, Tavazzani M, Rubino FM, Colombi A. 1999. High-performance liquid chromatography of methotrexate for environmental monitoring of surface contamination in hospital departments and assessment of occupational exposure. J Chromatogr B Biomed Sci Appl. 726(1-2):95-103. https://dx.doi.org/10.1016/S0378-4347(98)00561-1

Fransman W, Huizer D, Tuerk J, Kromhout H. 2007. Inhalation and dermal exposure to eight antineoplastic drugs in an industrial laundry facility. Int Arch Occup Environ Health. 80(5):396-403. https://dx.doi.org/10.1007/s00420-006-0148-x

Fransman W, Peelen S, Hilhorst S, Roeleveld N, Heederik D, Kromhout H. 2007. A pooled analysis to study trends in exposure to antineoplastic drugs among nurses. Ann Occup Hyg. 51(3):231-239. https://dx.doi.org/10.1093/annhyg/mel081

Fransman W, Roeleveld N, Peelen S, de Kort W, Kromhout H, Heederik D. 2007. Nurses with dermal exposure to antineoplastic drugs: Reproductive outcomes. Epidemiology. 18(1):112-119. https://dx.doi.org/10.1097/01.ede.0000246827.44093.c

Fransman W, Vermeulen R, Kromhout H. 2004. Occupational dermal exposure to cyclophosphamide in Dutch hospitals: A pilot study. Ann Occup Hyg. 48(3):237-244. https://dx.doi.org/10.1093/annhyg/meh017

Fransman W, Vermeulen R, Kromhout H. 2005. Dermal exposure to cyclophosphamide in hospitals during preparation, nursing and cleaning activities. Int Arch Occup Environ Health. 78(5):403-412. https://dx.doi.org/10.1007/s00420-004-0595-1

Friederich U, Molko F, Hofmann V, Scossa D, Hann D, Wurgler FE, Senn HJ. 1986. Limitations of the salmonella/mammalian microsome assay (Ames test) to determine occupational exposure to cytostatic drugs. Eur J Cancer Clin Oncol. 22(5):567-575. https://dx.doi.org/10.1016/0277-5379(86)90045-3

Friese CR, McArdle C, Zhao T, Sun D, Spasojevic I, Polovich M, McCullagh MC. 2015. Antineoplastic drug exposure in an ambulatory setting: A pilot study. Cancer Nurs. 38(2):111-117. https://dx.doi.org/10.1097/NCC.0000000000000143

Fung V, Seneviratne M. 2016. Regulatory verification on safe use of cytotoxic drugs in veterinary clinics and animal hospitals. Aust Vet J. 94(11):400-404. https://dx.doi.org/10.1111/avj.12515

Graeve C, McGovern PM, Arnold S, Polovich M. 2017. Testing an intervention to decrease healthcare workers' exposure to antineoplastic agents. Oncol Nurs Forum. 44(1):E10-e19. https://dx.doi.org/10.1188/17.onf.e10-e19

Guillemette A, Langlois H, Voisine M, Merger D, Therrien R, Mercier G, Lebel D, Bussieres JF. 2014. Impact and appreciation of two methods aiming at reducing hazardous drug environmental contamination: The centralization of the priming of IV tubing in the pharmacy and use of a closed-system transfer device. J Oncol Pharm Pract. 20(6):426-432. https://dx.doi.org/10.1177/1078155213517127

Guinée EP, Beuman GH, Hageman G, Welle IJ, Kleinjans JC. 1991. Evaluation of genotoxic risk of handling cytostatic drugs in clinical pharmacy practice. Pharm Weekbl Sci. 13(2):78-82. https://dx.doi.org/10.1007/BF01974985

Hama K, Fukushima K, Hirabatake M, Hashida T, Kataoka K. 2012. Verification of surface contamination of Japanese cyclophosphamide vials and an example of exposure by handling. J Oncol Pharm Pract. 18(2):201-206. https://dx.doi.org/10.1177/1078155211419543

Hama T, Aoyama T, Shirai T, Higuchi S, Yokokawa T, Sugimoto Y. 2009. Environmental contamination due to preparation of cyclophosphamide and exposure of pharmacists to it. Jpn J Pharm Health Care Sci. 35(10):693-700. https://dx.doi.org/10.5649/jjphcs.35.693

Hanada T, Takami Y, Moriyama K, Oro M, Ogawa T, Moriyasu H, Inoue Y, Kanemitsu A, Kawamoto E, Nagase A et al. 2015. Prevention of the exposure by cyclophosphamide oral tablet. J Pharm Health Care Sci. 1:20. https://dx.doi.org/10.1186/s40780-015-0020-9

Harrison BR, Peters BG, Bing MR. 2006. Comparison of surface contamination with cyclophosphamide and fluorouracil using a closed-system drug transfer device versus standard preparation techniques. Am J Health Syst Pharm. 63(18):1736-1744. https://dx.doi.org/10.2146/ajhp050258

Hedmer M, Georgiadi A, Bremberg ER, Jonsson BA, Eksborg S. 2005. Surface contamination of cyclophosphamide packaging and surface contamination with antineoplastic drugs in a hospital pharmacy in Sweden. Ann Occup Hyg. 49(7):629-637. https://dx.doi.org/10.1093/annhyg/mei042

Hedmer M, Tinnerberg H, Axmon A, Jonsson BA. 2008. Environmental and biological monitoring of antineoplastic drugs in four workplaces in a Swedish hospital. Int Arch Occup Environ Health. 81(7):899-911. https://dx.doi.org/10.1007/s00420-007-0284-y

Hedmer M, Wohlfart G. 2012. Hygienic guidance values for wipe sampling of antineoplastic drugs in Swedish hospitals. J Environ Monit. 14(7):1968-1975. https://dx.doi.org/10.1039/c2em10704j

Higginbotham ML, Fritz SE. 2017. Evaluation of environmental cytotoxic drug contamination in a clinical setting. J Am Anim Hosp Assoc. 53(1):32-37. https://dx.doi.org/10.5326/jaaha-ms-6471

Hirst M, Tse S, Mills DG, Levin L, White DF. 1984. Occupational exposure to cyclophosphamide. Lancet. 323(8370):186-188. https://dx.doi.org/10.1016/S0140-6736(84)92111-1

Hon CY, Astrakianakis G, Danyluk Q, Chu W. 2011. Pilot evaluation of dermal contamination by antineoplastic drugs among hospital pharmacy personnel. Can J Hosp Pharm. 64(5):327-332.

Hon CY, Chua PP, Danyluk Q, Astrakianakis G. 2014. Examining factors that influence the effectiveness of cleaning antineoplastic drugs from drug preparation surfaces: A pilot study. J Oncol Pharm Pract. 20(3):210-216. https://dx.doi.org/10.1177/1078155213497070

Hon CY, Teschke K, Chu W, Demers P, Venners S. 2013. Antineoplastic drug contamination of surfaces throughout the hospital medication system in Canadian hospitals. J Occup Environ Hyg. 10(7):374-383. https://dx.doi.org/10.1080/15459624.2013.789743

Hon CY, Teschke K, Chua P, Venners S, Nakashima L. 2011. Occupational exposure to antineoplastic drugs: Identification of job categories potentially exposed throughout the hospital medication system. Saf Health Work. 2(3):273-281. https://dx.doi.org/10.5491/SHAW.2011.2.3.273

Hon CY, Teschke K, Demers PA, Venners S. 2014. Antineoplastic drug contamination on the hands of employees working throughout the hospital medication system. Ann Occup Hyg. 58(6):761-770. https://dx.doi.org/10.1093/annhyg/meu019

Hon CY, Teschke K, Shen H, Demers PA, Venners S. 2015. Antineoplastic drug contamination in the urine of Canadian healthcare workers. Int Arch Occup Environ Health. 88(7):933-941. https://dx.doi.org/10.1007/s00420-015-1026-1

Ikeda K, Yagi Y, Takegami M, Lu Y, Morimoto K, Kurokawa N. 2007. Efforts to ensure safety of hospital pharmacy personnel occupationally exposed to antineoplastic drugs during a preparation task. Hosp Pharm. 42(3):209-218. https://dx.doi.org/10.1310/hpj4203-209

Janes A, Tanguay C, Caron NJ, Bussieres JF. 2015. Environmental contamination with cyclophosphamide, ifosfamide, and methotrexate: A study of 51 Canadian centres. Can J Hosp Pharm. 68(4):279-289.

Janssens T, Brouwers EE, de Vos JP, de Vries N, Schellens JH, Beijnen JH. 2015. Determination of platinum surface contamination in veterinary and human oncology centres using inductively coupled plasma mass spectrometry. Vet Comp Oncol. 13(3):305-313. https://dx.doi.org/10.1111/vco.12049

Jeebhay M, Mbuli S, Uebel R. 1993. Assessment of exposure to chloramphenicol and azathioprine among workers in a South African pharmaceutical plant. Int Arch Occup Environ Health. 65(S1):S119-122. https://dx.doi.org/10.1007/BF00381321

Johnson BL. 1982. Handling methotrexate --a safety problem? Am J Nurs. 82(10):1531. https://dx.doi.org/10.1097/00000446-198282100-00006

Karahalil B, Ilter Akkoyunlu K. 2004. Determination of urinary cyclophosphamide in oncology nurses handling antineoplastic drugs by gas chromatography-mass spectrometry. FABAD J Pharm Sci. 28(3):125-130.

Kiefer M. 2002. Health Hazard Evaluation Report: HETA 98-0052-2820, MD Anderson Cancer Center, Houston, Texas. Govt Reports Announcements & Index. (26):28.

Kiffmeyer TK, Kube C, Opiolka S, Schmidt KG, Schöppe G, Sessink PJM. 2002. Vapour pressures, evaporation behaviour and airborne concentrations of hazardous drugs: Implications for occupational safety. Pharm J. 268(7188):331-337.

Kiffmeyer TK, Tuerk J, Hahn M, Stuetzer H, Hadtstein C, Heinemann A, Eickmann U. 2013. Application and assessment of a regular environmental monitoring of the antineoplastic drug contamination level in pharmacies - the MEWIP project. Ann Occup Hyg. 57(4):444-455. https://dx.doi.org/10.1093/annhyg/mes081

Konate A, Poupon J, Villa A, Garnier R, Hasni-Pichard H, Mezzaroba D, Fernandez G, Pocard M. 2011. Evaluation of environmental contamination by platinum and exposure risks for healthcare workers during a heated intraperitoneal perioperative chemotherapy (HIPEC) procedure. J Surg Oncol. 103(1):6-9. https://dx.doi.org/10.1002/jso.21740

Kopp B, Crauste-Manciet S, Guibert A, Mourier W, Guerrault-Moro MN, Ferrari S, Jomier JY, Brossard D, Schierl R. 2013. Environmental and biological monitoring of platinum-containing drugs in two hospital pharmacies using positive air pressure isolators. Ann Occup Hyg. 57(3):374-383. https://dx.doi.org/10.1093/annhyg/mes073

Kopp B, Schierl R, Nowak D. 2013. Evaluation of working practices and surface contamination with antineoplastic drugs in outpatient oncology health care settings. Int Arch Occup Environ Health. 86(1):47-55. https://dx.doi.org/10.1007/s00420-012-0742-z

Korczowska E, Jankowiak-Gracz H. 2013. How can we improve safe handling of antineoplastic drugs: Can devices be helpful. Eur J Onc Pharm. 7(1):5-7.

Kromhout H, Hoek F, Uitterhoeve R, Huijbers R, Overmars RF, Anzion R, Vermeulen R. 2000. Postulating a dermal pathway for exposure to anti-neoplastic drugs among hospital workers. Applying a conceptual model to the results of three workplace surveys. Ann Occup Hyg. 44(7):551-560. https://dx.doi.org/10.1016/S0003-4878(00)00050-8

Kushnir CL, Fleury AC, Couch J, Hill MC, Spirtos NM. 2013. Evaluation of exposures to healthcare personnel from cisplatin during a mock demonstration of intra-operative intraperitoneal chemotherapy administration. Gynecol Oncol. 130(2):350-353. https://dx.doi.org/10.1016/j.ygyno.2013.04.467

Ladeira C, Viegas S, Pádua M, Gomes M, Carolino E, Gomes MC, Brito M. 2014. Assessment of genotoxic effects in nurses handling cytostatic drugs. J Toxicol Environ Health A. 77(14-16):879-887. https://dx.doi.org/10.1080/15287394.2014.910158

Lee SG, Tkaczuk M, Jankewicz G, Ambados F. 2007. Surface contamination from cytotoxic chemotherapy following preparation and administration. J Pharm Pract Res. 37(4):271-276.

Mader RM, Kokalj A, Kratochvil E, Pilger A, Rudiger HW. 2009. Longitudinal biomonitoring of nurses handling antineoplastic drugs. J Clin Nurs. 18(2):263-269. https://dx.doi.org/10.1111/j.1365-2702.2007.02189.x

Mader RM, Rizovski B, Steger GG, Wachter A, Kotz R, Rainer H. 1996. Exposure of oncologic nurses to methotrexate in the treatment of osteosarcoma. Arch Environ Health. 51(4):310-314. https://dx.doi.org/10.1080/00039896.1996.9936030

Maeda S, Miyawaki K, Matsumoto S, Oishi M, Miwa Y, Kurokawa N. 2010. Evaluation of environmental contaminations and occupational exposures involved in preparation of chemotherapeutic drugs. Yakugaku Zasshi. 130(6):903-910. https://dx.doi.org/10.1248/yakushi.130.903

Martins I, Apostoli P, Della Rosa HV. 2008. Cyclophosphamide levels in sites of preparation and administration of antineoplastic drugs. Lat Am J Pharm. 27(2):217-223.

Martins I, Rosa HVD, Apostoli P. 2004. Cyclophosphamide identification in wipe test by GC-MS and solid phase extraction. Braz J Pharm. 40(1):67-73.

Mason HJ, Blair S, Sams C, Jones K, Garfitt SJ, Cuschieri MJ, Baxter PJ. 2005. Exposure to antineoplastic drugs in two UK hospital pharmacy units. Ann Occup Hyg. 49(7):603-610. https://dx.doi.org/10.1093/annhyg/mei023

Mason HJ, Morton J, Garfitt SJ, Iqbal S, Jones K. 2003. Cytotoxic drug contamination on the outside of vials delivered to a hospital pharmacy. Ann Occup Hyg. 47(8):681-685.

McDevitt JJ, Lees PS, McDiarmid MA. 1993. Exposure of hospital pharmacists and nurses to antineoplastic agents. J Occup Med. 35(1):57-60.

McDiarmid MA, Egan T, Furio M, Bonacci M, Watts SR. 1986. Sampling for airborne fluorouracil in a hospital drug preparation area. Am J Hosp Pharm. 43(8):1942-1945.

Meijster T, Fransman W, Veldhof R, Kromhout H. 2006. Exposure to antineoplastic drugs outside the hospital environment. Ann Occup Hyg. 50(7):657-664. https://dx.doi.org/10.1093/annhyg/mel023

Merger D, Tanguay C, Langlois E, Lefebvre M, Bussieres JF. 2013. Environmental contamination with methotrexate in Canadian community pharmacies. J Am Pharm Assoc. 53(4):423-426. https://dx.doi.org/10.1331/JAPhA.2013.12245

Merger D, Tanguay C, Langlois E, Lefebvre M, Bussieres JF. 2014. Multicenter study of environmental contamination with antineoplastic drugs in 33 Canadian hospitals. Int Arch Occup Environ Health. 87(3):307-313. https://dx.doi.org/10.1007/s00420-013-0862-0

Micoli G, Turci R, Arpellini M, Minoia C. 2001. Determination of 5-fluorouracil in environmental samples by solid-phase extraction and high-performance liquid chromatography with ultraviolet detection. J Chromatogr B Biomed Sci Appl. 750(1):25-32. https://dx.doi.org/10.1016/S0378-4347(00)00377-7

Minoia C, Turci R, Sottani C, Schiavi A, Perbellini L, Angeleri S, Draicchio F, Apostoli P. 1998. Application of high performance liquid chromatography/tandem mass spectrometry in the environmental and biological monitoring of health care personnel occupationally exposed to cyclophosphamide and ifosfamide. Rapid Commun Mass Spectrom. 12(20):1485-1493. https://dx.doi.org/10.1002/(SICI)1097-0231(19981030)12:20%3c1485::AID-RCM333%3e3.0.CO;2-N

Miyake T, Iwamoto T, Tanimura M, Okuda M. 2013. Impact of closed-system drug transfer device on exposure of environment and healthcare provider to cyclophosphamide in Japanese hospital. Springerplus. 2(1):273. https://dx.doi.org/10.1186/2193-1801-2-273

Moretti M, Grollino MG, Pavanello S, Bonfiglioli R, Villarini M, Appolloni M, Carrieri M, Sabatini L, Dominici L, Stronati L et al. 2015. Micronuclei and chromosome aberrations in subjects occupationally exposed to antineoplastic drugs: A multicentric approach. Int Arch Occup Environ Health. 88(6):683-695. https://dx.doi.org/10.1007/s00420-014-0993-y

Naito T, Osawa T, Suzuki N, Goto T, Takada A, Nakamichi H, Onuki Y, Imai K, Nakanishi K, Kawakami J. 2012. Comparison of contamination levels on the exterior surfaces of vials containing platinum anticancer drugs in Japan. Biol Pharm Bull. 35(11):2043-2049. https://dx.doi.org/10.1248/bpb.b12-00628

Naslund Andreasson S, Anundi H, Thoren SB, Ehrsson H, Mahteme H. 2010. Is platinum present in blood and urine from treatment givers during hyperthermic intraperitoneal chemotherapy? J Oncol. 2010:649719. https://dx.doi.org/10.1155/2010/649719

Ndaw S, Denis F, Marsan P, d'Almeida A, Robert A. 2010. Biological monitoring of occupational exposure to 5-fluorouracil: Urinary alpha-fluoro-beta-alanine assay by high performance liquid chromatography tandem mass spectrometry in health care personnel. J Chromatogr B Analyt Technol Biomed Life Sci. 878(27):2630-2634. https://dx.doi.org/10.1016/j.jchromb.2010.02.011

Nussbaumer S, Geiser L, Sadeghipour F, Hochstrasser D, Bonnabry P, Veuthey JL, Fleury-Souverain S. 2012. Wipe sampling procedure coupled to LC-MS/MS analysis for the simultaneous determination of 10 cytotoxic drugs on different surfaces. Anal Bioanal Chem. 402(8):2499-2509. https://dx.doi.org/10.1007/s00216-011-5157-2

Nygren O, Gustavsson B, Strom L, Eriksson R, Jarneborn L, Friberg A. 2002. Exposure to anti-cancer drugs during preparation and administration. Investigations of an open and a closed system. J Environ Monit. 4(5):739-742. https://dx.doi.org/10.1039/B205132J

Nygren O, Lundgren C. 1997. Determination of platinum in workroom air and in blood and urine from nursing staff attending patients receiving cisplatin chemotherapy. Int Arch Occup Environ Health. 70(3):209-214. https://dx.doi.org/10.1007/s004200050209

Nyman HA, Jorgenson JA, Slawson MH. 2007. Workplace contamination with antineoplastic agents in a new cancer hospital using a closed-system drug transfer device. Hosp Pharm. 42(3):219-225. https://dx.doi.org/10.1310/hpj4203-219

Odraska P, Dolezalova L, Kuta J, Oravec M, Piler P, Blaha L. 2013. Evaluation of the efficacy of additional measures introduced for the protection of healthcare personnel handling antineoplastic drugs. Ann Occup Hyg. 57(2):240-250. https://dx.doi.org/10.1093/annhyg/mes057

Odraska P, Dolezalova L, Kuta J, Oravec M, Piler P, Synek S, Blaha L. 2014. Association of surface contamination by antineoplastic drugs with different working conditions in hospital pharmacies. Arch Environ Occup Health. 69(3):148-158. https://dx.doi.org/10.1080/19338244.2013.763757

Odraska P, Dolezalova L, Piler P, Oravec M, Blaha L. 2011. Utilization of the solid sorbent media in monitoring of airborne cyclophosphamide concentrations and the implications for occupational hygiene. J Environ Monit. 13(5):1480-1487. https://dx.doi.org/10.1039/c0em00660b

Page EH, Couch JR, De Perio MA. 2015. Evaluation of a multiple sclerosis cluster among nurses in an inpatient oncology ward. J Occup Environ Hyg. 12(5):D54-D59. https://dx.doi.org/10.1080/15459624.2014.989359

Panahi D, Azari M, Akbari ME, Zendehdel R, Mirzaei HR, Hatami H, Mehrabi Y. 2016. Development of a new method for sampling and monitoring oncology staff exposed to cyclophosphamide drug. Environ Monit Assess. 188(4):238. https://dx.doi.org/10.1007/s10661-016-5255-x

Peelen S, Roeleveld N, Heederik D, Kromhout H, De Kort W. 1999. Reproductietoxische effecten bij ziekenhuispersoneel [Toxic effects on reproduction in hospital personnel]. The Hague, Netherlands: Dutch Ministry of Social Affairs and Employment.

Pethran A, Schierl R, Hauff K, Grimm CH, Boos KS, Nowak D. 2003. Uptake of antineoplastic agents in pharmacy and hospital personnel. Part I: Monitoring of urinary concentrations. Int Arch Occup Environ Health. 76(1):5-10. https://dx.doi.org/10.1007/s00420-002-0383-8

Pieri M, Castiglia L, Basilicata P, Sannolo N, Acampora A, Miraglia N. 2010. Biological monitoring of nurses exposed to doxorubicin and epirubicin by a validated liquid chromatography/fluorescence detection method. Ann Occup Hyg. 54(4):368-376. https://dx.doi.org/10.1093/annhyg/meq006

Pilger A, Kohler I, Stettner H, Mader RM, Rizovski B, Terkola R, Diem E, Franz-Hainzl E, Konnaris C, Valic E et al. 2000. Long-term monitoring of sister chromatid exchanges and micronucleus frequencies in pharmacy personnel occupationally exposed to cytostatic drugs. Int Arch Occup Environ Health. 73(7):442-448. https://dx.doi.org/10.1007/s004200000164

Poupeau C, Tanguay C, Caron NJ, Bussieres JF. 2016. Multicenter study of environmental contamination with cyclophosphamide, ifosfamide, and methotrexate in 48 Canadian hospitals. J Oncol Pharm Pract. https://dx.doi.org/10.1177/1078155216676632

Poupeau C, Tanguay C, Plante C, Gagne S, Caron N, Bussieres JF. 2017. Pilot study of biological monitoring of four antineoplastic drugs among Canadian healthcare workers. J Oncol Pharm Pract. 23(5):323-332. https://dx.doi.org/10.1177/1078155216643860

Power L, Sessink P, Gesy K, Charbonneau F. 2014. Hazardous drug residue on exterior vial surfaces: Evaluation of a commercial manufacturing process. Hosp Pharm. 49(4):355-362.

Pyy L, Sorsa M, Hakala E. 1988. Ambient monitoring of cyclophosphamide in manufacture and hospitals. Am Ind Hyg Assoc J. 49(6):314-317. https://dx.doi.org/10.1080/15298668891379800

Ramphal R, Bains T, Goulet G, Vaillancourt R. 2015. Occupational exposure to chemotherapy of pharmacy personnel at a single centre. Can J Hosp Pharm. 68(2):104-112.

Ramphal R, Bains T, Vaillancourt R, Osmond MH, Barrowman N. 2014. Occupational exposure to cyclophosphamide in nurses at a single center. J Occup Environ Med. 56(3):304-312. https://dx.doi.org/10.1097/JOM.0000000000000097

Rekhadevi PV, Sailaja N, Chandrasekhar M, Mahboob M, Rahman MF, Grover P. 2007. Genotoxicity assessment in oncology nurses handling anti-neoplastic drugs. Mutagenesis. 22(6):395-401. https://dx.doi.org/10.1093/mutage/gem032

Rubino FM, Verduci C, Buratti M, Fustinoni S, Campo L, Omodeo-Sale E, Giglio M, Iavicoli S, Brambilla G, Colombi A. 2006. Assay of urinary alpha-fluoro-beta-alanine by gas chromatography-mass spectrometry for the biological monitoring of occupational exposure to 5-fluorouracil in oncology nurses and pharmacy technicians. Biomed Chromatogr. 20(3):257-266. https://dx.doi.org/10.1002/bmc.559

Sabatini L, Barbieri A, Lodi V, Violante FS. 2012. Biological monitoring of occupational exposure to antineoplastic drugs in hospital settings. Med Lav. 103(5):394-401.

Schierl R, Masini C, Groeneveld S, Fischer E, Bohlandt A, Rosini V, D P. 2016. Environmental contamination by cyclophosphamide preparation: Comparison of conventional manual production in biological safety cabinet and robot-assisted production by APOTECAchemo. J Oncol Pharm Pract. 22(1):37-45. https://dx.doi.org/10.1177/1078155214551316

Schierl R, Bohlandt A, Nowak D. 2009. Guidance values for surface monitoring of antineoplastic drugs in German pharmacies. Ann Occup Hyg. 53(7):703-711. https://dx.doi.org/10.1093/annhyg/mep050

Schierl R, Herwig A, Pfaller A, Groebmair S, Fischer E. 2010. Surface contamination of antineoplastic drug vials: Comparison of unprotected and protected vials. Am J Health Syst Pharm. 67(6):428-429. https://dx.doi.org/10.2146/ajhp080621

Schierl R, Novotna J, Piso P, Bohlandt A, Nowak D. 2012. Low surface contamination by cis/oxaliplatin during hyperthermic intraperitoneal chemotherapy (HIPEC). Eur J Surg Oncol. 38(1):88-94. https://dx.doi.org/10.1016/j.ejso.2011.10.009

Schmaus G, Schierl R, Funck S. 2002. Monitoring surface contamination by antineoplastic drugs using gas chromatography-mass spectrometry and voltammetry. Am J Health Syst Pharm. 59(10):956-961.

Schmid K, Boettcher MI, Pelz JO, Meyer T, Korinth G, Angerer J, Drexler H. 2006. Investigations on safety of hyperthermic intraoperative intraperitoneal chemotherapy (HIPEC) with Mitomycin C. Eur J Surg Oncol. 32(10):1222-1225. https://dx.doi.org/10.1016/j.ejso.2006.05.011

Schreiber C, Radon K, Pethran A, Schierl R, Hauff K, Grimm CH, Boos KS, Nowak D. 2003. Uptake of antineoplastic agents in pharmacy personnel. Part II: Study of work-related risk factors. Int Arch Occup Environ Health. 76(1):11-16. https://dx.doi.org/10.1007/s00420-002-0385-6

Schulz H, Bigelow S, Dobish R, Chambers CR. 2005. Antineoplastic agent workplace contamination study: The Alberta Cancer Board Pharmacy perspective. J Oncol Pharm Pract. 11(3):101-109. https://dx.doi.org/10.1191/1078155205jp152oa

Sessink PJ, Anzion RB, Van den Broek PH, Bos RP. 1992. Detection of contamination with antineoplastic agents in a hospital pharmacy department. Pharm Weekbl Sci. 14(1):16-22.

Sessink PJ, Boer KA, Scheefhals AP, Anzion RB, Bos RP. 1992. Occupational exposure to antineoplastic agents at several departments in a hospital. Environmental contamination and excretion of cyclophosphamide and ifosfamide in urine of exposed workers. Int Arch Occup Environ Health. 64(2):105-112. https://dx.doi.org/10.1007/BF00381477

Sessink PJ, Cerna M, Rossner P, Pastorkova A, Bavarova H, Frankova K, Anzion RB, Bos RP. 1994a. Urinary cyclophosphamide excretion and chromosomal aberrations in peripheral blood lymphocytes after occupational exposure to antineoplastic agents. Mutat Res. 309(2):193-199. https://dx.doi.org/10.1016/0027-5107(94)90092-2

Sessink PJ, Connor TH, Jorgenson JA, Tyler TG. 2011. Reduction in surface contamination with antineoplastic drugs in 22 hospital pharmacies in the US following implementation of a closed-system drug transfer device. J Oncol Pharm Pract. 17(1):39-48. https://dx.doi.org/10.1177/1078155210361431

Sessink PJ, Friemel NS, Anzion RB, Bos RP. 1994b. Biological and environmental monitoring of occupational exposure of pharmaceutical plant workers to methotrexate. Int Arch Occup Environ Health. 65(6):401-403. https://dx.doi.org/10.1007/BF00383251

Sessink PJ, Leclercq GM, Wouters DM, Halbardier L, Hammad C, Kassoul N. 2015. Environmental contamination, product contamination and workers exposure using a robotic system for antineoplastic drug preparation. J Oncol Pharm Pract. 21(2):118-127. https://dx.doi.org/10.1177/1078155214522840

Sessink PJ, Timmersmans JL, Anzion RB, Bos RP. 1994. Assessment of occupational exposure of pharmaceutical plant workers to 5-fluorouracil. Determination of alpha-fluoro-beta-alanine in urine. J Occup Med. 36(1):79-83.

Sessink PJ, Trahan J, Coyne JW. 2013. Reduction in surface contamination with cyclophosphamide in 30 US hospital pharmacies following implementation of a closed-system drug transfer device. Hosp Pharm. 48(3):204-212. https://dx.doi.org/10.1310/hpj4803-204

Sessink PJ, Van de Kerkhof MC, Anzion RB, Noordhoek J, Bos RP. 1994c. Environmental contamination and assessment of exposure to antineoplastic agents by determination of cyclophosphamide in urine of exposed pharmacy technicians: Is skin absorption an important exposure route? Arch Environ Health. 49(3):165-169. https://dx.doi.org/10.1080/00039896.1994.9940377

Sessink PJ, Wittenhorst BC, Anzion RB, Bos RP. 1997b. Exposure of pharmacy technicians to antineoplastic agents: Reevaluation after additional protective measures. Arch Environ Health. 52(3):240-244. https://dx.doi.org/10.1080/00039899709602893

Sessink PJM, Joost HCdR, Pierik FH, Anzion RBM, Bos RP. 1993. Occupational exposure of animal caretakers to cyclophosphamide. J Occup Med. 35(1):47-52.

Siderov J, Kirsa S, McLauchlan R. 2009. Surface contamination of cytotoxic chemotherapy preparation areas in Australian Hospital Pharmacy Departments. J Pharm Pract Res. 39(2):117-121. https://dx.doi.org/10.1002/j.2055-2335.2009.tb00434.x

Siderov J, Kirsa S, McLauchlan R. 2010. Reducing workplace cytotoxic surface contamination using a closed-system drug transfer device. J Oncol Pharm Pract. 16(1):19-25. https://dx.doi.org/10.1177/1078155209352543

Solass W, Giger-Pabst U, Zieren J, Reymond MA. 2013. Pressurized intraperitoneal aerosol chemotherapy (PIPAC): Occupational health and safety aspects. Ann Surg Oncol. 20(11):3504-3511. https://dx.doi.org/10.1245/s10434-013-3039-x

Sorsa M, Pyy L, Salomaa S, Nylund L, Yager JW. 1988. Biological and environmental monitoring of occupational exposure to cyclophosphamide in industry and hospitals. Mutat Res. 204(3):465-479. https://dx.doi.org/10.1016/0165-1218(88)90042-0

Sottani C, Porro B, Comelli M, Imbriani M, Minoia C. 2010. An analysis to study trends in occupational exposure to antineoplastic drugs among health care workers. J Chromatogr B Analyt Technol Biomed Life Sci. 878(27):2593-2605. https://dx.doi.org/10.1016/j.jchromb.2010.04.030

Sottani C, Porro B, Imbriani M, Minoia C. 2012. Occupational exposure to antineoplastic drugs in four Italian health care settings. Toxicol Lett. 213(1):107-115. https://dx.doi.org/10.1016/j.toxlet.2011.03.028

Sottani C, Rinaldi P, Leoni E, Poggi G, Teragni C, Delmonte A, Minoia C. 2008. Simultaneous determination of cyclophosphamide, ifosfamide, doxorubicin, epirubicin and daunorubicin in human urine using high-performance liquid chromatography/electrospray ionization tandem mass spectrometry: Bioanalytical method validation. Rapid Commun Mass Spectrom. 22(17):2645-2659. https://dx.doi.org/10.1002/rcm.3657

Stover D, Achutan C. 2011. Occupational exposures to antineoplastic drugs in an Oncology-Hematology Department. J Occup Environ Hyg. 8(1):D1-6. https://dx.doi.org/10.1080/15459624.2011.537510

Stuart OA, Stephens AD, Welch L, Sugarbaker PH. 2002. Safety monitoring of the coliseum technique for heated intraoperative intraperitoneal chemotherapy with mitomycin C. Ann Surg Oncol. 9(2):186-191. https://dx.doi.org/10.1007/BF02557372

Sugiura S, Asano M, Kinoshita K, Tanimura M, Nabeshima T. 2011. Risks to health professionals from hazardous drugs in Japan: A pilot study of environmental and biological monitoring of occupational exposure to cyclophosphamide. J Oncol Pharm Pract. 17(1):14-19. https://doi.org/10.1177/1078155209358632

Sugiura S, Nakanishi H, Asano M, Hashida T, Tanimura M, Hama T, Nabeshima T. 2011. Multicenter study for environmental and biological monitoring of occupational exposure to cyclophosphamide in Japan. J Oncol Pharm Pract. 17(1):20-28. https://dx.doi.org/10.1177/1078155210369851

Tanimura M, Yamada K, Sugiura S, Mori K, Nagata H, Tadokoro K, Miyake T, Hamaguchi Y, Sessink P, Nabeshima T. 2009. An environmental and biological study of occupational exposure to cyclophosphamide in the pharmacy of a Japanese community hospital designated for the treatment of cancer. J Health Sci. 55(5):750-756. https://dx.doi.org/10.1248/jhs.55.750

Thulin H, Sundberg E, Hansson K, Cole J, Hartley-Asp B. 1995. Occupational exposure to nor-nitrogen mustard: Chemical and biological monitoring. Toxicol Ind Health. 11(1):89-97. https://dx.doi.org/10.1177/074823379501100108

Touzin K, Bussieres JF, Langlois É, Lefebvre M. 2009. Evaluation of surface contamination in a hospital hematology-oncology pharmacy. J Onc Pharm Pract. 15(1):53-61. https://dx.doi.org/10.1177/1078155208096904

Touzin K, Bussieres JF, Langlois E, Lefebvre M, Gallant C. 2008. Cyclophosphamide contamination observed on the external surfaces of drug vials and the efficacy of cleaning on vial contamination. Ann Occup Hyg. 52(8):765-771. https://dx.doi.org/10.1093/annhyg/men050

Turci R, Minoia C, Sottani C, Coghi R, Severi P, Castriotta C, Del Bianco M, Imbriani M. 2011. Occupational exposure to antineoplastic drugs in seven Italian hospitals: The effect of quality assurance and adherence to guidelines. J Oncol Pharm Pract. 17(4):320-332. https://dx.doi.org/10.1177/1078155210381931

Turci R, Sottani C, Ronchi A, Minoia C. 2002. Biological monitoring of hospital personnel occupationally exposed to antineoplastic agents. Toxicol Lett. 134(1-3):57-64. https://dx.doi.org/10.1016/S0378-4274(02)00163-7

Ursini CL, Cavallo D, Colombi A, Giglio M, Marinaccio A, Iavicoli S. 2006. Evaluation of early DNA damage in healthcare workers handling antineoplastic drugs. Int Arch Occup Environ Health. 80(2):134-140. https://dx.doi.org/10.1007/s00420-006-0111-x

Van Vloten WA, Cooijmans AC, Poel J, Meulenbelt J. 1993. Concentrations of nitrogen mustard in the air during topical treatment of patients with mycosis fungoides. Br J Dermatol. 128(4):404-406. https://dx.doi.org/10.1111/j.1365-2133.1993.tb00199.x

Vandenbroucke J, Robays H. 2001. How to protect environment and employees against cytotoxic agents, the UZ Ghent experience. J Oncol Pharm Practice. 6:146-152. https://dx.doi.org/10.1177/107815520100600403

Venitt S, Crofton-Sleigh C, Hunt J, Speechley V, Briggs K. 1984. Monitoring exposure of nursing and pharmacy personnel to cytotoxic drugs: Urinary mutation assays and urinary platinum as markers of absorption. Lancet. 323(8368):74-77. https://dx.doi.org/10.1016/S0140-6736(84)90005-9

Viegas S, Padua M, Veiga AC, Carolino E, Gomes M. 2014. Antineoplastic drugs contamination of workplace surfaces in two Portuguese hospitals. Environ Monit Assess. 186(11):7807-7818. https://dx.doi.org/10.1007/s10661-014-3969-1

Villa AF, El Balkhi S, Aboura R, Sageot H, Hasni-Pichard H, Pocard M, Elias D, Joly N, Payen D, Blot F et al. 2015. Evaluation of oxaliplatin exposure of healthcare workers during heated intraperitoneal perioperative chemotherapy (HIPEC). Ind Health. 53(1):28-37. https://dx.doi.org/10.2486/indhealth.2014-0025

Villarini M, Dominici L, Piccinini R, Fatigoni C, Ambrogi M, Curti G, Morucci P, Muzi G, Monarca S, Moretti M. 2011. Assessment of primary, oxidative and excision repaired DNA damage in hospital personnel handling antineoplastic drugs. Mutagenesis. 26(3):359-369. https://dx.doi.org/10.1093/mutage/geq102

Vyas N, Turner A, Clark JM, Sewell GJ. 2016. Evaluation of a closed-system cytotoxic transfer device in a pharmaceutical isolator. J Oncol Pharm Pract. 22(1):10-19. https://dx.doi.org/10.1177/1078155214544993

Wick C, Slawson MH, Jorgenson JA, Tyler LS. 2003. Using a closed-system protective device to reduce personnel exposure to antineoplastic agents. Am J Health Syst Pharm. 60(22):2314-2320.

Yoshida J, Koda S, Nishida S, Nakano H, Tei G, Kumagai S. 2013. Association between occupational exposure and control measures for antineoplastic drugs in a pharmacy of a hospital. Ann Occup Hyg. 57(2):251-260. https://doi.org/10.1093/annhyg/mes061

Yoshida J, Tei G, Mochizuki C, Masu Y, Koda S, Kumagai S. 2009. Use of a closed system device to reduce occupational contamination and exposure to antineoplastic drugs in the hospital work environment. Ann Occup Hyg. 53(2):153-160. https://dx.doi.org/10.1093/annhyg/men081

Yuki M, Ishida T, Sekine S. 2015. Secondary exposure of family members to cyclophosphamide after chemotherapy of outpatients with cancer: A pilot study. Oncol Nurs Forum. 42(6):665-671. https://dx.doi.org/10.1188/15.ONF.42-06AP

Yuki M, Sekine S, Takase K, Ishida T, Sessink PJ. 2012. Exposure of family members to antineoplastic drugs via excreta of treated cancer patients. J Oncol Pharm Pract. https://dx.doi.org/10.1177/1078155212459667

Ziegler E, Mason HJ, Baxter PJ. 2002. Occupational exposure to cytotoxic drugs in two UK oncology wards. Occup Environ Med. 59(9):608-612. https://dx.doi.org/10.1136/oem.59.9.608