# Appendix F Studies Reporting on Genetic Toxicity

Table F-1 Studies Reporting on Genetic Toxicity, Including Chromosomal Aberrations, Micronucleus Induction, and DNA Damage Measured by Comet Assay

Study | Study Design (Occupation, Location, Sex) | No. of Participants | Exposure Measure (Duration) | Outcome Measured | Analysis | Results
Anwar et al. (1994) | Cross-sectional (Nurses, National Cancer Institute, Egypt, F) | 20 exposed, 20 unexposed nurses | Job title and interviewer-led questionnaire (79.9 ± 46.2 months) Note: Nurses routinely operated under inadequate protection | % cells with CA/100 cells and no. of MN/1,000 cells (lymphocytes) | Chi-squared test | Significantly higher % cells with CA and no. of cells with MN compared to control nurses
Bolognesi et al. (2005) | Cross-sectional (Nurses, IMPEA project, Italy, FM) | For lymphocytes: 42 exposed, 43 unexposed university professionals; for buccal cells, 50 exposed and 50 unexposed | Job title, [self-reported] questionnaire, and biomonitoring (10.2 years) Note: Adequate safety equipment and PPE were used | No. of MN/1,000 cells (lymphocytes or buccal) | Mann-Whitney U-test | No difference in no. of MN (lymphocyte or buccal) compared to control subjects
Boughattas et al. (2010) | Cross-sectional (Nurses, Tunisia, FM) Note: Same population as Bouraoui 2011 | 20 exposed, 20 unexposed administrative staff | Job title and self-reported questionnaire (range 1–16 years) Note: 80% of nurses used PPE; ward nurses usually used a laminar flow cabinet to prepare doses, while outpatient nurses usually prepared drugs at patient’s side or in the hallway | No. of cells with MN/1,000 cells (lymphocytes) | Pearson’ Chi-squared test; ANOVA and Student’s t-test used to test effect of age, sex, exposure duration, smoking, PPE, cytostatic contact index (CCI), family history of cancer | Significantly higher no. of cells with MN in exposed nurses; significant effect of CCI on outcome and other variables were NS
Bouraoui et al. (2011) | Cross-sectional (Nurses, Tunisia, FM) Note: Same population as Boughattas 2010 | 20 exposed, 20 unexposed administrative staff | Job title and self-reported questionnaire (range <5–10 years) Note: 75% of nurses used gloves, 10% used gowns, 15% used masks, and 5% did not use PPE | No. of CA/100 cells and no. of MN/1,000 cells (lymphocytes) | Student’s-t-test; multivariate regression on effect of age, sex exposure duration, smoking, PPE, and proliferation rate index on CA | Significantly higher no. of CA and no. of MN compared to unexposed administrative staff; no effect of variables on CA
Buono-Michel et al. (2000) | Cross-sectional (Nurses, France, FM) | 14 exposed, 14 unexposed blood donors | Job title and self-reported questionnaire (range 1–28 years) Note: No hood or dedicated ventilation available in drug preparation area; most nurses wore gloves and accidental exposure occurred to 7 nurses | No. of cells with MN/1,000 cells (lymphocytes) | Mann-Whitney U-test; ANOVA tested effects of age, family history of cancer; correlation analysis tested for effect of smoking and exposure duration | Significantly higher no. of cells with MN compared to unexposed blood donors; no correlation or effect of variables on MN
Burgaz et al. (1999) | Cross-sectional (Nurses, Turkey, F) Note: Overlapping population with Burgaz 2002 | Lymphocytes: 23 exposed, 13 unexposed nurses and office staff; for buccal cells, 25 and 14, respectively | Job title, interviewer-led questionnaire, and biomonitoring (5 ± 4.45 years) Note: Nurses involved in preparation and administration of the agents for at least 1 year, 4–5 times per day, no safety hoods were used, and inconsistent PPE use | No. of MN/1,000 cells (lymphocytes or buccal cells) | Student’s t-test or Mann-Whitney U-test; Pearson and Spearman Rank test examined influence of age, smoking, exposure duration, frequency of handling | Significantly higher no. of MN in lymphocytes and higher, but NS, no. of MN in buccal cells compared to unexposed subjects; no significant effect of variables on outcome
Burgaz et al. (2002) | Cross-sectional (Nurses, Turkey, F) Note: Overlapping population with Burgaz 1999 | 20 exposed, 18 unexposed secretaries and nursing students | Job title, [self-reported] questionnaire, and biomonitoring (8.15 ± 4.70 years) Note: Nurses involved in preparation and administration of the agents for at least 1 year with minimal protection | % cells with CA/200 cells (lymphocytes) | Student’s t-test or Mann-Whitney U-test; multivariate ANOVA examining effect of exposure, smoking, and age; correlation analysis on urinary CP, frequency of handling, and PPE | Higher, but NS, % cells with CA compared to unexposed subjects; exposure a significant factor in ANOVA; no relationships observed in correlation analysis
Buschini et al. (2013) | Cross-sectional (Hospital nurses, Italy, F) Note: Same population as Moretti 2015 | 63 exposed, 74 unexposed nurses | Job title and [self-reported] questionnaire (110 ± 86 months) | % Tail DNA (leukocytes) | Wilcoxson rank sum test | No difference in % tail DNA
Cavallo et al. (2005) | Cross-sectional (Ward and outpatient nurses, and pharmacy technicians, Italy, FM) Note: Same population as Ursini 2006 | 30 exposed: 13 ward nurses, 12 outpatient nurses, 5 pharmacy technicians, and 30 unexposed administrative staff | Job title, [self-reported] questionnaire, and biomonitoring (6.2 ± 2.9 years, ward nurses; 7.0 ± 2.0 years, pharmacists; 8.1 ± 6.0 years, outpatient nurses) Note: All exposed personnel used adequate PPE, including gloves, caps, overalls, and goggles | No. of CA/100 cells (lymphocytes) and no. of MN/1,000 cells (lymphocytes or buccal cells) | ANOVA for CA, and Z normal test for MN | Significantly higher no. of CA compared to unexposed subjects; significantly higher no. of MN in buccal cells in ward and outpatient nurses compared to unexposed subjects; no. of MN in lymphocytes NS
Connor et al. (2010) | Cross-sectional (Nurses, pharmacists, and pharmacy technicians, USA, FM) Note: Same population as McDiarmid 2010 and 2014 | 66 exposed, 52 unexposed nurses and pharmacy personnel | Job title, [self-reported] questionnaire, 6–week diary of drug-handling events, biomonitoring, and environmental monitoring (>6 months) Note: Exposed personnel followed safe handling practices as per NIOSH, and used biological safety cabinets for drug preparation | % Tail DNA and tail moment | Linear models adjusted for covariates; covariates included: study site location, age, glove usage, personal medication use | No difference in % tail DNA or tail moment; covariate NS
Cornetta et al. (2008) | Cross-sectional (Nurses, Italy, FM) Note: Population overlaps with Testa 2007 | 83 exposed, 73 unexposed administrative staff | Job title and interviewer-led questionnaire (12.2 ± 7.3 years) Note: Exposed nurses used adequate PPE and vertical laminar flow cabinet | No. of MN/1,000 cells (lymphocytes) and % tail DNA | Mann-Whitney U-test and unpaired t-test; multivariate regression examined influence of age, sex, smoking, exposure duration, and genotype | Significantly higher no. of MN and % tail DNA compared to unexposed subjects; age and sex were significant variables for no. of MN
Cooke et al. (1991) | Cross-sectional (Nurses, pharmacists and pharmacy technicians, United Kingdom, sex NR) | 61 exposed, 12 unexposed office workers | Job title and [self-reported] questionnaire (mc > 6 months) Note: Exposed pharmacists used biological safety cabinets | No. of CA/100 cells (lymphocytes) | Chi-squared test for individuals with ≤0.9 versus ≥1.0 CA per 100 cells; ANOVA of transformed data | No difference in no. of CA compared to unexposed controls
Deng et al. (2005) | Cross-sectional (Methotrexate production workers, China, FM) | 21 exposed, 21 unexposed [no description] | Job title, demographics, and job tasks reported [method NR] (range 1–14 years) Note: Inadequate ventilation equipment; 20 of 21 workers used PPE | No. of cells with MN and no. of MN/1,000 cells, tail length and tail moment (lymphocytes) | Student’s t-test; Kendall’s test evaluated correlation of exposure duration | Significantly higher no. of cells with MN, no. of MN, and significantly greater tail length compared to controls; significant correlation with exposure duration for no. of cells with MN, no. of MN; tail moment NS
Deng et al. (2006) | Cross-sectional (Vincristine production workers, China, FM) | 15 exposed, 15 unexposed [no description] | Job title, work tasks and safety equipment availability [method NR] (range 1–20 years) Note: Inadequate ventilation equipment; all 15 workers used PPE | No. of cells with MN and no. of MN/1,000 cells (lymphocytes), tail length and tail moment | Student’s t-test (tail moment only), Wilcoxon’s rank sum; Kendall’s test evaluated correlation of exposure duration | Significantly higher no. of cells with MN, no. of MN, and tail length; tail moment NS
El-Ebiary et al. (2013) | Cross-sectional (Nurses and pharmacists, Egypt, F) | 38 exposed, 30 unexposed nurses | Job title and [self-reported] questionnaire (8.18 ± 4.55 years) Note: Nurse used gloves, but not other PPE; pharmacists used adequate PPE and worked with biological safety cabinets | % cells with CA and no. of CA/200 cells, no of MN/1,000 cells (lymphocytes) | Student’s t-test; correlation analysis by Pearson’s test for age and exposure duration | Significantly higher % cells with CA, no. of CA, and no. of MN compared to unexposed nurses; significant Pearson’s coefficient for duration of exposure for CA
Ensslin et al. (1997) | Cross-sectional (Pharmacy personnel, Germany, FM) | 13 exposed, 13 unexposed [no description] | Job title, work tasks and drugs handled [method NR], and biomonitoring (31.6 ± 13.5 months) Note: Pharmacists used vertical laminar flow hood; gloves and gown always worn | No. of MN/1,000 cells (lymphocytes) | Wilcoxon rank test | No difference in no. of MN compared to unexposed subjects
Garaj-Vrhovac and Kopjar (1998) | Cross-sectional (Nurses, Croatia, sex NR) Note: Same population as Kasuba 1999 | 10 exposed, 10 unexposed [no description] | Job title only (17.3 years) | No. of MN/500 cells (lymphocytes) | Chi-squared test | Significantly higher no. of MN compared to unexposed subjects
Grummt et al. (1993) | Cross-sectional (Nurses and physicians, Germany, FM) | 106 exposed, 93 unexposed [no description] | Job title and self-reported questionnaire (range 1–39 years) Note: Exposed personnel prepared, administered and handled drugs with a biological safety cabinet | No. of CA/100 cells | Mann-Whitney U-test, including analyses of data by smoking status, age, and exposure duration | Significantly higher no. of CA compared to unexposed subjects
Harris et al. (1992) | Cross-sectional (Nurses, USA, F) | 24 low exposure, 21 moderate exposure, and 19 high exposure | Job title and interviewer-led questionnaire (duration NR) | No. of MN/1,000 cells (lymphocytes) | Kruskal-Wallis one-way ANOVA, evaluated effect of age, ionizing radiation, chemicals or drugs, exposure duration, smoking, PPE | No difference in no. of MN compared to lower exposed nurses; significantly higher no. of MN was observed in low and moderate exposure nurses using gloves <100% of the time compared to nurses using gloves 100% of the time
Hessel et al. (2001) | Cross-sectional (Nurses, pharmacy personnel, one physician, and one orderly, Germany, FM) | 113 exposed (tested end of 1 work week for 3 cycles: 83 for cycle 1, 91 for cycle 2, 73 for cycle 3), 93 baseline (3-week absence from exposure), and 60 unexposed office workers | Job title, self-reported questionnaire, and biomonitoring (53 months, range 1–144 months) | No. of MN/1,000 cells (lymphocytes) – tested beginning work shift and 3 work cycles | Mann-Whitney U and Student’s t-test; Friedman’s ANOVA to test outcome over study period; multiple linear regression to test the effect of age, ionizing radiation, and exposure status | No difference in no. of MN compared to unexposed subjects on cycle 1 or over the entire study; ionizing radiation exposure was a significant factor in MN at baseline; for cycle 1 (highest exposure cycle), age was a significant factor, but not ionizing radiation or exposure status
Hola et al. (1988) | Cross-sectional (Nurses and physicians, Czech Republic, FM) | 136 exposed (114 nurses and 22 physicians), 20 unexposed blood donors, 277 historical unexposed controls | Job title, number of drug administrations, and use of safety cabinet [method NR] (9.3 ± 0.7 years, nurses and 10.3 ± 1.4 years, physicians) | % cells with CA/100 cells scored (lymphocytes) | Student’s t-test | Significantly higher % cells with CA in exposed nurses working in pulmonary department compared to unexposed blood donors; % cells with CA in exposed physicians NS
Izdes et al. (2009) | Cross-sectional (Nurses, Turkey, FM) | 19 exposed, 19 unexposed office workers | Job title and self-reported questionnaire (11.3 ± 4.2 years) Note: Vertical flow safety cabinet, gloves and mask used during preparation of drugs | DNA damage index (0 = none, 1 = low, 2 = high migration) | Mann-Whitney U-test with Bonferroni correction; Pearson’s or Spearman’s correlation test for exposure duration (years of employment) | Significantly greater DNA damage index compared to unexposed office workers; no correlation with years of employment
Jakab et al. (2001) | Cross-sectional (Nurses, Hungary, F) | 95 exposed from 4 hospitals, 34 unexposed industrial workers, 74 historical unexposed controls | Job title and interviewer-led questionnaire (mean range 4.0–6.5 years across 4 hospitals) Note: Hospital 1 had no safety equipment, Hospital 2 had insufficient safety equipment, and Hospital 3 and 4 had sufficient equipment | % of cells with CA and no. of CA/100 cells | Student’s t-test and Mann-Whitney U-test | Significantly higher % cells with CA and no. of CA in exposed nurses from all 4 hospitals compared to unexposed industrial workers
Kašuba et al. (1999) | Cross-sectional (Nurses, Croatia, F) Note: Same population as Garaj-Vrhovac and Kopjar 1998 | 20 exposed, 16 unexposed [no description] | Job title, work tasks, and drugs handled [method NR] (range 1–31 years) | No. of cells with MN and no. of MN/1,000 cells (lymphocytes) | Chi-squared test | Significantly higher no. of cells with MN and no. of MN in exposed nurses, with significant increases in nurses with duration of exposure 20-31 years, but not 11–14 years compared to compared to unexposed subjects
Kevekordes et al. (1998) | Cross-sectional (Nurses, Germany, FM) | 10 exposed (n = 10 in first examination 2 months after installation of [vertical] laminar flow safety hood and n = 6 retested 9 months after installation), 10 unexposed [no description] | Job title and self-reported questionnaire (duration NR) Note: Exposed nurses reported following recommended safety precautions; PPE was used | No. of MN/1000 cells (lymphocytes) | Mann-Whitney U-test | Significantly higher no. of MN compared to unexposed subjects in first examination (2 months after installation of safety hood); second examination (9 months following installation of safety hood) revealed no difference in MN compared to first examination values for exposed or unexposed subjects
Kopjar and Garaj-Vrhovac (2001) | Cross-sectional (Nurses and physicians, Croatia, FM) Note: Overlapping population with Kopjar 2009 | 50 exposed, 20 unexposed students and office workers | Job title and self-reported questionnaire (12.9 years, range 1–30 years) Note: PPE usage differed among exposed subjects; n = 20 used gloves only, n = 8 used gloves and masks, n = 19 used gloves and safety cabinet with vertical air flow, and n = 3 used gloves, masks, and safety cabinet with vertical air flow | % Tail DNA, tail length, and tail moment (lymphocytes) | Mann-Whitney U-test | Significantly greater % tail DNA, tail length and tail moment compared to unexposed subjects; significantly greater DNA damage seen in exposed nurses using only gloves versus exposed nurses using glove and safety cabinet with vertical air flow, or using glove, mask, and safety cabinet with vertical air flow
Kopjar et al. (2009) | Cross-sectional (Nurses and physicians, Croatia, F) Note: Overlapping population with Kopjar and Garaj-Vrhorac 2001 | 50 exposed, 50 unexposed students and office workers | Job title and self-reported questionnaire (12.9 years, range 1–30 years) Note: 38% of exposed subjects used gloves and vertical laminar flow; 16% used gloves and mask, while only 6% simultaneously used gloves, mask, and vertical laminar flow cabinet | % cells with CA and no. of CA/200 cells, no. of cells with MN and no. of MN/1,000 cells and tail moment (lymphocytes) | Mann-Whitney U-test; Spearman Rank Order Correlations age, smoking, exposure duration, PPE; Kruskal-Wallis ANOVA by ranks | Significantly higher % cells with CA, no. of CA, no. of cells with MN, no. of MN, and tail length compared to unexposed subjects; highest level of tail length observed in exposed subjects who only used latex gloves; age and exposure duration influenced MN; longer exposure duration was accompanied with a shift toward higher values for tail length, % cells with CA and number of cells with MN
Krepinsky et al. (1990) | Cross-sectional (Nurses, Canada, F) | 10 exposed, 10 unexposed nurses | Job title, types and frequency of drug handling, and safety equipment used [method NR] (duration NR) Note: Exposed nurses prepared drugs in separate rooms without safety hoods or special ventilation; safety education provided, but PPE usage not monitored | No. of CA/300 cells (lymphocytes) measured at end of work cycle and after 2–6 days off work | Chi-squared test | No difference in no. of CA compared to unexposed nurses at end of work cycle or after time off work; no. of CA was higher, but NS, compared to unexposed nurses (combining end of work and after work samples)
Ladeira et al. (2014) | Cross-sectional (Nurses, Portugal, FM) | 27 exposed, 111 unexposed university employees | Job title, self-reported questionnaire, and environmental monitoring (6.01 years, range 0.17–30 years) | No. of MN/1,000 cells (lymphocytes) | Mann-Whitney U-test, multiple linear regression of exposure, age, sex, smoking and alcohol consumption | Significantly higher no. of MN compared to unexposed subjects; exposure and age were significant variables
Laffon et al. (2005) | Cross-sectional Nurses, Portugal, FM) | 30 exposed, 22 unexposed nurses from schools | Job title and interviewer-led questionnaire (6.40 ± 6.22 years) Note: Exposed nurses used laminar airflow hoods and wore laboratory coat, mask, and gloves while preparing, mixing, and administering these drugs | No. of MN/1,000 cells (lymphocytes) and tail length (leukocytes) | ANOVA with Student’s t-test; overall F-test assessed effect of exposure duration, age, sex, smoking and genotypes | Significantly greater tail length compared to unexposed subjects; exposure duration was a significant factor; no difference in no. of MN compared to unexposed subjects
Machado-Santelli et al. (1994) | Cross-sectional (Nurses, Brazil, FM) | 25 exposed, 25 unexposed nurses, physician, secretaries, and drivers | Job title and self-reported questionnaire (range 1–6 years) Note: Only one nurse used a safety hood, 21 nurses used gloves, 19 nurses used masks, and 2 nurses did not use PPE | No. of cells with MN/1,000 cells (buccal cells) | Chi-squared test | Significantly higher no. of cells with MN compared to unexposed subjects
Mader et al. (2009) | Cohort, longitudinal (Nurses, Austria, F) Note: Same population as Pilger 2000 | 15 subjects served as their own controls: exposed (1, 3, 6, and 9 months on job, referent, after a 3-week vacation) | Job title, self-reported questionnaire, and environmental monitoring (range 1–17 years) | DNA damage index (0 = <5%, 1 = 5–20%, 2 = >20–40%, 3 = >40–95%, 4 = >95%) | Kruskal-Wallis test followed by a post-hoc Dunn’s multiple comparisons; trend analysis by linear regression | Significantly higher DNA damage compared to referent using trend analysis (p = 0.02); no correlation with years of exposure
Mahmoodi et al. (2017) | Cross-sectional (Nurses and pharmacy technicians, Iran, FM) | 71 exposed nurses, 10 exposed pharmacy technicians, 74 unexposed nurses | Job title and self-reported questionnaire (duration >6 months and worked the week prior to assessment) | No. of CA/100 cells and no. of MN/1,000 cells (lymphocytes) | Student’s t-test | Significantly higher no. of CA and no. of MN compared to unexposed nurses
Maluf and Erdtmann (2000b) | Cross-sectional (Nurses and pharmacists, Brazil, FM) | First study: 10 exposed and 10 unexposed workers; follow-up study: 12 exposed and 12 unexposed; 34 historical unexposed controls | Job title and self-reported questionnaire (range 1–6 years) | No. of MN/2,000 cells and DNA damage index (0 = <5%, 1 = 5–20%, 2 = >20–40%, 3 = >40–95%, 4 = >95%) (lymphocytes) | Mann-Whitney U-test; Spearman rank test for correlations for age and smoking | In first study, significantly higher no. of MN compared to concurrent unexposed workers; in follow-up study, no difference in no. of MN and significantly higher DNA damage index (only measured in follow-up study) compared to both unexposed groups; no correlation with age or smoking
McDiarmid et al. (2010) | Cross-sectional (Nurses, pharmacists, and pharmacy technicians, USA, FM) Note: Same population as Connor 2010 and McDiarmid 2014 | 63 exposed, 46 unexposed nursing and pharmacy personnel | Job title, interviewer-led questionnaire, and 6–week diary of drug-handling events (duration >6 months and worked 24 hours in week prior to assessment) Note: Exposed personnel followed safe handling practices, including drug preparation in a biological safety cabinet, use of gloves, work practices to reduce drug aerosolization | No. of CA/200 cells scored and IRR of CA on chromosomes 5, 7, and 11 (lymphocytes) | Poisson regression (categorical analysis) and Poisson distribution and log link function (continuous variable for frequency of drug handling) | Significantly higher no. of CA and IRR of CA on chromosome 5 of highest exposed nurses compared to unexposed subjects; significantly higher IRR of CA on chromosome 5 with increasing handling events of all cancer chemotherapy or alkylating agents only; IRR of CA on chromosome 7 or 11 NS
McDiarmid et al. (2014) | Cross-sectional (Nurses, pharmacists, and pharmacy technicians, USA, FM) Note: Same population as Connor 2010 and McDiarmid 2010 | 63 exposed, 46 unexposed nursing and pharmacy personnel | Job title, interviewer-led questionnaire, and 6-week diary of drug-handling events (duration >6 months and worked 24 hours in week prior to assessment) Note: Exposed personnel followed safe handling practices, including drug preparation in a biological safety cabinet, use of gloves, work practices to reduce drug aerosolization | IRR of CA on chromosomes 5, 7, and 11 for non-alkylating agent exposure/200 cells scored (lymphocytes) | Poisson regression (categorical analysis) and Poisson distribution and log link function (continuous variable for frequency of drug handling) | Significantly higher IRR of CA on chromosome 5 with increasing handling events of non-alkylating cancer chemotherapy agents; IRR of CA on chromosome 7 or 11 NS
Medková (1990) | Cross-sectional (Physicians, nurses, auxiliary workers, Czech Republic, FM) | 40 exposed from Department of Radiotherapy, 51 unexposed (20 medical studies and 31 workers from Department of Anesthesiology and Resuscitation) | Job title and [self-reported] questionnaire (range 0–15 years) | % cells with CA/100 cells scored (lymphocytes) | Student’s t-test | Significantly higher % of cells with CA compared to unexposed subjects
Milković-Kraus and Horvat (1991) | Cross-sectional (Nurses, Yugoslavia, F) | 42 exposed, 42 unexposed nurses | Job title and [self-reported] questionnaire (duration NR) Note: None of nurses routinely used PPE | No. of CA/200 cells (lymphocytes) | Sign test for paired samples; linear regression analysis for possible age-dependent increase of observed variables | Significantly higher no. of CA compared to unexposed nurses; age was not a significant factor
Moretti et al. (2013) | Cross-sectional (Nurses, pharmacists, and support personnel, Italy, FM) Note: Same population as Villarini 2011 | 52 exposed, 52 unexposed blood donors | Job position and [self-reported] questionnaire (<10 years, 65%; >10 years, 35%) Note: 3 nurses used gloves only, 41 used gloves and mask, and 8 used no protection | No. of MN/1,000 cells and % tail DNA (lymphocytes) | Mann-Whitney U-test followed by Whitney U-test and Bonferroni correction; multiple linear regression tested effects of exposure, sex, age, smoking, type of occupation, exposure duration, and PPE | Significantly higher % tail DNA compared to unexposed blood donors; >10 years of employer had significantly higher levels of % tail DNA than less years employed; no. of MN NS
Moretti et al. (2015) | Cross-sectional (Nurses, Italy, F) Note: Same population as Buschini 2013 | 71 exposed, 77 unexposed nurses (70 exposed and 75 unexposed for no. of CA/100 cells) | Job title, self-reported questionnaire, biomonitoring, and environmental monitoring (9.20 ± 7.18 years) | No. of CA/100 cells and no. of MN/1,000 cells (lymphocytes) | Mann-Whitney U-test; followed by Mann-Whitney U-test post-hoc analysis with Bonferroni correction; multiple linear regression tested effects of exposure, age, type of occupation, exposure duration, PPE and urinary CP | Significantly higher no. of CA and no. of MN compared to unexposed nurses; variance was mainly explained by the subjects’ type of occupation (another measure of exposure)
Mrđanović et al. (2012) | Cross-sectional (Nurses, Bosnia and Herzegovina, F) | 15 exposed, 20 unexposed workers [no description provided] | Job title and self-reported questionnaire (range 1–20 years) Note: Nurses used gloves, masks, and protective clothes | No. of MN/1,000 cells (lymphocytes) | Mann-Whitney U-test and ANOVA | Significantly higher no. of MN in exposed nurses
Mušák et al. (2006) | Cross-sectional (Healthcare workers, Slovakia, FM) Note: Same population as Mušák 2013 | 72 exposed, 34 unexposed hospital workers | Job title (8.09 ± 7.30 years) | No. of CA/100 cells (lymphocytes) | Mann-Whitney U-test | Higher, but NS (p = 0.07), no. of CA compared to unexposed workers
Mušák et al. (2013) | Cross-sectional (Nurses and physicians, Slovakia, FM) Note: Same population as Mušák 2006 | 249 exposed, 250 unexposed hospital workers | Job title and self-reported questionnaire (8.5 ± 8.6 years) | % cells with >1 CA (lymphocytes) | Mann-Whitney U-test and Kruskal-Wallis test and logistic regression tested effect of exposure, age, sex, and smoking | Significantly higher % cells with >1 CA compared to unexposed workers; exposure was only significant variable
Nikula et al. (1984) | Cross-sectional (Nurses, Finland, [F]) | 11 exposed, 16 unexposed (11 hospital clerks and 5 laboratory workers) | Job title and interviewer-led questionnaire (range 2.5–10 years) Note: After 1980, improvements were made to work practices and safety equipment (e.g., biological safety cabinet and isolated room for drug handling); nurses wear gloves and masks | % cells with CA (lymphocytes) | Mann-Whitney U-test | Significantly higher % cells with CA compared to either unexposed hospital clerks or unexposed laboratory workers
Pilger et al. (2000) | Cross-sectional (Pharmacy personnel, Austria, FM) Note: Same populations as Mader 2009 | 16 exposed, 16 unexposed workers from same hospital who were tested at 5 time points | Job title, self-reported questionnaire, and biomonitoring (duration NR) Note: Hospitals had central workplaces containing cabinets with vertical laminar flow and personnel wear glove, overalls, caps, and goggles | No. of MN/2,000 cells (lymphocytes) | ANOVA with stochastic components to compare data on the same subjects over 5 sampling periods | No difference in the no. of MN compared to unexposed subjects
Pohlová et al. (1986) | Cross-sectional (Chemists, laboratory assistants, pilot plant workers, Czech Republic, FM) | 38 exposed (8 pilot workers and 30 chemists and laboratory assistants), 18 unexposed librarians and clerks | Job title and self-administered questionnaire (range >1–<6 years) | % cells with CA (lymphocytes) | Student’s t-test | Significantly higher % of cells with CA compared to unexposed workers
Rekhadevi et al. (2007) | Cross-sectional (Nurses, India, F) | 60 exposed, 60 unexposed from general population | Job title, interviewer-led questionnaire, and biomonitoring (range 6–23 years) | No. of MN/1,000 cells (lymphocytes or buccal cells), and tail length (lymphocytes) | Student’s t-test; multiple linear regression for age, exposure duration, daily exposure | Significantly higher no. of MN (buccal or lymphocytes) and tail length compared to unexposed subjects; age and exposure duration were significant for MN and tail length; significantly higher tail length for nurses with ≥10 years exposure compared to <10 years exposure
Rodríguez-Montero et al. (2016) | Cross-sectional (Medical Oncology Service workers, Cuba, FM) | 14 exposed: 10 workers preparing doses in the Central Unit of Cytostatic Mixes (CUCM) and 4 workers of the Ambulatory Chemotherapy Room (ACR), 14 unexposed workers at same medical institution | Job title, job tasks, duration, and frequency of handling drugs [method NR] (mean range 12.8–129.6 months) Note: Drugs were prepared in CUCM with correct use of primary protective barriers; good laboratory practice is employed in both the CUCM and the ACR | No. of cells with MN/1,000 cell (buccal cells) | Mann-Whitney U-test | No difference in no. of MN compared to unexposed subjects
Rombaldi et al. (2009) | Cross-sectional (Nurses and pharmacists, Brazil, FM) | 20 exposed, 20 unexposed office workers | Job position and self-reported questionnaire (range 0.5–10 years) Note: All nurses and pharmacists used PPE, such as protective clothes, eyes glasses, gloves, masks; both hospitals had vertical laminar flow hoods | No. of cells with MN/1,000 cells and DNA damage index (0 = <5%, 1 = 5–20%, 2 = >20–40%, 3 = >40–95%, 4 = >95%) (lymphocytes) | Student’s t-test; ANOVA with post-hoc Tukey’s t-test for multiple comparisons during the week; Pearson coefficient for age and exposure duration | Significantly higher no. of cells with MN and DNA damage index compared to unexposed subjects; age was a significant factor for MN; positive correlation between DNA damage index and sampling day such that the it was significantly greater on Wednesday or Thursday relative to Monday (the first day sampled); alcohol consumption also a significant factor for DNA damage index
Roth et al. (1994) | Cohort, prospective (Pharmacists, Finland, F) | 6 exposed: tested at start of job and after 1 year of work, 6 unexposed office workers | Job title, previous and current drug handling, use of PPE [method NR] (duration not applicable) Note: Pharmacists used overall, masks, and gloves; drug handling conducted in vertical laminar flow safety cabinet in a special negative-pressured laboratory, apart from other working facilities | % cells with CA and no. of cells with MN/1,000 cells scored (lymphocytes) | Logistic-binomial regression (30 trials); model considered exposure, age, and sample batch | No difference in % cells with CA or no. of cells with MN after 1 year of work compared to unexposed subjects
Rubeš et al. (1998) | Cross-sectional (Nurses and physicians, Czech Republic, FM) | 10 exposed, 10 unexposed nurses and doctors, 11 unexposed blood donors | Job title and drug handling (types, frequency, and duration) [method NR] (4–27 years) | % cells with CA (lymphocytes) | Mann-Whitney U-test | Significantly higher % cells with CA compared to unexposed blood donors, but not to unexposed nurses and physicians; significantly higher % cells with CA in all medical personal compared to unexposed blood donors; exposure duration or smoking status NS
Sasaki et al. (2008) | Cross-sectional (Nurses, Japan, F) | 121 exposed (only 57 prepared and administered agents), 46 unexposed hospital clerks | Job title and self-reported questionnaire (≤6 months) | Tail length and tail moment (lymphocytes) | ANCOVA tested for influence of exposure, sex, age, smoking habits, occupation, exposure duration, and PPE; logarithmic-transformation because data were not normally distributed | Following log-transformation, significantly greater tail length in all 121 nurses and in the 57 actively exposed nurses compared to unexposed clerks; however, no difference in tail length of 64 nurses not actively exposed compared to unexposed clerks or the 57 exposed nurses; tail moment NS
Sessink et al. (1994a) | Cross-sectional (Nurses and pharmacy technicians, the Netherlands, F) | 17 exposed, 35 unexposed pharmacy technicians | Job title, [self-reported] questionnaire, and biomonitoring (7 years, range 4–14 years) Note: Most workers wore PPE; drugs were prepared in laminar down-flow hoods | % cells with CA (lymphocytes) | Two-way ANOVA evaluated exposure and smoking | No difference in % cells with CA compared to unexposed subject
| Cross-sectional (Nurses, laboratory technicians, cleaning staff, Czech Republic, FM) | 11 exposed, 23 unexposed physicians, nurses, lab technicians and a cleaning woman | Job title, [self-reported] questionnaire, and biomonitoring (13 years, range 3–25 years) Note: Most workers wore PPE; drugs were prepared in laminar down-flow hood | % cells with CA (lymphocytes) | Two-way ANOVA evaluated exposure and smoking | Significantly higher % cells with CA compared to unexposed workers; additive effects between exposure and smoking
Sorsa et al. (1988) | Cross-sectional (Drug manufacturing workers and laboratory technicians working with cyclophosphamide (CP), Finland, FM) | 36 exposed (13 manufacturing workers, 3 laboratory technicians), 20 unexposed (10 unexposed factory employees, 10 controls from outside the factory) | Job title, work tasks, use of PPE [method NR], and air monitoring (range 1.5–16 years based on subjects with MN data) Note: PPE and best available safety techniques were used; during the preparation of CP powder, manufacturing and production workers wore gas-protective suits | % cells with CA and no. of CA/100 cells (lymphocytes) | NR | No difference in % cells with CA or no. of CA between exposed subjects and controls
| Cross-sectional (Drug production and laboratory workers working with cyclophosphamide, Finland, FM) | 21 exposed (12 drug production workers, 9 laboratory workers), 11 unexposed factory employees | | % cells with CA and no. of CA/100 cells (lymphocytes) | NR | No difference in % cells with CA or no. of CA between exposed subjects and controls
| Cross-sectional (Same group of drug manufacturing and production workers working with cyclophosphamide, Finland, FM) | 19 exposed (7 process workers, 12 drug manufacturing workers), 7 unexposed factory employees | | No. of MN/1,000 cells (lymphocytes) | NR | No difference in the no. of MN compared to unexposed employees; significant correlation with age
Stücker et al. (1986) | Cross-sectional (Nurses in pneumology, France, F) | 16 exposed, 24 unexposed hospital staff from same department | Job title and [self-reported questionnaire] (3.5 years) Note: PPE not consistently used, no vertical laminar flow cabinet or isolated room for drug preparation was available | No. of CA/100 cells (lymphocytes) | Chi-squared test | No difference in no. of CA compared to unexposed hospital staff; correlation with age and adjustment for radiodiagnostic exposure NS; authors state that nurses had moderate exposure (11 perfusion per week)
Testa et al. (2007) | Cross-sectional (Nurses, Italy, FM) | 76 exposed, 72 unexposed blood donors | Job title and interviewer-led questionnaire (12.2 ± 7.7 years) Note: Exposed nurses were involved in preparation and administration of drugs; they used PPE (gloves, overalls, and goggles) and chemical and biohazard laminar flow [safety cabinets] | No. of CA/100 cells (lymphocytes) | Mann-Whitney U-test | Significantly higher no. of CA compared to unexposed blood donors
Thiringer et al. (1991) | Cross-sectional (Nurses, Sweden, FM) | 54 exposed nurses in Hematology and Oncology, 54 unexposed nurses | Job title and self-reported questionnaire (duration NR) Note: 91% of exposed nurses always used the safety hood; all but one nurse always used gloves; use of masks was less consistent | No. of MN/1,000 cells (lymphocytes) | Wilcoxon signed-rank test | No difference in the no. of MN compared to unexposed nurses
Thulin et al. (1995) | Cross-sectional (nor-Nitrogen mustard production workers, [Sweden], M) | 6 exposed, 6 unexposed office workers Exposed subjects were sampled before production, 1 and 2 weeks during production, and 4 weeks after end of production | Job title, PPE usage, and environmental monitoring (4 years) Note: Production unit was in a building adjacent to the office with free access between the two spaces; all workers wore PPE with personal fresh-air devices during production | No. of CA/100 cells (lymphocytes) | Student’s t-test and Wilcoxon’s test | No difference in no. of CA compared to unexposed controls at any sampling time; no. of CA in unexposed office workers were higher than concurrent unexposed subjects or historical unexposed data
Ündeğer et al. (1999) | Cross-sectional (Nurses, Turkey, FM) | 30 exposed, 30 unexposed nurses, secretaries, and technicians | Job title and self-reported questionnaire (range 0.5–13 years) Note: 26 exposed nurses used safety ventilation cabinets; 13 used gloves, masks, and gowns; 17 did not use gloves | DNA damage index (2.5 = <5%, 12.5 = 5–20%, 30 = >20–40%, 67.5 = >40–95%, 97.5 = >95%) | Student’s t-test; linear regression for effects of exposure duration | Significantly greater DNA damage index of >5% damage compared to unexposed subjects; no correlation with age, exposure duration; exposed nurses without safety equipment had significantly higher DNA damage index than those with safety equipment
Ursini et al. (2006) | Cross-sectional (Nurses and pharmacy technicians, Italy, FM) Note: Same population as Cavallo 2005 | 30 exposed (5 pharmacy technicians, 15 day nurses, 10 ward nurses), 30 unexposed administrative staff | Job title, self-reported questionnaire, biomonitoring, and environmental monitoring (6.2 ± 2.9 years, ward nurses; 7.0 ± 2.0 years, pharmacists; 8.1 ± 6.0 years, outpatient nurses) Note: Exposed personnel wore PPE, including gloves, caps, overalls, and goggles; specialized pharmacy prepared the doses | Tail moment (lymphocytes or buccal cells) | Student’s t-test; ANOVA to test effects of age and exposure duration | No difference in tail moment (in either cell population) compared to unexposed subjects
Villarini et al. (2011) | Cross-sectional (Pharmacy technicians, nurses, and nurses’ aides, Italy, FM) Note: Same population as Moretti 2013 | 52 exposed subjects involved in preparation, administration, transportation, and disposal, 52 unexposed public workers from same localities as exposed | Job title, interviewer-led questionnaire, biomonitoring, and environmental monitoring (<10 years, n = 13; 11–20 years, n = 14, and >20 years, n = 4) Note: Exposed workers involved in preparation, transportation, administration, and disposal of cancer chemotherapy agents | % Tail DNA and tail length (leukocytes) | Mann-Whitney U-test; sub-group analysis by Kruskal-Wallis H-test; multivariate regression analysis to examine effect of exposure status, gender, age, smoking, occupation, PPE, job seniority, and genetic polymorphisms | Significantly greater % tail DNA in exposed subjects; tail length NS; occupation was a significant covariate
Yager et al. (1988) | Cross-sectional (Chemical process workers, manufacturing workers, and nurses, Finland, FM) Note: Overlapping population with Sorsa 1988 | 27 exposed (7 chemical process workers, 12 manufacturing workers, and 8 oncology nurses), 9 unexposed subjects [no description provided] | Job title and work history [method NR] (range 2–25 years) | No. of MN/1,000 cells (lymphocytes) | ANOVA; log-transformation of data and adjustment for influence of age | ANOVA variables for exposure and age were significant); log-transformed data adjusted for age revealed significantly higher no. of MN compared to unexposed subjects
Yang et al. (2002a) | Cross-sectional (Nurses, China, [F]) Note: Same population as Yang 2002b | 16 exposed, 16 nursing students | Job title and drug handling (types and frequency) (5.6 years, range 1–16 years) | Tail length | [Mann-Whitney] U-test | Significantly greater tail length in exposed subjects than controls
Yang et al. (2002b) | Cross-sectional (Nurses, China, F) Note: Same population as Yang 2002a | 16 exposed, 16 nursing students | Job title and frequency of drug handling (5.5 years) | No. of CA/100 cells and no. of MN/1,000 cells (lymphocytes) | [Mann-Whitney U-test] | Significantly higher no. of CA and no. of MN compared to unexposed nursing students
Yin et al. (2010) | Cross-sectional (Oncology Nurses, China, F) | 30 exposed, 30 unexposed nurses | Job title, work tasks, drug handling, PPE usage [method NR] (9.8 ± 5.9 years) Note: PPE and biosafety cabinets were used during preparation of doses | % Tail DNA, tail length, and tail moment | Logarithmic-transformation followed by multiple linear regression | Significantly greater % tail DNA, tail length, and tail moment compared to unexposed nurses
Yoshida et al. (2006) | Cross-sectional (Nurses from hematology department, Japan, F) | 19 exposed nurses, 18 unexposed nurses from Department of Cardiovascular Disease | Job title and self-reported questionnaire (5.7 years, range 0.2–25.2 years) | Tail length (lymphocytes) | Mann-Whitney U-test | Significantly greater tail length compared to unexposed nurses; age and duration of exposure were significant variables

ANCOVA = analysis of covariance, ANOVA = analysis of variance, CA = chromosomal aberrations, CCI = cytotoxic contact index, CP = cyclophosphamide, DNA = deoxyribonucleic acid, F = female, IRR = incident rate ratios, M = male, MN = micronucleus or micronuclei, n or No. = number, NR = not reported, NS = not significant OR = odds ratio, PPE = personal protective equipment, USA = United States of America.