# Appendix E Inadequate Evidence: Evidence Synthesis and Risk-of-bias Assessment

## E.1 Acute Effects

The NTP evaluation identified nine cross-sectional studies reporting on acute health effects potentially associated with occupational exposure to cancer chemotherapy (Krstev et al. 2003; Medková 1991a; Rogers and Emmett 1987; Shahrasbi et al. 2014; Valanis et al. 1987; Valanis et al. 1993a; 1993b; Walusiak et al. 2003; Zhang et al. 2016). Acute effects are defined as health effects that develop rapidly, and these effects are often transient in nature and subside when the subject is no longer exposed. Given the wide range of symptoms that could be included under this category, there was a high degree of heterogeneity in type of effects reported, which limited the ability to compare across studies.

Summary: Based on the available studies, there is very low confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with the incidence of acute effects (Table E-1). There was a high degree of heterogeneity in the outcome assessment (i.e., symptoms evaluated), which resulted in few effects evaluated across all studies and the studies that evaluated related endpoints as a group reported mixed evidence of potential effects. For example, fewer than half of the studies that examined dermatological endpoints (e.g., skin rash, skin irritation or eczema) were significantly higher in exposed subjects versus controls (three of eight studies). Other examples of acute effects included significantly higher rates of hair loss reported in five of eight studies and significantly greater incidence of headache reported in four of six studies in exposed subjects relative to controls. The final rating of very low confidence in the body of evidence reflects downgrading for serious risk-of-bias concerns across multiple key risk-of-bias questions (e.g., majority of studies were rated probably high risk of bias for confounding, exposure characterization, and outcome assessment) (Figure E-1 and Figure E-2).

Table E-1 Studies Reporting on Acute Effects

Study | Study Design (Population, Location, Year Data Collected, Sex) | No. of Participants | Exposure Measure | Outcome Assessment | Analysis | Results
Krstev et al. (2003) | Cross-sectional (Nurses in 8 hospitals, Serbia, year NR, F) | 186 exposed, 77 unexposed | Job title and self-reported questionnaire; head nurses reported on work practice and work conditions Note: One hospital had a vertical laminar [flow] biological safety cabinet, and some concerns about its maintenance; none of the hospitals had a separate room for drug preparation; gloves were used by 81.7% of exposed nurses for drug preparation and by 60.1% for drug administration | Self-reported questionnaire | 2x2 table statistics used to compute relative risk (RR); unconditional logistic regression analysis used to adjust for confounders: age (≤35 and ≥36 years old), smoking status (smokers versus non-smokers and ex-smokers), and shift work (daily shift vs. rotating shift with night work) | Prevalence of several symptoms assessed: (*significantly higher OR compared to unexposed after adjustment for age, smoking and shiftwork) Hair loss*, skin rash*, eczema*, skin flush*, light headedness*, nausea*, dizziness*, vomiting, eye irritation, diarrhea, nasal congestion and runny nose, headache, insomnia, menstrual dysfunction, disappearance of symptoms during the weekend*, mean number of symptoms overall* and by frequency of exposure (daily ≥ weekly > monthly)*
Medková (1991a) | Cross-sectional (Physicians, nurses, auxiliary workers, Czech Republic, FM) | 44 exposed, 32 unexposed partners of exposed subjects | Job title and interviewer-led questionnaire (≥5 years, n = 25; 6–10 years, n = 14; 11–15 years, n = 4; and 16–20 years, n = 1) Note: All exposed personnel used gloves and gowns; isolated room for drug preparation only used by 25% of exposed subjects | Interviewer-led questionnaire | NR | No difference in prevalence of dermatological afflictions (including eczema) compared to unexposed subjects
Rogers and Emmett (1987) | Cross-sectional (Nurses in Oncology Nursing Society, United States, year NR, F) | 59 exposed, 64 unexposed community health nurses | Job title and interviewer-led questionnaire Note: Percent of nurses using PPE all the time was: 5% for masks, 8% for gowns, 20% for gloves; laminar flow hoods were not used | Interviewer-led questionnaire | [Chi-squared test] | Prevalence of 21 symptoms was assessed, but authors did not report on all the outcomes; significantly higher prevalence (p ≤ 0.02) of abdominal pain, hair loss, and headaches on a daily or weekly basis compared to unexposed; skin rash tended (p = 0.06) to be more frequently reported compared to unexposed nurses
Shahrasbi et al. (2014) | Cross-sectional (Nurses at 9 professional and specialized cancer hospitals, Iran, year NR, FM) | 225 exposed nurses, unexposed nurses from non-oncology wards [number NR] | Job title and self-reported questionnaire Note: Exposed nurses were working for ≥6 months in oncology ward; they used vertical flow laminar flow biological safety cabinets; PPE was available but not regularly used | Self-reported, validated questionnaire | NR | Prevalence of several symptoms assessed: (*significantly higher compared to unexposed nurses) hair loss*, irritation of mucous membranes, eye irritation, skin irritation*, dizziness, headache, nausea and vomiting*
Valanis et al. (1987) | Cross-sectional (Hospital nurses, United States, 1982–1984, sex NR) | 134 exposed: 51 prepared and administered the drugs, 39 only administered the drugs, and 44 handled patient excreta; 43 unexposed nurses | Job title and self-reported, validated questionnaire (duration NR) Note: 65% of exposed nurses used gloves during drug preparation and 45% during administration of drugs; skin contact occurred on at least half of drug-handling events for 18% of exposed nurses during drug preparation and 25% during administration of drugs; gowns, goggles and masks were rarely used | Self-reported questionnaire | Chi-square test for prevalence of individual acute symptoms; ANOVA or t-test, as appropriate, for mean number of symptoms or total symptoms of acute symptoms grouped into one of 5 body systems | Prevalence of 27 acute effects experienced in past 3 months: (*significantly higher compared to unexposed nurses) Cardiac related: shortness of breath, irregular heartbeat, swelling, elevated blood pressure, chest pain; Infection related*: chronic cough*, sore throat*, throat/sinus irritation, viral/other infection*; Gastrointestinal*: nausea and vomiting*, diarrhea, severe constipation, colicky abdomen, abdominal pain; General systemic*: dizziness*, headache*, insomnia, pain on urination, hair loss, nail hyperpigmentation; Allergic*: allergic reactions, dermatitis, eye irritation*; Miscellaneous: fainting, anorexia, back pain, other pain; significantly higher mean total symptoms for high exposure and lack of glove use compared to unexposed nurses
Valanis et al. (1993a) | Cross-sectional (Nurses and nurse aides in National Surgical Adjuvant Breast and Bowel Project (NSABP), USA, 1988–1990, F) | 1,346 exposed (283 skin contact, 1,063 no skin contact), 738 unexposed | Job title and self-reported, validated questionnaire (duration NR) Note: 92% of exposed nurses used gloves: during drug preparation, 82% during administration of drugs, 89% while cleaning up spills, and 75% when handling patient excreta; masks and goggles primarily during drug preparation; gowns worn only during drug preparation and cleaning up spills | Self-reported questionnaire, effects observed during the preceding 3 months | Multiple linear regression for total number of symptoms analyzed effects of dose, duration, use of protection, and skin exposure and factors of age, smoking status, stress at work, and body mass index; likelihood ratio tests compared the goodness of fit of competing models, and large sample maximum likelihood theory computed confidence limits and p-values for specific parameter estimates; logistic regression modelled the effects of exposure and control variables | Prevalence of 27 acute effects experienced in past 3 months: (*significantly higher compared to unexposed subjects) Cardiac: shortness of breath, irregular heartbeat, swelling of hands and feet, chest pain, elevated blood pressure; Infectious: chronic cough, chronic throat irritation, cough when lying down, fever; Gastrointestinal: loss of appetite, nausea, vomiting, diarrhea, colicky abdomen, constipation; General systemic: hair loss, nail hyperpigmentation, pain on urination, decreased libido, malaise; Allergic: allergic reactions, eye irritation, rash; Neurological: headache, dizziness, fainting, insomnia; no difference in the prevalence of acute effects compared to unexposed subjects; however exposed, nurses with skin exposure tended (p = 0.07) to have more acute effects in every category than exposed nurses without skin exposure, except neurological symptoms
Valanis et al. (1993b) | Cross-sectional (Pharmacists and pharmacy technicians in NSABP, USA, 1988–1990, FM) | 533 exposed, 205 unexposed | Job title and self-reported, validated questionnaire (duration NR) Note: Exposed pharmacy personnel used gloves at least 75% of the time when handling drugs | Self-reported questionnaire, effects observed during the preceding 3 months | Same analysis as Valanis 1993a | Prevalence of 27 acute effects experienced in past 3 months same as Valanis 1993a: significantly higher prevalence of chronic throat irritation* and diarrhea* compared to unexposed; skin contact with cancer chemotherapy agents was a significant factor for mean total symptoms or organ system subgroups
Walusiak et al. (2003) | Cross-sectional (Physicians, nurses, orderlies, year NR, Poland, FM) | 103 exposed, 104 unexposed | Job title and self-reported questionnaire (11.0 ± 9.3 years) | Self-reported questionnaire | Mann-Whitney U-test | Prevalence the following acute effects: (*significantly higher compared to unexposed subjects) accelerated hair loss*, changes in the fingernails (fragility, brittleness, wrinkling), dermal changes (bleed/bruising tendency), digestive tract bleeding, and skin symptoms (allergic or other etiology)
Zhang et al. (2016) | Cross-sectional (Nurses, China, 2011 pre-pharmacy intravenous admixture service (pre-PIVAS) and 2013 (post-PIVAS) in Hospital A, F) | Pre-PIVAS: 176 unexposed, 46 exposed non-oncology, 123 exposed oncology; post-PIVAS: 182 unexposed, 55 exposed non-oncology, 148 exposed oncology, and 190 exposed oncology nurses at Hospital B) | Job title and self-reported questionnaire (≥2 years in current job) | Self-reported questionnaire | [Student] t-test, Chi-square, and Wilcoxon [signed-rank sum] test | Significantly higher (p < 0.01) prevalence of severe hair loss and oral ulcers compared to unexposed nurses in pre- and post-PIVAS studies; however, the post-PIVAS prevalence of these two acute effects were significantly lower than pre-PIVAS values (p < 0.05); however, the post-PIVAS prevalence of oral ulcers was significantly higher than Hospital B without PIVAS

F = female, M = male, NR = not reported, NS = not significant, NSABP = National Surgical Adjuvant Breast and Bowel Project, OR = odds ratio, PIVAS = pharmacy intravenous admixture service.

Figure E-1

Risk-of-bias Bar Graph for Studies Reporting on Acute Effects Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure E-2

Risk-of-bias Heat Map for Studies Reporting on Acute Effects Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

## E.2 Cancer

NTP identified three studies reporting on cancer incidence (Gunnarsdóttir et al. 1997; Ratner et al. 2010; Skov et al. 1992). The confidence rating on the body of evidence were based on studies reporting on the cancers most commonly associated with exposure to cancer chemotherapy agents in patients administered the drugs for treatment of cancer: leukemia and/or lymphoma (Cogliano et al. 2011; Mistry et al. 2005; Pedersen-Bjergaard 2005; Pedersen-Bjergaard et al. 2002) as well as urinary bladder (chlornaphazine, cyclophosphamide), lung (MOPP: vincristine-prednisone-nitrogen mustard-procarbazine combination therapy), and skin (azathioprine, nitrogen mustard) (Cogliano et al. 2011). In addition, an elevated risk of breast cancer has been observed in women working as nurses (Gunnarsdóttir and Rafnsson 1995; Lie et al. 2007).

Summary: Based on the available studies, there is very low confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with cancer. There were very few studies of any one cancer site (Table E-2). For example, only one of two retrospective cohort studies of reporting on leukemia observed a significant association in nurses handling and administering cancer chemotherapy agents (Skov et al. 1992). Also, for some cancers, there were data reporting a lack of effect of exposure from study designs with lower initial confidence ratings (e.g., retrospective cohort studies), which limited the ability to reach level-of-evidence conclusions (e.g., Hodgkin lymphoma) (Ratner et al. 2010; Skov et al. 1992). The final rating of very low confidence in the body of evidence for other cancers reflects downgrading for serious risk-of-bias concerns across multiple key risk-of-bias questions (e.g., majority of studies were rated probably high risk of bias for confounding and exposure characterization) and only one to two available studies per each cancer type (Figure E-3 and Figure E-4).

Table E-2 Studies Reporting on Incidence of Cancer

Study | Study Design (Occupation, Location, Year Data Collected, Sex) | No. of Participants | Exposure Measure | Outcome Measured | Analysis | Results
Gunnarsdóttir et al. (1997) | Nested case-control in a cohort of nurses (Nurses, Iceland, 1955–1979, F) | 55 cases and 116 referents [number exposed to cancer chemotherapy agents NR] | National occupational records for Icelandic nurses; telephone-interviews with subjects or next of kin for deceased subjects | National cancer registry | Odds ratio adjusted for year of birth, breast cancer in first-degree relative, marital status, and nulliparity | No significant association for breast cancer (adjOR = 1.65, 95% CI = 0.53–5.17, 7 exposed cases) compared to unexposed
Ratner et al. (2010) | Cohort, retrospective (Female registered nurses from British Columbia, Canada, 1974–2000, F) Note: Subjects followed until 2000 | 56,213 nurses in cohort: 905 exposed (Method 1, ever working in oncology or a cancer center) or 7,635 exposed ≥15 days (Method 2, weighted duration of exposure) | Two exposure measures: Method 1: Years employed in oncology or at a cancer center (never, <5 years, ≥5 years, or ever) and Method 2: weighted duration of exposure based on job responsibilities (<15 days, ≥15 to 60 days, and >60 days, or ≥15 days; 15 days equivalent to 1 year of work in a job likely not exposed and 60 days equivalent to 1 year of work in job likely exposed to cancer chemotherapy agents) | Incidence of any cancer (combined and individual types); cases identified in the Canadian cancer registry | Poisson regression; adjusted for calendar year and age; lag of 10 years applied for cancer incidence; cancers with 3 or fewer cancers were not statistically analyzed | For Method 1, increased risk for breast cancer (aRR = 1.83; 95% CI = 1.03–3.23, 12 exposed cases) compared to never exposed and no exposed cases of leukemia, and all other cancers had >3 exposed cases for Method 1. For Method 2, there was a significant association with rectal cancer (aRR = 1.87, 95% CI 1.07–3.29, 14 exposed cases) compared to exposed <15 days, less than 3 exposed cases of Hodgkin lymphoma (HL), and no association for non-Hodgkin lymphoma (NHL) (aRR = 0.91, 95% CI = 0.42–1.96, 7 exposed cases), leukemia (aRR = 0.89, 95% CI = 0.27–2.88 3 exposed cases), bladder cancer (aRR = 1.67, 95% CI = 0.76–3.67, 7 exposed cases), lung cancer (aRR = 1.22, 95% CI = 0.65–1.94, 14 exposed cases) and melanoma (aRR = 1.28, 95% CI = 0.75–2.18, 15 exposed cases) compared to <15 days exposure
Skov et al. (1992) | Cohort, retrospective (Nurses, Denmark, 1973–1987, F) Note: Follow-up until 1987 | 1,282 exposed; referents were Danish national cancer rates | Employment records of 5 oncology hospitals, and data from head nurses regarding drug handling and administration of individual subjects | Medical records (Danish Cancer Registry); incidence of any cancer (combined), leukemia, Hodgkin lymphoma, non-Hodgkin lymphoma, multiple myeloma, mycosis fungoides | Standard incidence ratios | Significant association for leukemia (RR = 10.65, 95% CI = 1.29–38.5, 2 exposed cases), but not HL (RR = 8.35, 95% CI = 0.21–46.5, 1 exposed case) compared to the standard incidence ratio; one exposed nurses had both leukemia and JL was counted as 2 exposed cases

aRR = adjusted relative risk, CI = confidence interval, F = female, HL = Hodgkin lymphoma, M = male, NHL = non-Hodgkin lymphoma, No. = number, RR = relative risk.

^a^ In Method 2 of Ratner et al. (2010), 15 days is equivalent to 1 year of work in a position not likely to be exposed and 60 days is equivalent to full time work in a position likely to be exposed.

Figure E-3

Risk-of-bias Bar Graph for Studies Reporting on Cancer Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure E-4

Risk-of-bias Heat Map for Studies Reporting on Cancer Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

## E.3 Immune Toxicity

The NTP evaluation identified 11 cross-sectional studies reporting effects on the immune system (Biró et al. 2011; Bolognesi et al. 2005; Caciari et al. 2012; Jeebhay et al. 1993; Jochimsen et al. 1988; Li et al. 2005; Medková 1991a; Spatari et al. 2005; Valanis et al. 1987; Walusiak et al. 2003; Zhang et al. 2016). The effects included any immune-related diseases (e.g., asthma, auto-immune disease). Alterations in immune-related parameters were also reviewed, including but not limited to: white blood cell differential count, oxidative burst potential, cytokine levels, and natural killer cell function.

Summary: Based on the available studies, there is very low confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with higher incidence of immune-related diseases or alterations of immune-related parameters. The ability to compare among studies was limited due to heterogeneity in the outcomes assessed. For example, only one study reported on an immune-related disease (asthma) and most of the studies investigating possible alterations of immune-related parameters did not measure similar endpoints (Table E-3). Of the few studies that measured a similar endpoint, there were inconsistent results (e.g., only one of five studies measuring white blood cell counts reported significantly lower counts in exposed subjects versus controls). The final rating of very low confidence in the body of evidence confidence reflects downgrading for serious risk-of-bias concerns across multiple key risk-of-bias questions (e.g., majority of studies were rated probably high risk of bias for confounding), heterogeneity in the outcomes measured, and inconsistencies in the outcomes reported (Figure E-5 and Figure E-6).

Table E-3 Studies Reporting on Immune System Toxicity

Study | Study Design (Population, Location, Year Data Collected, Sex) | No. of Participants | Exposure Characterization (Duration) | Outcome Assessment | Analysis | Results (Outcomes Measured in Bold)
Biró et al. (2011) | Cross-sectional (Nurses, Hungary, year NR, sex NR) | 308 exposed, 98 unexposed | Job title and interviewer-led questionnaire (9.0 ± 0.5 years) | Medical tests conducted using flow cytometry | Student’s t-test | Significantly (p < 0.05) higher % of B cells, and significantly (p < 0.05) decreased CD25+/CD4+ activated T cells compared to unexposed subjects; ratio of T cells, cytotoxic T cells (Tc), helper T cells (Th), NK (natural killer) cells, and Th/Tc were NS
Bolognesi et al. (2005) | Cross-sectional (Nurses, IMPEA project, Italy, year NR, FM) | 50 exposed, 48 unexposed | Job title, [self-reported] questionnaire, and biomonitoring (10.2 years) Note: Nurses assigned to preparation and administration of agents; adequate safety equipment and PPE were used | Medical tests conducted using flow cytometry | Mann-Whitney U-test | No difference in % NK cells, peripheral lymphomonocytes, regulatory T cell (CD25), and IL-6 compared to unexposed subjects
Caciari et al. (2012) | Cross-sectional (Healthcare workers (doctors, nurses, social and health assistants), Italy, year NR, FM) | 57 exposed, 57 unexposed | Job title only (duration NR) | Medical tests | Student t-test, Chi-square analysis | Significantly lower levels of monocytes (possible myelosuppression) compared to unexposed subjects; red blood cell populations or other white blood cell type counts NS
Jeebhay et al. (1993) | Cross-sectional (Pharmaceutical plant workers, South Africa, year NR, M) | 6 exposed to azathioprine, 17 unexposed | Job title and [self-reported] questionnaire, biomonitoring, and environmental monitoring Note: Exposed workers in 2-week production campaign: measured at baseline, day 3, end, and 3 months after end | Medical tests conducted by a commercial laboratory | ANOVA | Significantly fewer reticulocytes at the end of the production run, and significantly fewer neutrophils at 3 months following the production run compared to unexposed subjects; number of platelets or white blood cell count NS
Jochimsen et al. (1988) | Cross-sectional (Nurses, USA, year NR, sex NR) | 18 exposed, 18 unexposed | Job title, work task, drug handling, and PPE usage [method NR] (4.5 years, range 1–10 years) Note: PPE not regularly used and no hoods or vapor barriers were used | Medical tests conducted using flow cytometry | Student’s t-test | Trend, though NS, of lower neutrophil, monocytes, platelet counts, and neutrophil reserve compared to unexposed nurses
Li et al. (2005) | Cross-sectional (Nurses, China, years NR, F) | 30 exposed, 30 unexposed | Job title, drug handling, and PPE usage [method NR] (14 years) Note: Exposed nurses handled these agents ≥5 years at minimum 5 times per day without taking protective measures | Medical tests conducted using flow cytometry | t-test | Significantly fewer helper T cells (CD4+) in exposed versus control nurses; other T lymphocyte cell types (CD8+, CD4+/CD8+, CD3) or NK cells NS
Medková (1991a) | Cross-sectional (Nurses, physicians, cleaning staff, Czech Republic, years NR, FM) | 44 exposed, 32 unexposed partners of exposed subjects | Job title and interviewer-led questionnaire (≥5 years, n = 25; 6–10 years, n = 14; 11–15 years, n = 4; and 16–20 years, n = 1) Note: All exposed personnel used gloves and gowns; isolated room for drug preparation only used by 25% of exposed subjects | Interviewer-led questionnaire | NR | Higher incidence of allergy including bronchial asthma in exposed nurses versus controls, but statistical significance unknown
Spatari et al. (2005) | Cross-sectional (Healthcare workers, Italy, years NR, FM) | 17 exposed, 17 unexposed | Job title only (13.25 ± 8.16 years) | Elisa kit | One-way ANOVA, Student-Newman Keuls test | Significantly higher interleukin-15 levels in exposed relative to control subjects
Valanis et al. (1987) | Cross-sectional (Pharmacists and pharmacy technicians in NSABP, USA, 1988–1990, FM) | 21 exposed, 13 unexposed | Job title and self-reported, validated questionnaire (duration NR) Note: 65% of exposed nurses used gloves during drug preparation and 45% during administration of drugs; skin contact occurred on at least half of drug-handling events for 18% of exposed nurses and 25% of nurses during administration of drugs; gowns, goggles and masks were rarely used | Medical tests conducted in single laboratory by technician blind to exposure group | Chi-squared test | Similar total white cell counts between control and exposed subjects; however, an analysis of subgroups of white cell counts (<5,600, 5,600–7,000, >7,000) revealed that significantly more exposed nurses had white blood cell counts of <1,500 cells than control nurses
Walusiak et al. (2003) | Cross-sectional (Nurses, physicians, orderlies, year NR, Poland, FM) | 104 exposed, 103 unexposed | Job title and self-reported questionnaire (11.0 ± 9.3 years, range 5–44 years) | Medical tests | Mann-Whitney U-test | Similar values between exposed and control subjects for all immune and hematopoietic parameters measured including: white blood cell count, red blood cells count and platelet count
Zhang et al. (2016) | Cross-sectional (Nurses, China, 2011 pre-PIVAS and 2013 (post-PIVAS) in Hospital A, F) | Pre-PIVAS: 88 unexposed, 33 exposed non-oncology, 101 exposed oncology; post-PIVAS: 55 unexposed, 25 exposed non-oncology, 85 exposed oncology, and 144 exposed oncology nurses at Hospital B) | Job title and self-reported questionnaire (≥2 years in current job) Note: All exposed nurses involved in mixing and/or administration of cancer chemotherapy agents | Medical tests | t-test, Chi-square, and Wilcoxon | Significantly lower mean white blood cell counts in oncology nurses compared to controls prior to the implementation of a PIVAS; after implementation of PIVAS, the white blood cell counts were similar between the two groups in the same hospital. The number of white blood cell counts, platelets, and red blood cells counts were higher in controls and oncology numbers after PIVAS implementation than before. Finally, oncology nurses in a second hospital (Hospital B) without PIVAS had significantly lower numbers of white bloods cells, platelets, and red blood cells compared to the oncology nurses post-PIVAS at Hospital A

adjOR = adjusted odds ratio, CD = cluster of differentiation, F = female, M = male, NK = natural killer cells, NR = not reported, NS = not significant, NSABP = National Surgical Adjuvant Breast and Bowel Project, OR = odds ratio, PIVAS = pharmacy intravenous admixture service, Tc = cytotoxic T cells, Th = helper T cells, TNF alpha = tumor necrosis factor alpha.

Figure E-5

Risk-of-bias Bar Graph for Studies Reporting on Immune System Effects Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure E-6

Risk-of-bias Heat Map for Studies Reporting on Immune System Effects Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

## E.4 Kidney, Liver, and Cardiovascular System Toxicity

The NTP evaluation identified six cross-sectional studies total that reported on kidney toxicity (five studies), liver toxicity (four studies), and cardiovascular system toxicity (two studies) (Caciari et al. 2012; Medková 1991a; Sessink et al. 1997a; Tigha Bouaziz et al. 2016; Walusiak et al. 2003; Zhang et al. 2016). The type of data available varied from biochemical measurements (e.g., secondary health outcomes) and the incidence of morbidity, which limited the ability to compare among studies.

Summary: Based on the available studies, there is very low confidence in the body of evidence that occupational exposure to cancer chemotherapy agents is associated with kidney, liver, or cardiovascular toxicity. There were very few studies per health outcome, which resulted in few effects evaluated across all studies (Table E-4). Another challenge was the lack of description provided for morbidity provided by the authors of one study (Medková 1991a). Of the four studies reporting on kidney toxicity, one study reported a higher rate of renal disease without further description and one of three studies reporting biochemical measurements reported a higher incidence of alterations in exposed subjects versus controls. In another example, one of two studies reported cardiovascular system toxicity. The final rating of very low confidence in the body of evidence reflects downgrading for serious risk-of-bias concerns across multiple key risk-of-bias questions (e.g., majority of studies were rated probably high risk of bias for confounding and exposure characterization) (Figure E-7 and Figure E-8).

Table E-4 Studies Reporting on Kidney, Liver, or Cardiovascular System Toxicity

Study | Study Design (Occupation, Location, Years Data Collected, Sex) | No. of Participants | Exposure Measure | Outcome Assessment | Analysis | Results (Outcomes Measured in Bold)
Caciari et al. (2012) | Cross-sectional (Healthcare workers (doctors, nurses, social and health assistants), Italy, year NR, FM) | 57 exposed, 57 unexposed | Job title only (duration NR) | Medical tests | Student t-test, Chi-square analysis | Significantly higher levels of bilirubin (possible indication of liver damage) compared to unexposed subjects; alanine or aspartate aminotransferase, alkaline phosphatase (measures of liver function) NS; blood urea nitrogen or creatinine (measures of kidney function) NS
Medková (1991a) | Cross-sectional (Physicians, nurses, auxiliary workers, Czech Republic, year NR, FM) | 44 exposed, 32 unexposed partners of exposed subjects | Job title and interviewer-led questionnaire (≥5 years, n = 25; 6–10 years, n = 14; 11–15 years, n = 4; and 16–20 years, n = 1) Note: Exposed personnel used gloves and gowns; isolated room for drug preparation only used by 25% of exposed subjects | Interviewer-led questionnaire | NR | Higher occurrence of renal disease and liver disease in compared to unexposed subjects, but statistics were not provided; no difference in occurrence of cardiovascular morbidity (described as diseases of the heart and circulation) or hypertension
Sessink et al. (1997a) | Cross-sectional (Nurses, lab technician, and cleaning staff, t-test, year NR, FM) | 11 exposed; 23 unexposed nurses, doctors, lab technicians and a cleaning woman | Job title and [self-reported] questionnaire (13, range 3–25 years) Note: Most exposed personnel used PPE; laminar down-flow cabinets used for drug preparation | Medical test | Student’s t-test, Pearson’s correlation of log-transformed data | No difference in renal function as measured by urinary albumin and urinary retinol-binding protein levels
Tigha Bouaziz et al. (2016) | Cross-sectional (Nurses, Algeria, year NR, FM) | 215 unexposed, 74 exposed | Job title and [self-reported] questionnaire (18.04 ± 11.11 years) | Medical tests | t-, z-, and Chi-squared tests, ANOVA, and logistic regression to adjust for age, sex, work shift, and other variables | Significantly higher occurrence cardiovascular morbidity associated with oncology nursing experience and higher cytostatic contact index levels (OR = 2.7, 95% CI = 1.26–6.04); significantly higher levels of creatinine, cholesterol, and triglycerides compared to unexposed nurses
Walusiak et al. (2003) | Cross-sectional (Physicians, nurses, orderlies, year NR, Poland, F) | 104 exposed, 103 unexposed | Job title and self-reported questionnaire (11.0 ± 9.3 years) | Self-report questionnaire | Mann-Whitney U-test | No difference in biochemical measures of liver function (aspartate and alanine transaminases, bilirubin, glutamyltransferase) or kidney function (creatinine, urea)
Zhang et al. (2016) | Cross-sectional (Nurses, China, 2011 pre-PIVAS and 2013 (post-PIVAS) in Hospital A, F) | Pre-PIVAS: 138 unexposed, 39 exposed non-oncology, 118 exposed oncology; Post-PIVAS: 185 unexposed, 55 exposed non-oncology, 137 exposed oncology, and 163 exposed oncology nurses at Hospital B) | Job title and self-reported questionnaire (≥2 years in current job) | Self-report questionnaire | [Student] t-test, Chi-square, and Wilcoxon for outcomes [authors did not specify which method] | Significantly (p < 0.05) altered levels of biochemical measurements of liver function (alanine transaminase, serum aspartate transaminase) and kidney function (creatinine, blood urea nitrogen) compared to unexposed nurses in Hospital A regardless of PIVAS implementation

ANOVA = analysis of variance, CI = confidence interval, F = female, M = male, No. = number, NR = not reported, NS = not significant, OR = odds ratio, PIVAS = pharmacy intravenous admixture service.

Figure E-7

Risk-of-bias Bar Graph for Studies Reporting on Kidney, Liver, or Cardiovascular System Toxicity Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure E-8

Risk-of-bias Heat Map for Studies Reporting on Kidney, Liver, or Cardiovascular System Toxicity Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

## E.5 Reproductive Toxicity, Other Than Spontaneous Abortion

In addition to spontaneous abortion, the NTP evaluation identified 24 studies of 19 unique populations reporting on reproductive and developmental toxicity, including pregnancy outcomes and female reproductive function (Bouyer et al. 1998; Elshamy et al. 2010; Fransman et al. 2007c; Hemminki et al. 1985; Krstev et al. 2003; Lawson et al. 2009; Lorente et al. 2000; McAbee et al. 1993; McDonald et al. 1988a; 1988b; Medková 1991a; Peelen et al. 1999; Ratner et al. 2010; Saurel-Cubizolles et al. 1993; Schaumburg and Olsen 1989; 1990a; 1991; Shortridge et al. 1995; Skov et al. 1992; Stücker et al. 1993; Valanis et al. 1997; Valanis et al. 1999; Walusiak et al. 2003; Zhang et al. 2016). The pregnancy outcomes included endpoints such as congenital malformations (12 studies), stillbirth (seven studies), preterm birth (seven studies), low birth weight or small for gestational age (eight studies), and ectopic pregnancy (three studies). Other studies reported on reproductive function, including time to pregnancy (three studies), infertility (three studies), and menstrual irregularities (three studies).

Summary: Based on the available data, there is very low confidence in the body of evidence that occupational exposure to cancer chemotherapy agents during pregnancy is associated with reproductive and developmental toxicity for endpoints other than spontaneous abortion.

Very few exposed cases were observed for some endpoints (e.g., congenital malformations), while there were very few studies were available for other endpoints (e.g., infertility) (Table E-5). There were 12 studies (of 11 unique populations) available that evaluated congenital malformations, including 11 studies evaluating any malformation (Elshamy et al. 2010; Fransman et al. 2007c; Hemminki et al. 1985; McAbee et al. 1993; McDonald et al. 1988a; Medková 1991a; Peelen et al. 1999; Ratner et al. 2010; Schaumburg and Olsen 1990a; Skov et al. 1992; Walusiak et al. 2003) and one study specifically evaluating oral clefts (Lorente et al. 2000). However, the results were inconsistent between studies with six of nine studies (one case-control study and five cross-sectional studies) reporting significantly higher rates of congenital malformations from exposed pregnancies, while three retrospective cohort studies, two with a larger number of exposed pregnancies, did not observe a significant increase. Only three studies limited the exposure characterization to the first trimester, and the results remained inconsistent when considering only the highest quality studies. Stillbirth did not appear to be associated with occupational exposure to cancer chemotherapy based on five available studies (one retrospective cohort study and six cross-sectional studies; six unique populations). However, the level of evidence for no effect conclusion requires a final rating of high confidence in the body of evidence (Rooney et al. 2014) and these studies did not achieve higher than a moderate confidence in the body of literature based on their study design. The final rating of very low confidence in the body of evidence for the reproductive and developmental toxicity effects, other than spontaneous abortion, reflected downgrading for inconsistency in the results for congenital malformations. No downgrading or upgrading for key risk-of-bias questions were identified for the other non-spontaneous abortion endpoints and few available studies were available for some endpoints, which also led to a final rating of very low confidence (Figure E-9 and Figure E-10).

Table E-5 Studies Reporting on Reproductive and Developmental Toxicity, Other Than Spontaneous Abortions

Study | Study Design (Occupation, Location, Years Data Collected, Sex) | No. of Participants, Pregnancies, or Infants, as Noted | Exposure Measure | Outcome Assessment | Analysis | Results (Outcomes Measured in Bold)
Bouyer et al. (1998) | Case-control (Hospital personnel, France, 1995, F) Note: Follow-up study to Saurel-Cubizolles 1993 | 140 cases, 279 control pregnancies (exposure to cancer chemotherapy: 37 pregnancies with past exposure and 43 with exposure in 3 months prior to conception) | Self-reported questionnaire on past and present occupational exposure to cancer chemotherapy agents, solvents, disinfectants, anesthetic agents, and ionizing radiation Note: Authors excluded subjects self-reporting to be seldom exposed or using a protective device | NR [presumably medical records] | Multivariate analysis using unconditional logistic regression | No association with ectopic pregnancy and past exposure (adjOR = 1.56, 95% CI = 0.65–3.72, 15 exposed cases) or 3-month prior exposure (adjOR = 0.95, 95% CI = 0.39–2.31, 10 exposed cases) compared to controls
Elshamy et al. (2010) | Cross-sectional (Nurses, Egypt, 2006, F) | 35 exposed, 29 unexposed | Job title, length of employment, self-administered questionnaire about drug handling, frequency of handling, number of accidents with cancer chemotherapy in past year, personal protective equipment usage, and level of training. Note: Only 42.9% of nurses reported using gloves when handling patient waste, and 45.7% of nurses admitted to eating in the drug preparation area | Self-reported questionnaire; no definitions were provided | Chi-square test with continuity correction, if indicated | Significantly higher (p<0.05) percentage of exposed than unexposed nurses experienced infertility/subfertility (11.4% vs. 3.4%), premature labor (11.4% vs. 3.4%), fetal loss [presumed stillbirth] (8.6% vs. 3.4%), congenital malformations (8.6 vs. 3.4), and developmental and behavioral abnormalities of offspring (5.7% vs. 0%), and higher but NS menstrual changes and low birth weight
Fransman et al. (2007c) | Cross-sectional (Nurses, the Netherlands, 1990–1997, F) Note: Same data as Peelen 1997 | Exposed pregnancies: 279 background, 146 low, 145 medium, 134 high; 555 unexposed pregnancies | Estimated dermal exposure based on job title, self-reported questionnaire, and glove usage in first trimester of pregnancy (or during time trying to get pregnant), combined with data on CP glove contamination conducted in 1996–1997 and glove and hand contamination in 2003–2007; categorized as: unexposed, background, low (≤0.20 μg CP/wk), medium (>0.20–0.74 μg CP/wk) or high exposure (>0.74 μg CP/wk) | Self-reported questionnaire | Logistic regression analysis; adjusted a prior for age at conception, parity, smoking, alcohol consumption, coffee intake during 1st trimester of pregnancy, vitamin/folic acid use during pregnancy as well as work factors (e.g., co-exposures during 1st trimester) | Significantly longer time to pregnancy in highly exposed nurses compared to unexposed nurses (aHR = 0.8, 95% CI = 0.6–0.9) and there was a log-linear increase in low birth weight per unit exposure (OR = 1.11, 95% CI = 1.01–1.21) and premature birth per unit exposure (OR = 1.08, 95% CI = 1.00–1.17); data on stillbirth; congenital anomalies, and alterations in sex ratio (% boys) NS
Hemminki et al. (1985) | Case-control (Nurses, 1973-1979, Finland, F) | 38 cases and 99 normal infants (16 pregnancies exposed to cancer chemotherapy agents) | Central Registry of Health Care Personnel and a questionnaire to head nurses regarding each subjects’ occupational exposures, including anesthetic gases, sterilizing agents, disinfectants, cancer chemotherapy drugs, and x-ray radiation, shift work and telephone duty Note: Exposed nurses were from non-oncology departments where exposure was relatively uncommon | Medical records | Odds ratios and logistic model of conditional likelihood function adjusted for shift work and co-exposures (e.g., ionizing radiation) | Significantly higher odds of congenital malformations compared to unexposed pregnancies (adjOR = 4.7, 95% CI = 1.2–18.1, 8 cases)
Krstev et al. (2003) | Cross-sectional (Nurses in 8 hospitals, Serbia, year NR, F) | 186 exposed, 77 unexposed | Job title and self-reported questionnaire; head nurses reported on work practice and work conditions Note: 60.1 to 81.7% of exposed nurses used gloves for drug administration or preparation; only one hospital had a vertical laminar [flow] biological safety cabinet, and some concerns about its maintenance | Self-reported questionnaire | Relative risks using two by two table statistics. Unconditional logistic regression measured effect of age, smoking and shift work | No difference in the occurrence of menstrual dysfunction compared to unexposed nurses
Lawson et al. (2009) | Cohort, retrospective (Nurses' Health Study II, USA, 1993–2001, F) | 270 exposed, 6,688 unexposed pregnancies, and 19 pregnancies missing exposure data | Self-reported questionnaire on first trimester exposure to anesthesia, cancer chemotherapy agents, anti-viral drugs, sterilizing agents, and X-ray radiation | Self-report questionnaire on most recent pregnancy since 1993 | Logistic regression adjusted for age; multivariate analysis included all 5 work exposures, parity, shift work, and hours worked adjusted for age and parity | No association with preterm birth (only 22 exposed preterm cases)
Lorente et al. (2000) | Case-control (Working women, Europe, 1989–1992, F) | Cases (infants): 64 cleft lip with or without cleft palate and 36 cleft palate only, 751 controls (no. of infants exposed to cancer chemotherapy agents not reported) | Interviewer-led questionnaire and industrial hygienist defined the exposure by route of exposure, level of exposure, frequency, and reliability of the assessment Note: Authors reported that all exposure to antineoplastic drugs was low-level, low-frequency, and certain exposure | National malformation registry | Odds ratio adjusted for study center, maternal age, mother's socioeconomic status, urbanization, and country of origin; backward stepwise logistic regression to determine exposures independently associated with oral clefts | Cleft palate was not significantly elevated in cases exposed to cancer chemotherapy (adjOR = 5.1, 95% CI = 0.8–34, 2 exposed cases)
McAbee et al. (1993) | Cross-sectional (Nurses, USA, year NR, F) | 663 women and 1,133 pregnancies (318 women exposed to cancer chemotherapy agents, no. of exposed pregnancies NR) | Job title and self-reported questionnaire about occupational exposure to ionizing radiation, cancer chemotherapy agents, solvents, and video display terminals | Self-report questionnaire | Mantel-Haenszel test for linear associations | Authors report a higher prevalence of congenital malformations in nurses exposed to cancer chemotherapy than unexposed nurses (10 exposed cases, p = 0.02)
McDonald et al. (1988a) | Cross-sectional (Working women, Canada, 1982–1984, F) Note: Same population as McDonald 1988b | 47, 913 pregnancies of working women (152 pregnancies exposed to cancer chemotherapy agents) | Interviewer-led questionnaire; jobs were assigned a code without knowledge of outcome; estimate made from published and unpublished studies, and occupational surveillance Note: Medical questionnaire also asked nurses or physicians if they administered cancer chemotherapy agents in the month after the first missed menstrual period | Interviewer-led questionnaire verified by medical records of previous pregnancy outcome | Poisson regression evaluated observed versus expected cases; age, gravidity, history of previous abortion, ethnic group, educational level as well as smoking habit and alcohol consumption | Significantly higher occurrence of congenital malformations from exposed pregnancies (8 exposed cases observed versus 4 cases expected)
McDonald et al. (1988b) | Cross-sectional (Working women, 1982–1984, Canada, F) Note: Same population as McDonald 1988a | 22,713 (63 pregnancies exposed to cancer chemotherapy agents) | Interviewer-led questionnaire; jobs were assigned a code without knowledge of outcome; estimate made from published and unpublished studies, and occupational surveillance | Interviewer-led questionnaire of pregnancy outcome prior to most recent live birth | Poisson regression evaluated observed versus expected cases; age, gravidity, history of previous abortion, ethnic group, educational level, and smoking habit and alcohol consumption | None of the 63 exposed pregnancies ended in stillbirth (expected rate = 0.48)
Medková (1991a) | Cross-sectional (Physicians, nurses, auxiliary workers, Czech Republic, year NR, FM) | 50 exposed infants, 11 unexposed infants (to partners of exposed subjects) | Job title and interviewer-led questionnaire Note: Isolated room for drug preparation only used by 25% of exposed subjects; glove and gowns used | Interviewer-led questionnaire | NR | Two congenital malformations were reported in exposed infants compared to none in the unexposed infants
Peelen et al. (1999) | Cross-sectional (Nurses, the Netherlands, 1990–1997, F) Note: Same data as Fransman et al. 2007c | Exposed: 249 pregnancies and 229 live births; unexposed: 1,010 pregnancies and 956 live births | Job title, self-reported questionnaire, biomonitoring, and environmental monitoring | Self-reported questionnaire on most recent pregnancies; [same as Fransman et al. 2007c] | [Logistic regression]; adjusted for age, coffee consumption, smoking, alcohol consumption, pregnancy, physical strain, and co-exposures (e.g., ionizing radiation, disinfectants), as needed | Significantly higher odds of congenital malformations (OR = 5.1, 95% CI 1.1–23.6; >7 exposed cases), and low birth weight in infants of exposed nurses preparing the agents (adjOR = 16.7, 95% CI = 3.4– 81.6) and low birth weight in infants of exposed nurses involved in cleaning activities associated with the agents (adjOR = 2.9, 95% CI = 1.2–7.2) compared with unexposed nurses; time to pregnancy, stillbirth, premature birth NS
Ratner et al. (2010) | Cohort, retrospective (Female registered nurses from British Columbia, Canada, 1974–2000, F) Note: Subjects followed until 2000 | 22,491 infants total: 190 exposed (Method 1, ever working in oncology or a cancer center) or 1,062 exposed ≥15 days during 1st trimester or 2,650 during 10 years prior to pregnancy (Method 2, weighted duration of exposure) | Two exposure measures: Method 1: Years employed in oncology or at a cancer center (never, <5 years, ≥5 years, or ever) and Method 2: weighted duration of exposure based on job responsibilities (<15 days, ≥15 to 60 days, and >60 days, or ≥15 days; 15 days equivalent to 1 year of work in a job likely not exposed and 60 days equivalent to 1 year of work in job likely exposed to cancer chemotherapy agents) | Provincial cancer registry | Logistic regression; adjusted for age of mother at birth, year of birth, and sex of child | Not significant, but higher, odds of congenital malformations (Method 1, adjOR = 1.42, 95% CI = 0.86–2.36, 17 exposed cases), premature birth (Method 1, adjOR = 1.88, 95% CI = 0.80–4.41, 6 exposed cases), and low birth weight (Method 1, adjOR = 1.41, 95% CI = 0.44–4.54, 3 exposed cases) following exposure at any time during pregnancy; using Method 2, congenital malformations (e.g., cleft palate/lip, adjOR = 1.84, 95% CI = 0.75–4.49, 6 exposed cases), premature birth, low birth weight, and stillbirth were NS
Saurel-Cubizolles et al. (1993) | Cross-sectional (Medical personnel except physicians, France, 1987–1988, F) | 82 exposed, 599 unexposed pregnancies | Job title and interviewer-led questionnaire asked about exposure to anesthetic gases, formol, ionizing radiation, or antineoplastic drugs during the first trimester of pregnancy | Interviewer-led questionnaire | Chi-square analysis and logistic regression | Significantly greater odds of ectopic pregnancy in medical personnel exposed during first trimester to cancer chemotherapy agents (adjOR = 11.4, 95% CI = 2.7–47.6, 6 exposed cases) compared to unexposed subjects
Schaumburg and Olsen (1989) | Cohort, retrospective (Pharmacy assistants, Denmark, 1979–1984, F) Note: Same population as Schaumburg and Olsen 1990a; 1991 | 4.924 women; 1,124 unexposed; only 8 exposed to cancer chemotherapy agents | Membership in national union of pharmacy assistants and self-reported questionnaire asked about work during pregnancy, type of pharmacy, work tasks, exposure to drugs and chemicals | Medical records | Stratified analyses with the Mantel-Haenszel test statistics and an unconditional logistic regression model; adjusted for parity, year of graduation, smoking, and alcohol consumption | Time to pregnancy was not prolonged for the 8 exposed subjects; all women became pregnancy in 0–6 months
Schaumburg and Olsen (1990a) | Cohort, retrospective (Pharmacy assistants, Denmark, 1979–1984, F) Note: Same population as Schaumburg and Olsen 1989; 1991 | 1,182 births; 718 unexposed pregnancies; only 8 pregnancies exposed to cancer chemotherapy agents | Membership in national union of pharmacy assistants and self-reported questionnaire asked about work during pregnancy, type of pharmacy, work tasks, exposure to drugs and chemicals | Medical records and Central Bureau of Statistics | Unconditional logistic regression model; adjusted for maternal age, parity, smoking | No congenital malformations were observed in offspring of 8 exposed pregnancies
Schaumburg and Olsen (1991) | Cohort, retrospective (Pharmacy assistants, Denmark, 1979–1984, F) Note: Same population as Schaumburg and Olsen 1989; 1990a | 1,182 births; 709 unexposed pregnancies; only 8 pregnancies exposed to cancer chemotherapy agents | Membership in national union of pharmacy assistants and self-reported questionnaire asked about work during pregnancy, type of pharmacy, work tasks, exposure to drugs and chemicals | Medical records and Central Bureau of Statistics | Analysis of variance and unconditional logistic regression model; adjusted for maternal age, parity, smoking, and alcohol consumption | Non-significant decreases in birth weight in offspring of exposed subjects; no increased risk of premature birth (OR = 6.50, 95% CI = 0.9–31.6: 2 of 8 exposed births were premature)
Shortridge et al. (1995) | Prospective cohort (Nurses in Oncology Nursing Society, USA, F) | 596 exposed, 497 unexposed women | Self-administered, validated questionnaire | Self-reported questionnaire | Logistic regression; evaluated age, interaction of age and exposure, and stress | Significant logistic regression results for menstrual dysfunction included: age groups >30 years old (p = 0.002), the interaction of age group and exposure (p = 0.03), and job stress (p = 0.045); menstrual dysfunction was significantly higher in nurses ages ≥30 years old (OR = 1.6, 95% CI = 1.3–1.9) and >46 years old (OR = 1.4, 95% CI = 1.1–1.8)
Skov et al. (1992) | Cohort, retrospective (Nurses, Denmark, 1973–1988, F) | 213 exposed, 604 unexposed pregnancies | Employment records of 5 oncology hospitals, and data from head nurses regarding drug handling and administration of individual subjects of individual subjects | Medical records | Logistic regression analysis; adjustment for maternal age | No higher odds of congenital malformations (adjOR = 0.99, 95% CI = 0.5–1.96) or low birth weight (adjOR = 1.06, 95% CI = 0.42–2.67), and no higher odds of altered sex ratio (% male) (OR = 1.12, 95% CI = 0.79–1.61) compared to unexposed infants; no difference in gestational age at birth
Stücker et al. (1993) | Cross-sectional (Nurses, France, 1985–1986, F) | 107 exposed, 292 unexposed pregnancies | Job position and interviewer-led questionnaire Note: At time of study, no special protective equipment was in operation and use of PPE was not uniform | Interviewer-led questionnaire | Logistic regression analysis; evaluated effect of gestational age, infant sex, age of mother at birth, parity, BMI maternal smoking during pregnancy | No association of birth weight with exposure to cancer chemotherapy agents during pregnancy
Valanis et al. (1997) | Case-control (Nurses, nurse's aides, pharmacists, and pharmacy technicians, USA, 1988–1989, FM) Note: Same population as Valanis 1999 | 405 cases and 1,125 controls (355 exposed women due to prior handling of cancer chemotherapy agents) | Self-reported, validated questionnaire | Self-reported questionnaire | Two-way ANOVA and conditional logistic regression | Significant association of infertility with prior handling of cancer chemotherapy agents regardless of skin contact compared to unexposed subjects (OR = 1.5, 95% CI 1.2–2, 206 exposed cases)
Valanis et al. (1999) | Cross-sectional (Nurses, nurse's aides, pharmacists, and pharmacy technicians, USA, 1988–1989, FM) Note: Same population as Valanis 1997 | 1,448 exposed, 5,297 unexposed pregnancies (6,041 pregnancies of female personnel and 704 from spouse of male personnel) | Self-reported, validated questionnaire; subjects exposed to cancer chemotherapy agents 2 years prior or during pregnancy | Self-report questionnaire | Logistic regression analyses for (1) independence model and (2) generalized estimating equations model; all models adjusted for age and gravidity at time of pregnancy, maternal smoking during pregnancy | No difference in stillbirth in subjects exposed during pregnancy (no adjustment for prior exposure) compared to unexposed subjects (adjOR = 1.1, 95% CI = 0.5–2.2)
Walusiak et al. (2003) | Cross-sectional (Physicians, nurses, orderlies, year NR, Poland, F) | 84 exposed, 169 unexposed pregnancies | Job title and self-reported questionnaire | Self-report questionnaire | Mann-Whitney U-test | Significantly higher occurrence of congenital malformations in exposed (4.8%) versus unexposed pregnancies (0.6%); [but incidence did not appear to be higher that US general population value of 3.0% (Correa et al. 2007)]; data on ectopic pregnancy, premature birth, and birth weight NS
Zhang et al. (2016) | Cross-sectional (Nurses, China, 2011 pre-PIVAS and 2013 (post-PIVAS) in Hospital A, F) | Pre-PIVAS: 106 unexposed, 30 exposed non-oncology, 82 exposed oncology; Post-PIVAS: 108 unexposed, 29 exposed non-oncology, 87 exposed oncology, and 112 exposed oncology nurses at Hospital B) | Job title and self-reported questionnaire Note: All exposed nurses involved in mixing and/or administration of cancer chemotherapy agents | Self-report questionnaire | [Student] t-test, Chi-square, and Wilcoxon for outcomes [authors did not specify which method] | Significantly higher rate of infertility among exposed oncology nurses versus unexposed nurses in Hospital A both before (p<0.01; 26.8 versus 9.4%) and after implementation of the PIVAS (p<0.05; 13.8% versus 3.7%); significant (p<0.05) decrease in infertility (13.8% versus 26.8%) and increase in full-term births (reduction in premature births) (33.3% versus 15.9%) in exposed oncology nurses after implementation of PIVAS compared to pre-PIVAS; significantly higher rates of infertility (p<0.01; 30.4% versus 13.8%) and lower full-term births (p<0.05; 19.6% versus 33.3%) were observed in Hospital B (no PIVAS) compared to post-PIVAS Hospital A

aHR = adjusted hazard ratio, adjOR = adjusted odds ratio, aRR = adjusted relative risk, CI = confidence interval, F = female, M = male, NK = natural killer cells, No. = number, NR = not reported, NS = not significant OR = odds ratio, PIVAS = pharmacy intravenous admixture service, USA = United States of America.

Figure E-9

Risk-of-bias Bar Graph for Studies Reporting on Reproductive and Developmental Toxicity, Other Than Spontaneous Abortion, Associated with Occupational Exposure to Cancer Chemotherapy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure E-10

Risk-of-bias Heat Map for Studies Reporting on Reproductive and Developmental Toxicity, Other Than Spontaneous Abortion, Associated with Occupational Exposure to Cancer Chemotherapy

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Fransman 2007 refers to Fransman et al. (2007c).