# Appendix D Data Figures

Figure D-1

Spontaneous Abortion Associated with Occupational Exposure to Cancer Chemotherapy Agents Reported as (A) Odds Ratio or (B) Percent of Pregnancies Affected

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Reference line is indicated as a vertical, blue dotted line in A. Fransman 2007 refers to Fransman et al. (2007c). Number of cases for Valanis et al. (1999) include the spouses of exposed male employees; however, the data graphed are pregnancy outcomes of exposed female employees only. Three studies are not graphed: McDonald et al. (1988b) reported that oncology nurses handling antineoplastic drugs had similar rates of spontaneous abortion compared to control subjects (observed versus expected ratio = 0.97), Medková (1991b) reported a higher number of early spontaneous abortions in exposed medical personnel (8 of 74 pregnancies) compared to unexposed spouses of medical personnel (0 of 11 pregnancies), and Schaumburg and Olsen (1990b) observed no spontaneous abortions among eight pregnancies of exposed pharmacy assistants.

Figure D-2

Risk-of-bias Bar Graph for Studies Reporting Spontaneous Abortions

Interactive figure and additional study details in [underlined: HAWC] (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-3

Risk-of-bias Heat Map for Studies Reporting Spontaneous Abortions

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Fransman 2007 refers to Fransman et al. (2007c).

Figure D-4

Risk-of-bias Bar Graph for All Included Studies Reporting on Genetic Toxicity Outcomes of Structural Chromosomal Aberrations, Micronucleus Induction, and DNA Damage Measured by the Comet Assay

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-5

Risk-of-bias Heat Map for All Included Studies Reporting on Genetic Toxicity Outcomes of Structural Chromosomal Aberrations, Micronucleus Induction, and DNA Damage Measured by the Comet Assay

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-6

Percent of Lymphocytes with Structural Chromosomal Aberrations (Excluding Gaps) Associated with Occupational Exposure to Cancer Chemotherapy Agents Presented as (A) Mean Values or (B) Adjusted Odds Ratio

Interactive figures and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population. In part B, reference line indicated by blue, dotted line.

Figure D-7

Number of Chromosomal Aberrations (Excluding Gaps) per 100 Lymphocytes Scored Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population. Two studies reporting no difference between exposed and unexposed subjects do not appear on the figure because the authors did not report the data values in the publication (Krepinsky et al. 1990) or the reported data were log-transformed and thus could not be included on the same graph with remainder of the data (Cooke et al. 1991).

Figure D-8

Risk-of-bias Bar Graph for All Included Studies Reporting on Structural Chromosomal Aberrations

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-9

Risk-of-bias Heat Map for All Included Studies Reporting on Structural Chromosomal Aberrations

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-10

Number of Cells with Micronuclei/1,000 Cells Scored Associated with Occupational Exposure to Cancer Chemotherapy Agents for (A) Binucleated Lymphocytes or (B) Buccal Cells

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population.

Figure D-11

Number of Micronuclei/1,000 Cells Scored Associated with Occupational Exposure to Cancer Chemotherapy Agents for Binucleated Lymphocytes

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population. An additional study of production workers handling cyclophosphamide reported a significantly (p < 0.05) higher mean log-transformed number of MN/1,000 cells scored in an ANOVA adjusting for age differences (data not shown) (Yager et al. 1988).

Figure D-12

Number of Micronuclei/1,000 Cells Scored Associated with Occupational Exposure to Cancer Chemotherapy Agents for Buccal Cells

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population.

Figure D-13

Risk-of-bias Bar Graph for Included Studies Reporting on Micronucleus Induction

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-14

Risk-of-bias Heat Map for Included Studies Reporting on Micronucleus Induction

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-15

Percent of Tail DNA Measured by the Comet Assay Associated with Occupational Exposure to Cancer Chemotherapy Agents for (A) Studies Reporting Values in the Expected Range and (B) Studies Reporting Higher than Expected Values

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population.

Figure D-16

Tail Length (μm) Measured by the Comet Assay Associated with Occupational Exposure to Cancer Chemotherapy Agents

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population. An additional study reported a greater log-transformed mean tail length (μm) in exposed nurses than controls following adjustment for age, smoking, coffee-drinking habits, hemoglobin, ionizing radiation, and hospital (data not graphed) (Sasaki et al. 2008).

Figure D-17

Tail Moment Measured by the Comet Assay Associated with Occupational Exposure to Cancer Chemotherapy Agents for (A) Studies in the Expected Range and (B) Studies in Higher than the Expected Range

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population. An additional study reported similar values of log-transformed mean tail moment in exposed nurses and controls following adjustment for age, smoking, coffee-drinking habits, hemoglobin, ionizing radiation, and hospital (data not graphed) (Sasaki et al. 2008).

Figure D-18

DNA Damage Index Measured by the Comet Assay Associated with Occupational Exposure to Cancer Chemotherapy Agents Reported as (A) Mean Comet Score or (B) Mean Number of Cells

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Controls refer to the unexposed, reference population. The mean comet scores (A) were calculated by binning the cells per category of DNA damage and multiplying the number of cells per category by a number per the level of DNA damage and summing up the numbers across the categories (see individual studies for more details). In addition, Mader et al. (2009) reported that a trend analysis for the entire observation period revealed a significantly greater (p = 0.02) genotoxicity in the alkaline comet assay compared to unexposed subjects; no means or standard deviations were provided (data not graphed).

Figure D-19

Risk-of-bias Bar Graph for Included Studies Reporting DNA Damage Measured by the Comet Assay

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).

Figure D-20

Risk-of-bias Heat Map for Included Studies Reporting DNA Damage Measured by the Comet Assay

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a).