# Appendix C Risk-of-bias Assessment for All Included Studies

Figure C-1

Risk-of-bias Heat Map for Included Studies Reporting on Health Outcomes

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/196/) (NTP, 2015a). Fransman 2007 refers to Fransman et al. (2007c).