# Appendix B List of Included Studies Reporting Health Outcomes

Anwar WA, Salama SI, el Serafy MM, Hemida SA, Hafez AS. 1994. Chromosomal aberrations and micronucleus frequency in nurses occupationally exposed to cytotoxic drugs. Mutagenesis. 9(4):315-317. https://dx.doi.org/10.1093/mutage/9.4.315

Biró A, Fodor Z, Major J, Tompa A. 2011. Immunotoxicity monitoring of hospital staff occupationally exposed to cytostatic drugs. Pathol Oncol Res. 17(2):301-308. https://dx.doi.org/10.1007/s12253-010-9317-z

Bolognesi C, Nucci MC, Colacci AM, Grilli S, Ippoliti F, Mucci N, Romano Spica V, Barbieri A, Canitano N, Chiozzotto D et al. 2005. [Biomonitoring of nurses occupationally exposed to antineoplastic drugs: The IMEPA Project]. Epidemiol Prev. 29(5-6 Suppl):91-95.

Boughattas AB, Bouraoui S, Debbabi F, El Ghazel H, Saad A, Mrizak N. 2010. [Genotoxic risk assessment of nurses handling antineoplastic drugs]. Ann Biol Clin. 68(5):545-553. https://dx.doi.org/10.1684/abc.2010.0464

Bouraoui S, Brahem A, Tabka F, Mrizek N, Saad A, Elghezal H. 2011. Assessment of chromosomal aberrations, micronuclei and proliferation rate index in peripheral lymphocytes from Tunisian nurses handling cytotoxic drugs. Environ Toxicol Pharmacol. 31(1):250-257. https://dx.doi.org/10.1016/j.etap.2010.11.004

Bouyer J, Saurel-Cubizolles MJ, Grenier C, Aussel L, Job-Spira N. 1998. Ectopic pregnancy and occupational exposure of hospital personnel. Scand J Work Environ Health. 24(2):98-103. https://dx.doi.org/10.5271/sjweh.285

Buono-Michel M, Orsière T, Sari-Minodier I, Botta A. 2000. Cytogenetic biomonitoring of nurses handling cytostatics. Arch Mal Prof. 61(3):148-155.

Burgaz S, Karahalil B, Bayrak P, Taskin L, Yavuzaslan F, Bokesoy I, Anzion RB, Bos RP, Platin N. 1999. Urinary cyclophosphamide excretion and micronuclei frequencies in peripheral lymphocytes and in exfoliated buccal epithelial cells of nurses handling antineoplastics. Mutat Res. 439(1):97-104. https://dx.doi.org/10.1016/S1383-5718(98)00180-6

Burgaz S, Karahalil B, Canhi Z, Terzioglu F, Ancel G, Anzion RB, Bos RP, Huttner E. 2002. Assessment of genotoxic damage in nurses occupationally exposed to antineoplastics by the analysis of chromosomal aberrations. Hum Exp Toxicol. 21(3):129-135. https://dx.doi.org/10.1191/0960327102ht230oa

Buschini A, Villarini M, Feretti D, Mussi F, Dominici L, Zerbini I, Moretti M, Ceretti E, Bonfiglioli R, Carrieri M et al. 2013. Multicentre study for the evaluation of mutagenic/carcinogenic risk in nurses exposed to antineoplastic drugs: Assessment of DNA damage. Occup Environ Med. 70(11):789-794. https://dx.doi.org/10.1136/oemed-2013-101475

Caciari T, Casale T, Tomei F, Samperi I, Tomei G, Capozzella A, Ripamonti K, Scala B, Andreozzi G, Nardone N et al. 2012. Exposure to antineoplastic drugs in health care and blood chemistry parameters. Clin Ter. 163(6):e387-392.

Cavallo D, Ursini CL, Perniconi B, Francesco AD, Giglio M, Rubino FM, Marinaccio A, Iavicoli S. 2005. Evaluation of genotoxic effects induced by exposure to antineoplastic drugs in lymphocytes and exfoliated buccal cells of oncology nurses and pharmacy employees. Mutat Res. 587(1-2):45-51. https://dx.doi.org/10.1016/j.mrgentox.2005.07.008

Connor TH, DeBord DG, Pretty JR, Oliver MS, Roth TS, Lees PS, Krieg EF, Jr., Rogers B, Escalante CP, Toennis CA et al. 2010. Evaluation of antineoplastic drug exposure of health care workers at three university-based US cancer centers. J Occup Environ Med. 52(10):1019-1027. https://dx.doi.org/10.1097/JOM.0b013e3181f72b63

Cooke J, Williams J, Morgan RJ, Cooke P, Calvert RT. 1991. Use of cytogenetic methods to determine mutagenic changes in the blood of pharmacy personnel and nurses who handle cytotoxic agents. Am J Hosp Pharm. 48(6):1199-1205.

Cornetta T, Pádua L, Testa A, Ievoli E, Festa F, Tranfo G, Baccelliere L, Cozzi R. 2008. Molecular biomonitoring of a population of nurses handling antineoplastic drugs. Mutat Res. 638(1-2):75-82. https://dx.doi.org/10.1016/j.mrfmmm.2007.08.017

Deng HP, Lou JL, Zhang MB, Wu W, Jin LF, Chen SJ, Zheng W, Wang BH, He JL. 2006. Detecting the cytogenetic effects in workers occupationally exposed to vincristine with four genetic tests. Mutat Res. 599(1-2):152-159. https://dx.doi.org/10.1016/j.mrfmmm.2006.02.003

Deng HP, Zhang MB, He JL, Wu W, Jin LF, Zheng W, Lou JL, Wang BH. 2005. Investigating genetic damage in workers occupationally exposed to methotrexate using three genetic end-points. Mutagenesis. 20(5):351-357. https://dx.doi.org/10.1093/mutage/gei048

El-Ebiary AA, Abuelfadl AA, Sarhan NI. 2013. Evaluation of genotoxicity induced by exposure to antineoplastic drugs in lymphocytes of oncology nurses and pharmacists. J Appl Toxicol. 33(3):196-201. https://dx.doi.org/10.1002/jat.1735

Elshamy K, El-Hadidi M, El-Roby M, Fouda M. 2010. Health hazards among oncology nurses exposed to chemotherapy drugs. Afr J Haematol Oncol. 1(3):70-78.

Ensslin AS, Huber R, Pethran A, Rommelt H, Schierl R, Kulka U, Fruhmann G. 1997. Biological monitoring of hospital pharmacy personnel occupationally exposed to cytostatic drugs: Urinary excretion and cytogenetics studies. Int Arch Occup Environ Health. 70(3):205-208. https://dx.doi.org/10.1007/s004200050208

Fransman W, Roeleveld N, Peelen S, de Kort W, Kromhout H, Heederik D. 2007. Nurses with dermal exposure to antineoplastic drugs: Reproductive outcomes. Epidemiology. 18(1):112-119. https://dx.doi.org/10.1097/01.ede.0000246827.44093.c1

Garaj-Vrhovac V, Kopjar N. 1998. Micronuclei in cytokinesis-blocked lymphocytes as an index of occupational exposure to antineoplastic drugs. Radiol Oncol. 32(4):385-392.

Grummt T, Grummt HJ, Schott G. 1993. Chromosomal aberrations in peripheral lymphocytes of nurses and physicians handling antineoplastic drugs. Mutat Res. 302(1):19-24. https://dx.doi.org/10.1016/0165-7992(93)90085-A

Gunnarsdóttir HK, Aspelund T, Karlsson T, Rafnsson VV. 1997. Occupational risk factors for breast cancer among nurses. Int J Occup Environ Health. 3(4):254-258. https://dx.doi.org/10.1179/oeh.1997.3.4.254

Harris PE, Connor TH, Stevens KR, Theiss JC. 1992. Cytogenetic assessment of occupational exposure of nurses to antineoplastic agents. J Occup Med Toxicol. 1(3):243-254.

Hemminki K, Kyyronen P, Lindbohm ML. 1985. Spontaneous abortions and malformations in the offspring of nurses exposed to anaesthetic gases, cytostatic drugs, and other potential hazards in hospitals, based on registered information of outcome. J Epidemiol Commun H. 39(2):141-147. https://dx.doi.org/10.1136/jech.39.2.141

Hessel H, Radon K, Pethran A, Maisch B, Grobmair S, Sautter I, Fruhmann G. 2001. The genotoxic risk of hospital, pharmacy and medical personnel occupationally exposed to cytostatic drugs--evaluation by the micronucleus assay. Mutat Res. 497(1-2):101-109. https://dx.doi.org/10.1016/S1383-5718(01)00236-4

Hola N, Sram RJ, Roznickova I. 1988. Evaluation of genotoxic risk in occupational exposure to cytostatics. Prac Lek. 40(4):154-157.

Izdes S, Sardas S, Kadioglu E, Kaymak C, Ozcagli E. 2009. Assessment of genotoxic damage in nurses occupationally exposed to anaesthetic gases or antineoplastic drugs by the comet assay. J Occup Health. 51(3):283-286. https://dx.doi.org/10.1080/152873901300018011

Jakab MG, Major J, Tompa A. 2001. Follow-up genotoxicological monitoring of nurses handling antineoplastic drugs. J Toxicol Environ Health A. 62(5):307-318. https://dx.doi.org/10.1080/152873901300018011

Jeebhay M, Mbuli S, Uebel R. 1993. Assessment of exposure to chloramphenicol and azathioprine among workers in a South African pharmaceutical plant. Int Arch Occup Environ Health. 65(S1):S119-122. https://dx.doi.org/10.1007/BF00381321

Jochimsen PR, Corder MP, Lachenbruch PA, Spaight ME. 1988. Preparation and administration of chemotherapy. Haematological consequences for hospital-based nurses. Med Toxicol Adverse Drug Exp. 3(1):59-63. https://dx.doi.org/10.1007/BF03259931

Kašuba V, Rozgaj R, Garaj-Vrhovac V. 1999. Analysis of sister chromatid exchange and micronuclei in peripheral blood lymphocytes of nurses handling cytostatic drugs. J Appl Toxicol. 19(6):401-404. https://dx.doi.org/10.1002/(SICI)1099-1263(199911/12)19:6%3c401::AID-JAT592%3e3.0.CO;2-H

Kevekordes S, Gebel TW, Hellwig M, Dames W, Dunkelberg H. 1998. Human effect monitoring in cases of occupational exposure to antineoplastic drugs: A method comparison. Occup Environ Med. 55(3):145-149. https://dx.doi.org/10.1136/oem.55.3.145

Kopjar N, Garaj-Vrhovac V. 2001. Application of the alkaline comet assay in human biomonitoring for genotoxicity: A study on Croatian medical personnel handling antineoplastic drugs. Mutagenesis. 16(1):71-78. https://dx.doi.org/10.1093/mutage/16.1.71

Kopjar N, Garaj-Vrhovac V, Kasuba V, Rozgaj R, Ramic S, Pavlica V, Zeljezic D. 2009. Assessment of genotoxic risks in Croatian health care workers occupationally exposed to cytotoxic drugs: A multi-biomarker approach. Int J Hyg Environ Health. 212(4):414-431. https://dx.doi.org/10.1016/j.ijheh.2008.10.001

Krepinsky A, Bryant DW, Davison L, Young B, Heddle J, McCalla DR, Douglas G, Michalko K. 1990. Comparison of three assays for genetic effects of antineoplastic drugs on cancer patients and their nurses. Environ Mol Mutagen. 15(2):83-92. https://dx.doi.org/10.1002/em.2850150205

Krstev S, Perunicic B, Vidakovic A. 2003. Work practice and some adverse health effects in nurses handling antineoplastic drugs. Med Lav. 94(5):432-439.

Ladeira C, Viegas S, Pádua M, Gomes M, Carolino E, Gomes MC, Brito M. 2014. Assessment of genotoxic effects in nurses handling cytostatic drugs. J Toxicol Environ Health A. 77(14-16):879-887. https://dx.doi.org/10.1080/15287394.2014.910158

Laffon B, Teixeira JP, Silva S, Loureiro J, Torres J, Pasaro E, Mendez J, Mayan O. 2005. Genotoxic effects in a population of nurses handling antineoplastic drugs, and relationship with genetic polymorphisms in DNA repair enzymes. Am J Ind Med. 48(2):128-136. https://dx.doi.org/10.1080/15287394.2014.910158

Lawson CC, Rocheleau CM, Whelan EA, Lividoti Hibert EN, Grajewski B, Spiegelman D, Rich-Edwards JW. 2012. Occupational exposures among nurses and risk of spontaneous abortion. Am J Obstet Gynecol. 206(4):327.e321-327.e328. https://dx.doi.org/10.1016/j.ajog.2011.12.030

Lawson CC, Whelan EA, Hibert EN, Grajewski B, Spiegelman D, Rich-Edwards JW. 2009. Occupational factors and risk of preterm birth in nurses. Am J Obstet Gynecol. 200(1):51 e51-58. https://dx.doi.org/10.1016/j.ajog.2008.08.006

Li ML, Zhang YY, Wang QX, Pei Y, Xiao CS. 2005. [Effects of antineoplastics drug on T-lymphocytes subsets in nurses of occupational exposure to antineoplastic drugs]. Zhonghua Lao Dong Wei Sheng Zhi Ye Bing Za Zhi. 23(6):450-451.

Lorente C, Cordier S, Bergeret A, De Walle HE, Goujard J, Ayme S, Knill-Jones R, Calzolari E, Bianchi F. 2000. Maternal occupational risk factors for oral clefts. Occupational Exposure and Congenital Malformation Working Group. Scand J Work Environ Health. 26(2):137-145. https://dx.doi.org/10.5271/sjweh.523

Machado-Santelli GM, Cerqueira EM, Oliveira CT, Pereira CA. 1994. Biomonitoring of nurses handling antineoplastic drugs. Mutat Res. 322(3):203-208. https://dx.doi.org/10.1016/0165-1218(94)90007-8

Mader RM, Kokalj A, Kratochvil E, Pilger A, Rudiger HW. 2009. Longitudinal biomonitoring of nurses handling antineoplastic drugs. J Clin Nurs. 18(2):263-269. https://dx.doi.org/10.1111/j.1365-2702.2007.02189.x

Mahmoodi M, Soleyman-Jahi S, Zendehdel K, Mozdarani H, Azimi C, Farzanfar F, Safari Z, Mohagheghi MA, Khaleghian M, Divsalar K et al. 2017. Chromosomal aberrations, sister chromatid exchanges, and micronuclei in lymphocytes of oncology department personnel handling anti-neoplastic drugs. Drug Chem Toxicol. 40(2):235-240. https://dx.doi.org/10.1080/01480545.2016.1209678

Maluf SW, Erdtmann B. 2000. Follow-up study of the genetic damage in lymphocytes of pharmacists and nurses handling antineoplastic drugs evaluated by cytokinesis-block micronuclei analysis and single cell gel electrophoresis assay. Mutat Res. 471(1-2):21-27. https://dx.doi.org/10.1016/S1383-5718(00)00107-8

McAbee RR, Gallucci BJ, Checkoway H. 1993. Adverse reproductive outcomes and occupational exposures among nurses: An investigation of multiple hazardous exposures. AAOHN J. 41(3):110-119.

McDiarmid MA, Oliver MS, Roth TS, Rogers B, Escalante C. 2010. Chromosome 5 and 7 abnormalities in oncology personnel handling anticancer drugs. J Occup Environ Med. 52(10):1028-1034. https://dx.doi.org/10.1097/JOM.0b013e3181f73ae6

McDiarmid MA, Rogers B, Oliver MS. 2014. Chromosomal effects of non-alkylating drug exposure in oncology personnel. Environ Mol Mutagen. 55(4):369-374. https://dx.doi.org/10.1002/em.21852

McDonald AD, McDonald JC, Armstrong B, Cherry NM, Cote R, Lavoie J, Nolin AD, Robert D. 1988. Congenital defects and work in pregnancy. Brit J Ind Med. 45(9):581-588.

McDonald AD, McDonald JC, Armstrong B, Cherry NM, Cote R, Lavoie J, Nolin AD, Robert D. 1988. Fetal death and work in pregnancy. Brit J Ind Med. 45(3):148-157.

Medková J. 1990. Cytogenetic analysis of peripheral lymphocytes in occupationally exposed health personnel. Acta Univ Palacki Olomuc Fac Med. 126:93-106.

Medková J. 1991. An analysis of the health condition of personnel exposed to cytostatics at an oncology unit. Acta Univ Palacki Olomuc Fac Med. 130:311-322.

Milković-Kraus S, Horvat D. 1991. Chromosomal abnormalities among nurses occupationally exposed to antineoplastic drugs. Am J Ind Med. 19(6):771-774. https://dx.doi.org/10.1002/ajim.4700190609

Moretti M, Grollino MG, Pavanello S, Bonfiglioli R, Villarini M, Appolloni M, Carrieri M, Sabatini L, Dominici L, Stronati L et al. 2015. Micronuclei and chromosome aberrations in subjects occupationally exposed to antineoplastic drugs: A multicentric approach. Int Arch Occup Environ Health. 88(6):683-695. https://dx.doi.org/10.1007/s00420-014-0993-y

Moretti M, Villarini M, Dominici L, Fatigoni C, Dell'omo M, Elisei E, Muzi G, Monarca S. 2013. [Evaluation of genotoxic effects in subjects occupationally exposed to antineoplastic drugs]. Ig Sanita Pubbl. 69(1):55-77.

Mrđanović J, Jungic S, Solajic S, Bogdanovic V, Jurisic V. 2012. Effects of orally administered antioxidants on micronuclei and sister chromatid exchange frequency in workers professionally exposed to antineoplastic agents. Food Chem Toxicol. 50(8):2937-2944. https://dx.doi.org/10.1016/j.fct.2012.04.027

Mušák L, Smerhovsky Z, Halasova E, Osina O, Letkova L, Vodickova L, Polakova V, Buchancova J, Hemminki K, Vodicka P. 2013. Chromosomal damage among medical staff occupationally exposed to volatile anesthetics, antineoplastic drugs, and formaldehyde. Scand J Work Environ Health. 39(6):618-630. https://dx.doi.org/10.5271/sjweh.3358

Mušák L, Vodicka P, Klimentova G, Soucek P, Hanova M, Mikulkova R, Buchancova J, Vodickova L, Polakova V, Pec M. 2006. Chromosomal damage and polymorphisms of DNA repair genes XRCC1 and XRCC3 in workers exposed to cytostatics. Neuro Endocrinol Lett. 27 Suppl 2:57-60.

Nikula E, Kiviniitty K, Leisti J, Taskinen PJ. 1984. Chromosome aberrations in lymphocytes of nurses handling cytostatic agents. Scand J Work Environ Health. 10(2):71-74. https://dx.doi.org/10.5271/sjweh.2355

Peelen S, Roeleveld N, Heederik D, Kromhout H, De Kort W. 1999. Reproductietoxische effecten bij ziekenhuispersoneel [Toxic effects on reproduction in hospital personnel]. The Hague, Netherlands: Dutch Ministry of Social Affairs and Employment.

Pilger A, Kohler I, Stettner H, Mader RM, Rizovski B, Terkola R, Diem E, Franz-Hainzl E, Konnaris C, Valic E et al. 2000. Long-term monitoring of sister chromatid exchanges and micronucleus frequencies in pharmacy personnel occupationally exposed to cytostatic drugs. Int Arch Occup Environ Health. 73(7):442-448. https://dx.doi.org/10.1007/s004200000164

Pohlová H, Cerna M, Rossner P. 1986. Chromosomal aberrations, SCE and urine mutagenicity in workers occupationally exposed to cytostatic drugs. Mutat Res. 174(3):213-217. https://dx.doi.org/10.1016/0165-7992(86)90154-5

Ratner PA, Spinelli JJ, Beking K, Lorenzi M, Chow Y, Teschke K, Le ND, Gallagher RP, Dimich-Ward H. 2010. Cancer incidence and adverse pregnancy outcome in registered nurses potentially exposed to antineoplastic drugs. BMC Nurs. 9:15. https://dx.doi.org/10.1186/1472-6955-9-15

Rekhadevi PV, Sailaja N, Chandrasekhar M, Mahboob M, Rahman MF, Grover P. 2007. Genotoxicity assessment in oncology nurses handling anti-neoplastic drugs. Mutagenesis. 22(6):395-401. https://dx.doi.org/10.1093/mutage/gem032

Rodríguez-Montero HM, Argote-Pelegrino E, Díaz-Curbelo A, Cuétara-Lugo EB. 2016. Genotoxicity biomarkers for monitoring occupational exposure to antineoplastic drugs. J Pharm Pharmacogn Res. 4(3):122-133.

Rogers B, Emmett EA. 1987. Handling antineoplastic agents: Urine mutagenicity in nurses. Image J Nurs Sch. 19(3):108-113. https://dx.doi.org/10.1111/j.1547-5069.1987.tb00604.x

Rombaldi F, Cassini C, Salvador M, Saffi J, Erdtmann B. 2009. Occupational risk assessment of genotoxicity and oxidative stress in workers handling anti-neoplastic drugs during a working week. Mutagenesis. 24(2):143-148. https://dx.doi.org/10.1093/mutage/gen060

Roth S, Norppa H, Jarventaus H, Kyyronen P, Ahonen M, Lehtomaki J, Sainio H, Sorsa M. 1994. Analysis of chromosomal aberrations, sister-chromatid exchanges and micronuclei in peripheral lymphocytes of pharmacists before and after working with cytostatic drugs. Mutat Res. 325(4):157-162. https://dx.doi.org/10.1016/0165-7992(94)90079-5

Rubeš J, Kucharova S, Vozdova M, Musilova P, Zudova Z. 1998. Cytogenetic analysis of peripheral lymphocytes in medical personnel by means of FISH. Mutat Res. 412(3):293-298. https://dx.doi.org/10.1016/S1383-5718(97)00201-5

Sasaki M, Dakeishi M, Hoshi S, Ishii N, Murata K. 2008. Assessment of DNA damage in Japanese nurses handling antineoplastic drugs by the comet assay. J Occup Health. 50(1):7-12. https://dx.doi.org/10.1539/joh.50.7

Saurel-Cubizolles MJ, Job-Spira N, Estryn-Behar M. 1993. Ectopic pregnancy and occupational exposure to antineoplastic drugs. Lancet. 341(8854):1169-1171. https://dx.doi.org/10.1016/0140-6736(93)91000-C

Schaumburg I, Olsen J. 1989. Time to pregnancy among Danish pharmacy assistants. Scand J Work Environ Health. 15:222-226. https://dx.doi.org/10.5271/sjweh.1859

Schaumburg I, Olsen J. 1990a. Congenital malformations and death among the offspring of Danish pharmacy assistants. Am J Ind Med. 18(5):555-564. https://dx.doi.org/10.1002/ajim.4700180506

Schaumburg I, Olsen J. 1990b. Risk of spontaneous abortion among Danish pharmacy assistants. Scand J Work Environ Health. 16(3):169-174. https://dx.doi.org/10.5271/sjweh.1797

Schaumburg I, Olsen J. 1991. Birth weight and gestational age among children of Danish pharmacy assistants. J Epidemiol Commun H. 45(1):49-51. https://dx.doi.org/10.1136/jech.45.1.49

Selevan SG, Lindbohm ML, Hornung RW, Hemminki K. 1985. A study of occupational exposure to antineoplastic drugs and fetal loss in nurses. N Engl J Med. 313(19):1173-1178. https://dx.doi.org/10.1056/NEJM198511073131901

Sessink PJ, Cerna M, Rossner P, Pastorkova A, Bavarova H, Frankova K, Anzion RB, Bos RP. 1994a. Urinary cyclophosphamide excretion and chromosomal aberrations in peripheral blood lymphocytes after occupational exposure to antineoplastic agents. Mutat Res. 309(2):193-199. https://dx.doi.org/10.1016/0027-5107(94)90092-2

Sessink PJ, Verplanke AJ, Herber RF, Bos RP. 1997a. Occupational exposure to antineoplastic agents and parameters for renal dysfunction. Int Arch Occup Environ Health. 69(3):215-218. https://dx.doi.org/10.1007/s004200050139

Shahrasbi AA, Afshar M, Shokraneh F, Monji F, Noroozi M, Ebrahimi-Khojin M, Madani SF, Ahadi-Barzoki M, Rajabi M. 2014. Risks to health professionals from hazardous drugs in Iran: A pilot study of understanding of healthcare team to occupational exposure to cytotoxics. EXCLI Journal. 13:491-501.

Shortridge LA, Lemasters GK, Valanis B, Hertzberg V. 1995. Menstrual cycles in nurses handling antineoplastic drugs. Cancer Nurs. 18(6):439-444. https://dx.doi.org/10.1097/00002820-199512000-00003

Skov T, Maarup B, Olsen J, Rorth M, Winthereik H, Lynge E. 1992. Leukaemia and reproductive outcome among nurses handling antineoplastic drugs. Brit J Ind Med. 49(12):855-861.

Sorsa M, Pyy L, Salomaa S, Nylund L, Yager JW. 1988. Biological and environmental monitoring of occupational exposure to cyclophosphamide in industry and hospitals. Mutat Res. 204(3):465-479. https://dx.doi.org/10.1016/0165-1218(88)90042-0

Spatari G, Fenga C, Minciullo PL, Di Pasquale G, Cacciola A, Ventura-Spagnolo E, Gangemi S. 2005. Modification of interleukin-15 serum levels in workers exposed to chemotherapeutic agents. Mediators Inflamm. 2005(1):60-62. https://dx.doi.org/10.1155/MI.2005.60

Stücker I, Caillard JF, Collin R, Gout M, Poyen D, Hemon D. 1990. Risk of spontaneous abortion among nurses handling antineoplastic drugs. Scand J Work Environ Health. 16(2):102-107. https://dx.doi.org/10.5271/sjweh.1811

Stücker I, Hirsch A, Doloy T, Bastie-Sigeac I, Hemon D. 1986. Urine mutagenicity, chromosomal abnormalities and sister chromatid exchanges in lymphocytes of nurses handling cytostatic drugs. Int Arch Occup Environ Health. 57(3):195-205. https://dx.doi.org/10.1007/BF00405788

Stücker I, Mandereau L, Hemon D. 1993. Relationship between birthweight and occupational exposure to cytostatic drugs during or before pregnancy. Scand J Work Environ Health. 19(3):148-153. https://dx.doi.org/10.5271/sjweh.1488

Taskinen H, Kyyronen P, Hemminki K, Hoikkala M, Lajunen K, Lindbohm ML. 1994. Laboratory work and pregnancy outcome. J Occup Environ Med. 36(3):311-319. https://dx.doi.org/10.1097/00043764-199403000-00008

Taskinen H, Lindbohm ML, Hemminki K. 1986. Spontaneous abortions among women working in the pharmaceutical-industry. Brit J Ind Med. 43(3):199-205.

Testa A, Giachelia M, Palma S, Appolloni M, Padua L, Tranfo G, Spagnoli M, Tirindelli D, Cozzi R. 2007. Occupational exposure to antineoplastic agents induces a high level of chromosome damage. Lack of an effect of GST polymorphisms. Toxicol Appl Pharmacol. 223(1):46-55. https://dx.doi.org/10.1016/j.taap.2007.05.006

Thiringer G, Granung G, Holmen A, Hogstedt B, Jarvholm B, Jonsson D, Persson L, Wahlstrom J, Westin J. 1991. Comparison of methods for the biomonitoring of nurses handling antitumor drugs. Scand J Work Environ Health. 17(2):133-138. https://dx.doi.org/10.5271/sjweh.1724

Thulin H, Sundberg E, Hansson K, Cole J, Hartley-Asp B. 1995. Occupational exposure to nor-nitrogen mustard: Chemical and biological monitoring. Toxicol Ind Health. 11(1):89-97. https://dx.doi.org/10.1177/074823379501100108

Tigha Bouaziz N, Tourab D, Nezzal AM. 2016. Study of cardiovascular morbidity in nurses exposed to cytostatic drugs: Multivaried approach analysis. Ann Cardiol Angeiol. 65(3):179-184. https://dx.doi.org/10.1016/j.ancard.2016.04.014

Ündeğer U, Basaran N, Kars A, Guc D. 1999. Assessment of DNA damage in nurses handling antineoplastic drugs by the alkaline COMET assay. Mutat Res. 439(2):277-285. https://dx.doi.org/10.1016/S1383-5718(99)00002-9

Ursini CL, Cavallo D, Colombi A, Giglio M, Marinaccio A, Iavicoli S. 2006. Evaluation of early DNA damage in healthcare workers handling antineoplastic drugs. Int Arch Occup Environ Health. 80(2):134-140. https://dx.doi.org/10.1007/s00420-006-0111-x

Valanis B, Vollmer W, Labuhn K, Glass A. 1997. Occupational exposure to antineoplastic agents and self-reported infertility among nurses and pharmacists. J Occup Environ Med. 39(6):574-580. https://dx.doi.org/10.1097/00043764-199706000-00013

Valanis B, Vollmer WM, Steele P. 1999. Occupational exposure to antineoplastic agents: Self-reported miscarriages and stillbirths among nurses and pharmacists. J Occup Environ Med. 41(8):632-638. https://dx.doi.org/10.1097/00043764-199908000-00004

Valanis BG, Hertzberg V, Shortridge L. 1987. Antineoplastic drugs. Handle with care. AAOHN J. 35(11):487-492.

Valanis BG, Vollmer WM, Labuhn KT, Glass AG. 1993. Acute symptoms associated with antineoplastic drug handling among nurses. Cancer Nurs. 16(4):288-295. https://dx.doi.org/10.1097/00002820-199308000-00005

Valanis BG, Vollmer WM, Labuhn KT, Glass AG. 1993. Association of antineoplastic drug handling with acute adverse effects in pharmacy personnel. Am J Hosp Pharm. 50(3):455-462.

Villarini M, Dominici L, Piccinini R, Fatigoni C, Ambrogi M, Curti G, Morucci P, Muzi G, Monarca S, Moretti M. 2011. Assessment of primary, oxidative and excision repaired DNA damage in hospital personnel handling antineoplastic drugs. Mutagenesis. 26(3):359-369. https://dx.doi.org/10.1093/mutage/geq102

Walusiak J, Wagrowska-Koski E, Palczynski C. 2003. [Health effects of occupational exposure to cytostatics in medicinal personnel in the light of compulsory prophylactics: a cross-sectional study]. Med Pr. 54(3):229-236.

Yager JW, Sorsa M, Selvin S. 1988. Micronuclei in cytokinesis-blocked lymphocytes as an index of occupational exposure to alkylating cytostatic drugs. IARC Sci Publ. (89):213-216.

Yang D, Xu S, Wang J. 2002a. [The study of DNA damage of peripheral lymphocytes in the nurses occupationally exposed to anticancer drugs]. Zhonghua Lao Dong Wei Sheng Zhi Ye Bing Za Zhi. 20(3):197-199.

Yang DP, Xu SJ, Wang JX. 2002b. Study on chromosome damage among nurses occupationally exposed to antineoplastic drugs in an oncology department. Biomed Environ Sci. 15(3):268-270.

Yin H, Xu XQ, Lin LY. 2010. [DNA damage of antineoplastic drugs exposure on nurses]. Zhonghua Lao Dong Wei Sheng Zhi Ye Bing Za Zhi. 28(3):218-219.

Yoshida J, Kosaka H, Tomioka K, Kumagai S. 2006. Genotoxic risks to nurses from contamination of the work environment with antineoplastic drugs in Japan. J Occup Health. 48(6):517-522. https://dx.doi.org/10.1539/joh.48.517

Zhang X, Zheng Q, Lv Y, An M, Zhang Y, Wei Y, Feng W. 2016. Evaluation of adverse health risks associated with antineoplastic drug exposure in nurses at two Chinese hospitals: The effects of implementing a pharmacy intravenous admixture service. Am J Ind Med. 59(4):264-273. https://dx.doi.org/10.1002/ajim.22553