# Appendix A Literature Search Strategy

The strategy for this search is broad for the consideration of adverse health outcomes, including biomarkers of effect, and comprehensive for occupational exposure to cancer chemotherapy agents as an exposure or treatment in order to ensure inclusion of relevant papers.

Table A-1 Literature Search Strategy

Database | Search Terms
Embase | ('Antineoplastic agent'/exp OR 'antineoplastic agent') AND ('health care personnel'/exp OR 'health care personnel') AND ('occupational exposure'/de OR 'occupational exposure' OR 'occupational hazard'/de OR 'occupational hazard' OR 'occupational safety'/de OR 'occupational safety') AND ([embase]/lim OR [embase classic]/lim)
PubMed | (“Neoplasms/drug therapy”[mh] OR “antineoplastic protocols”[mh] OR “chemotherapy, adjuvant”[mh] OR “antineoplastic agents”[mh] OR “antineoplastic agents”[pharmacological action] OR chemotherapy[tiab] OR chemotherapies[tiab] OR chemotherapeutic*[tiab] OR anticancer[tiab] OR antineoplastic*[tiab] OR anti- tumor*[tiab] OR anti-tumour*[tiab] OR cytostatic[tiab] OR hazardous-drug*[tiab] OR drug*-hazardous[tiab] OR category-D[tiab] OR category-x[tiab])) OR (“4 aminofolic acid”[tiab] OR “4 epidoxorubicin”[tiab] OR “5 fluorouracil”[tiab] OR “6 mercaptopurine”[tiab] OR “6 thioguanine”[tiab] OR Abraxane[tiab] OR adrucil[tiab] OR “all-trans retinoic acid”[tiab] OR ATRA[tiab] OR altretamine[tiab] OR adriamycin[tiab] OR “actinomycin D”[tiab] OR aminopterin[tiab] OR Anastrozole[tiab] OR “ARA-C”[tiab] OR arimidex[tiab] OR aromasin[tiab] OR “behenoyl cytosine arabinoside”[tiab] OR bevacizumab[tiab] OR BHAC[tiab] OR bleomycin[tiab] OR bortezomib[tiab] OR busulfan[tiab] OR busulfex[tiab] OR carboplatin[tiab] OR capecitabine[tiab] OR carmustine[tiab] OR Cerubidine[tiab] OR chlorambucil[tiab] OR cisplatin[tiab] OR cis-platinum[tiab] OR cyclophosphamide[tiab] OR cytarabine[tiab] OR cytosar[tiab] OR “cytosine arabinoside”[tiab] OR Cytoxan[tiab] OR dacarbazine[tiab] OR dasatinib[tiab] OR daunorubicin[tiab] OR daunoxome[tiab] OR deltasone[tiab] OR docetaxel[tiab] OR doxorubicin[tiab] OR efudex[tiab] OR eldisine[tiab] OR Ellence[tiab] OR Eloxatin[tiab] OR emcyt[tiab] OR enocitabine[tiab] OR epirubicin[tiab] OR erlotinib[tiab] OR etopophos[tiab] OR etoposide[tiab] OR estramustine[tiab] OR exemestane[tiab] OR fareston[tiab] OR femara[tiab] OR fludara[tiab] OR fludarabine[tiab] OR folex[tiab] OR fulvestrant[tiab] OR Faslodex[tiab] OR gefitinib[tiab] OR gemcitabine[tiab] OR gemtuzumab[tiab] OR gemzar[tiab] OR gleevec[tiab] OR glivec[tiab] OR herceptin[tiab] OR hexamethylmelamine[tiab] OR hydroxycarbamide[tiab] OR hydroxyurea[tiab] OR idarubicin[tiab] OR IFEX[tiab] OR ifosfamide[tiab] OR imatinib[tiab] OR “interferon alpha”[tiab] OR iressa[tiab] OR irinotecan[tiab] OR ixabepilone[tiab] OR ixempra[tiab] OR lapatinib[tiab] OR letrozole[tiab] OR lomustine[tiab] OR matulane[tiab] OR mechlorethamine[tiab] OR melphalan[tiab] OR methotrexate[tiab] OR “mitomycin c”[tiab] OR mitoxantrone[tiab] OR mustargen[tiab] OR “mustine Hcl”[tiab] OR mutamycin[tiab] OR myleran[tiab] OR mylotarg[tiab] OR navelbine[tiab] OR nilotinib[tiab] OR “nitrogen mustard HCl”[tiab] OR nolvadex[tiab] OR novantrone[tiab] OR oncovin[tiab] OR oxaliplatin[tiab] OR ozogamicin[tiab] OR paclitaxel[tiab] OR paraplatin[tiab] OR pemetrexed[tiab] OR pentostatin[tiab] OR platinol[tiab] OR prednisone[tiab] OR procarbazine[tiab] OR rituxan[tiab] OR rituximab[tiab] OR sorafenib[tiab] OR sprycel[tiab] OR streptozocin[tiab] OR sunitinib[tiab] OR sunrabin[tiab] OR sutent[tiab] OR tamoxifen[tiab] OR tarceva[tiab] OR tasigna[tiab] OR taxol[tiab] OR taxotere[tiab] OR temodar[tiab] OR temozolomide[tiab] OR teniposide[tiab] OR thioplex[tiab] OR thiotepa[tiab] OR toposar[tiab] OR topotecan[tiab] OR toremifene[tiab] OR trastuzumab[tiab] OR tretinoin[tiab] OR tykerb[tiab] OR velban[tiab] OR velcade[tiab] OR vepesid[tiab] OR vesanoid[tiab] OR vinblastine[tiab] OR vincasar[tiab] OR
| vincrex[tiab] OR vincristine[tiab] OR vindesine[tiab] OR vinorelbine[tiab] OR VM26[tiab] OR VP16[tiab] OR Vumon[tiab] OR Xeloda[tiab] OR zanosar[tiab]) AND (Environmental exposure[mh] OR Occupational exposure[mh] OR occupational diseases[mh] OR occupation*[tiab] OR workplace[tiab] OR work-related[tiab] OR exposure*[tiab] OR exposed[tiab] OR contaminat*[tiab] OR handl*[tiab]) AND Health services[mh] OR health occupations[mh] OR health personnel[mh] OR pharmacist*[tiab] OR technician*[tiab] OR nurse*[tiab] OR nursing[tiab] OR physician*[tiab] OR clinician*[tiab] OR doctor*[tiab] OR veterinarian*[tiab])) OR ((hospital[tiab] OR clinic[tiab] OR medical[tiab] OR health[tiab] OR healthcare[tiab] OR health-care[tiab] OR pharmacy[tiab] OR pharmaceutical*[tiab] OR cancer[tiab] OR oncolog*[tiab] OR veterinary[tiab]) AND (staff[tiab] OR personnel[tiab] OR worker*[tiab] OR employee*[tiab] OR technician*[tiab] OR aide*[tiab] OR assistant*[tiab] OR professional*[tiab] OR setting*[tiab] AND (Neoplasms[mh] OR neoplas*[tiab] OR cancer[tiab] OR cancerous[tiab] OR carcinogenic*[tiab] OR tumor[tiab] OR tumors[tiab] OR tumorigen*[tiab] OR tumour*[tiab] OR leukemia*[tiab] OR lymphoma*[tiab] OR sarcoma*[tiab] OR carcinoma*[tiab] OR adenoma*[tiab] OR melanoma*[tiab] OR DNA damage[mh] OR dna-damage[tiab] OR genetic-damage[tiab] OR chromosom*[tiab] OR chromatid[tiab] OR mutagenicity tests[mh] OR mutagen*[tiab] OR genotox*[tiab] OR micronucle*[tiab]) OR (Reproduction[mh] OR reproduction[tiab] OR reproductive[tiab] OR sexual[tiab] OR intercourse[tiab] OR coitus[tiab] OR ejaculat*[tiab] OR orgasm*[tiab] OR fertiliz*[tiab] OR conception[tiab] OR gametogenesis[tiab] OR oogenesis[tiab] OR spermatogenesis[tiab] OR inseminat*[tiab] OR luteinization[tiab] OR ovulat*[tiab] OR anovulat*[tiab] OR superovulat*[tiab] OR erection*[tiab] OR Reproductive physiological phenomena[mh] OR andropause[tiab] OR menopause[tiab] OR estrous[tiab] OR fertility[tiab] OR fecund*[tiab] OR time-to-pregnancy[tiab] OR menstrua*[tiab] OR pubert*[tiab] OR adrenarche[tiab] OR menarche[tiab] OR Genital diseases, female[mh] OR endometriosis[tiab] OR infertil*[tiab] OR pelvic-inflamm*[tiab] OR genital diseases, male[mh] OR epididymitis[tiab] OR hypospadia*[tiab] OR priapism[tiab] OR prostatitis[tiab] OR cryptorchidism[tiab] OR varicocele[tiab] OR erectile-dysfunction[tiab] OR Pregnancy[mh] OR Pregnant[tiab] OR pregnancy[tiab] OR pregnancies[tiab] OR obstetric*[tiab] OR maternal*[tiab] OR mother*[tiab] OR embryonic and fetal development[mh] OR embryonic-development[tiab] OR fetal-development[tiab] OR organogenesis[tiab] OR body size[mh] OR birth-weight*[tiab] OR growth-retardation[tiab] OR small-for-gestation*[tiab] OR embryo[tiab] OR embryos[tiab] OR embryonic[tiab] OR fetus[tiab] OR foetus[tiab] OR fetal[tiab] OR foetal[tiab] OR gestation*[tiab] OR peripartum[tiab] OR postpartum[tiab] OR placent*[tiab] OR prenatal[tiab] OR perinat*[tiab] OR neonat*[tiab] OR postnat*[tiab] OR labor-onset[tiab] OR Parturition*[tiab] OR birth[tiab] OR births[tiab] OR childbirth*[tiab] OR gravidity[tiab] OR parity[tiab] OR Pregnancy complications[mh] OR pregnancy-complication*[tiab] OR complicated-pregnan*[tiab] OR labor-complication*[tiab] OR complicated-labor[tiab] OR gestational-diabetes[tiab] OR (pregnancy[tiab] AND hypertension[tiab]) OR maternal-death[tiab] OR morning-sickness[tiab] OR breech[tiab] OR ectopic[tiab] OR Pregnancy outcome[mh] OR pregnancy-outcome*[tiab] OR live-birth*[tiab] OR full-term[tiab] OR term-birth*[tiab] OR newborn*[tiab] OR baby[tiab] OR babies[tiab] OR infant*[tiab] OR premature[tiab] OR preterm[tiab] OR pre-term[tiab] OR stillbirth*[tiab] OR still-birth*[tiab] OR stillborn*[tiab] OR still-born*[tiab] OR spontaneous-abortion*[tiab] OR miscarriage*[tiab] OR infant mortality[mh] OR infant-mortality[tiab] OR embryo*-loss[tiab] OR congenital, hereditary, and neonatal diseases and abnormalities[mh] OR congenital[tiab] OR abnormal*[tiab] OR malform*[tiab] OR retard*[tiab] OR prenatal exposure delayed effects[mh] OR teratogen*[tiab] OR embryotoxic*[tiab])
Scopus | TITLE-ABS-KEY(chemotherapy* OR anticancer OR antineoplastic* OR anti-tumor* OR anti-tumour* OR cytostatic OR hazardous-drug* OR drug*-hazardous OR category-d OR category-x OR “4 aminofolic acid” OR “4 epidoxorubicin” OR “5 fluorouracil” OR “6 mercaptopurine” OR “6 thioguanine” OR abraxane OR adrucil OR “all-trans retinoic acid” OR atra OR altretamine OR adriamycin OR “actinomycin D” OR aminopterin OR anastrozole OR “ARA-C” OR arimidex OR aromasin OR “behenoyl cytosine arabinoside” OR bevacizumab OR bhac OR bleomycin OR bortezomib OR busulfan OR busulfex OR carboplatin OR capecitabine OR carmustine OR cerubidine OR chlorambucil OR cisplatin OR cis-platinum OR cyclophosphamide OR cytarabine OR cytosar OR “cytosine arabinoside” OR cytoxan OR dacarbazine OR dasatinib OR daunorubicin OR daunoxome OR deltasone OR docetaxel OR doxorubicin OR efudex OR eldisine OR ellence OR eloxatin OR emcyt OR enocitabine OR epirubicin OR erlotinib OR etopophos OR etoposide OR estramustine OR exemestane OR fareston OR femara OR fludara OR fludarabine OR folex OR fulvestrant OR faslodex OR gefitinib OR gemcitabine OR gemtuzumab OR gemzar OR gleevec OR glivec OR herceptin OR hexamethylmelamine OR hydroxycarbamide OR hydroxyurea OR idarubicin OR ifex OR ifosfamide OR imatinib OR “interferon alpha” OR iressa OR irinotecan OR ixabepilone OR ixempra OR lapatinib OR letrozole OR lomustine OR matulane OR mechlorethamine OR melphalan OR methotrexate OR “mitomycin c” OR mitoxantrone OR mustargen OR “mustine Hcl” OR mutamycin OR myleran OR mylotarg OR navelbine OR nilotinib OR “nitrogen mustard HCl” OR nolvadex OR novantrone OR oncovin OR oxaliplatin OR ozogamicin OR paclitaxel OR paraplatin OR pemetrexed OR pentostatin OR platinol OR prednisone OR procarbazine OR rituxan OR rituximab OR sorafenib OR sprycel OR streptozocin OR sunitinib OR sunrabin OR sutent OR tamoxifen OR tarceva OR tasigna OR taxol OR taxotere OR temodar OR temozolomide OR teniposide OR thioplex OR thiotepa OR toposar OR topotecan OR toremifene OR trastuzumab OR tretinoin OR tykerb OR velban OR velcade OR vepesid OR vesanoid OR vinblastine OR vincasar OR vincrex OR vincristine OR vindesine OR vinorelbine OR vm26 OR vp16 OR vumon OR xeloda OR zanosar) AND TITLE-ABS-KEY(occupation* OR workplace OR work-related OR contaminat* OR handl*) AND TITLE-ABS-KEY((pharmacist* OR technician* OR nurse* OR nursing OR physician* OR clinician* OR doctor* OR veterinarian* OR hospital OR clinic OR medical OR health OR healthcare OR health-care OR pharmacy OR pharmaceutical* OR cancer OR oncolog* OR veterinary) AND (staff OR personnel OR worker* OR employee* OR technician* OR aide* OR assistant* OR professional* OR setting*))
TOXLINE | (chemotherapy OR chemotherapies OR chemotherapeutic OR anticancer OR “anti cancer” OR antineoplastic* OR “anti tumor” OR “anti tumorigenic” OR “anti tumour” OR “anti tumourigenic” OR cytostatic) AND (occupation* OR workplace OR work related OR contaminat* OR handl*) AND (pharmacist OR pharmacists OR technician OR nurse OR nursing OR physician OR clinician OR doctor OR veterinarian OR hospital OR clinic OR medical OR health OR healthcare OR health care OR pharmacy OR pharmaceutical OR cancer OR oncolog* OR veterinary) AND (staff OR personnel OR worker OR employee OR technician OR aide OR assistant OR professional OR setting)
Web of Science | Topic = (Chemotherap* OR anticancer OR antineoplastic* OR anti- tumor* OR anti-tumour* OR cytostatic OR hazardous-drug* OR drug*-hazardous OR category-D OR category-x OR “4 aminofolic acid” OR “4 epidoxorubicin” OR “5 fluorouracil” OR “6 mercaptopurine” OR “6 thioguanine” OR Abraxane OR adrucil OR “all-trans retinoic acid” OR ATRA OR altretamine OR adriamycin OR “actinomycin D” OR aminopterin OR Anastrozole OR “ARA-C” OR arimidex OR aromasin OR “behenoyl cytosine arabinoside” OR bevacizumab OR BHAC OR bleomycin OR bortezomib OR busulfan OR busulfex OR carboplatin OR capecitabine OR carmustine OR Cerubidine OR chlorambucil OR cisplatin OR cis-platinum OR cyclophosphamide OR cytarabine OR cytosar OR “cytosine arabinoside” OR Cytoxan OR dacarbazine OR dasatinib OR daunorubicin OR daunoxome OR deltasone OR docetaxel OR doxorubicin OR efudex OR eldisine OR Ellence OR Eloxatin OR emcyt OR enocitabine OR epirubicin OR erlotinib OR etopophos OR etoposide OR estramustine OR exemestane OR fareston OR femara OR fludara OR fludarabine OR folex OR fulvestrant OR Faslodex OR gefitinib OR gemcitabine OR gemtuzumab OR gemzar OR gleevec OR glivec OR herceptin OR hexamethylmelamine OR hydroxycarbamide OR hydroxyurea OR idarubicin OR IFEX OR ifosfamide OR imatinib OR “interferon alpha” OR iressa OR irinotecan OR ixabepilone OR ixempra OR lapatinib OR letrozole OR lomustine OR matulane OR mechlorethamine OR melphalan OR methotrexate OR “mitomycin c” OR mitoxantrone OR mustargen OR “mustine Hcl” OR mutamycin OR myleran OR mylotarg OR navelbine OR nilotinib OR “nitrogen mustard HCl” OR nolvadex OR novantrone OR oncovin OR oxaliplatin OR ozogamicin OR paclitaxel OR paraplatin OR pemetrexed OR pentostatin OR platinol OR prednisone OR procarbazine OR rituxan OR rituximab OR sorafenib OR sprycel OR streptozocin OR sunitinib OR sunrabin OR sutent OR tamoxifen OR tarceva OR tasigna OR taxol OR taxotere OR temodar OR temozolomide OR teniposide OR thioplex OR thiotepa OR toposar OR topotecan OR toremifene OR trastuzumab OR tretinoin OR tykerb OR velban OR velcade OR vepesid OR vesanoid OR vinblastine OR vincasar OR vincrex OR vincristine OR vindesine OR vinorelbine OR VM26 OR VP16 OR Vumon OR Xeloda OR zanosar) AND Topic = ((pharmacist* OR technician* OR nurse* OR nursing OR physician* OR clinician* OR doctor* OR veterinarian* OR hospital OR clinic OR medical OR health OR healthcare OR health-care OR pharmacy OR pharmaceutical* OR cancer OR oncolog* OR veterinary) AND (staff OR personnel OR worker* OR employee* OR technician* OR aide* OR assistant* OR professional* OR setting*)) AND Topic = (occupation* OR workplace OR work-related OR contaminat* OR handl*) AND Topic = (neoplas* OR cancer OR cancerous OR carcinogenic* OR tumor OR tumors OR tumorigen* OR tumour* OR leukemia* OR lymphoma* OR sarcoma* OR carcinoma* OR adenoma* OR melanoma* OR dna-damage OR genetic-damage OR chromosom* OR chromatid OR mutagen* OR genotox* OR micronucle*) OR Topic = (reproduction OR reproductive OR sexual OR intercourse OR coitus OR ejaculat* OR orgasm* OR fertiliz* OR conception OR gametogenesis OR oogenesis OR spermatogenesis OR inseminat* OR luteinization OR ovulat* OR anovulat* OR superovulat* OR erection* OR andropause OR menopause OR estrous OR fertility OR fecund* OR time-to-pregnancy OR menstrua* OR pubert* OR adrenarche OR menarche OR endometriosis OR infertil* OR pelvic-inflamm* OR epididymitis OR hypospadia* OR priapism OR prostatitis OR cryptorchidism OR varicocele OR erectile-dysfunction OR pregnant OR pregnancy OR pregnancies OR obstetric* OR maternal* OR mother* OR embryonic-development OR fetal-development OR organogenesis OR “body size” OR birth-weight* OR growth-retardation OR small-for-gestation* OR embryo OR embryos OR embryonic OR fetus OR foetus OR fetal OR foetal OR gestation* OR peripartum OR postpartum OR placent* OR prenatal OR perinat* OR neonat* OR postnat* OR labor-onset OR Parturition* OR birth OR births OR childbirth* OR gravidity OR parity OR pregnancy-complication* OR complicated-pregnan* OR labor-complication* OR complicated-labor OR gestational-diabetes OR (pregnancy AND hypertension) OR maternal-death OR morning-sickness OR breech OR ectopic OR pregnancy-outcome* OR live-birth* OR full-term OR term-birth* OR newborn* OR baby OR babies OR infant* OR premature OR preterm OR pre-term OR stillbirth* OR still-birth* OR stillborn* OR still-born* OR spontaneous-abortion* OR miscarriage* OR infant-mortality OR embryo*-loss OR congenital OR abnormal* OR malform* OR retard* OR teratogen* OR embryotoxic*)