# Overview

The Centers for Disease Control and Prevention and the Agency for Toxic Substances and Disease Registry nominated chemicals associated with the Elk River spill in West Virginia to the National Toxicology Program (NTP) for toxicology studies. In response, NTP performed research to evaluate the toxicity of 4-methylcyclohexanemethanol (MCHM) and the additional chemical components of crude MCHM through various short-term studies. The goals of this research program were to: (1) evaluate the teratogenic, immunotoxic, and genotoxic potential of MCHMl; (2) identify sensitive biological effects of the spill chemicals and provide additional information about the levels at which there are no adverse effects; and (3) use efficient, medium-, and high-throughput methods to predict qualitative and quantitative toxicological properties of all chemicals spilled into the Elk River.

These goals were addressed utilizing prenatal developmental toxicity studies in rats, dermal hypersensitivity and irritancy studies in mice, short-term toxicogenomic studies in rats, medium-throughput screening assessments in lower animal models, and high-throughput screening assays. The information and results presented in this Immunotoxicity Report are specific to the dermal hypersensitivity and irritancy studies on MCHM and crude MCHM, however, further information about the NTP research program related to the Elk River spill in West Virginia is available at: https://ntp.niehs.nih.gov/results/areas/wvspill/index.html.

This report is a comprehensive presentation of all data and information related to the studies of the dermal hypersensitivity and irritancy work on MCHM.