# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2690-2060

DOI: https://doi.org/10.22427/NTP-IMM-01

Report Series: NTP Immunotoxicity Report Series

Report Series Number: 01

Official citation: National Toxicology Program (NTP). 2020. NTP immunotoxicity technical report on the dermal hypersensitivity and irritancy studies of 4-methylcyclohexanemethanol (CASRN 34885-03-5) and crude 4-methylcyclohexanemethanol administered topically to female BALB/c mice. Research Triangle Park, NC: National Toxicology Program. Immunotoxicity Report 01.